# References

Abou-Donia MB, Goldstein LB, Bullman S, Tu T, Khan WA, Dechkovskaia AM, Abdel-Rahman AA. 2008. Imidacloprid induces neurobehavioral deficits and increases expression of glial fibrillary acidic protein in the motor cortex and hippocampus in offspring rats following in utero exposure. J Toxicol Environ Health A. 71(2):119–130. 10.1080/15287390701613140 18080902
Alloisio S, Nobile M, Novellino A. 2015. Multiparametric characterisation of neuronal network activity for in vitro agrochemical neurotoxicity assessment. Neurotoxicology. 48:152–165. 10.1016/j.neuro.2015.03.013 25845298
Babelova J, Sefcikova Z, Cikos S, Spirkova A, Kovarikova V, Koppel J, Makarevich AV, Chrenek P, Fabian D. 2017. Exposure to neonicotinoid insecticides induces embryotoxicity in mice and rabbits. Toxicology. 392:71–80. 10.1016/j.tox.2017.10.011 29061322
Bal R, Erdogan S, Theophilidis G, Baydas G, Naziroglu M. 2010. Assessing the effects of the neonicotinoid insecticide imidacloprid in the cholinergic synapses of the stellate cells of the mouse cochlear nucleus using whole-cell patch-clamp recording. Neurotoxicology. 31(1):113–120. 10.1016/j.neuro.2009.10.004 19853623
Bao H, Shao X, Zhang Y, Cheng J, Wang Y, Xu X, Fang J, Liu Z, Li Z. 2016. IPPA08 allosterically enhances the action of imidacloprid on nicotinic acetylcholine receptors. Insect Biochem Mol Biol. 79:36–41. 10.1016/j.ibmb.2016.10.010 27793626
Bhaskar R, Mishra AK, Mohanty B.2017. Neonatal exposure to endocrine disrupting chemicals impairs learning behaviour by disrupting hippocampal organization in male Swiss albino mice. Basic Clin Pharmacol Toxicol. 10.1111/bcpt.12767
Bhaskar R, Mohanty B. 2014. Pesticides in mixture disrupt metabolic regulation: In silico and in vivo analysis of cumulative toxicity of mancozeb and imidacloprid on body weight of mice. Gen Comp Endocrinol. 205:226–234. 10.1016/j.ygcen.2014.02.007 24530807
Bonmatin JM, Giorio C, Girolami V, Goulson D, Kreutzweiser DP, Krupke C, Liess M, Long E, Marzaro M, Mitchell EA, 2015. Environmental fate and exposure; neonicotinoids and fipronil. Environ Sci Pollut Res Int. 22(1):35–67. 10.1007/s11356-014-3332-7 25096486
Camlica Y, Bediz SC, Comelekoglu U, Yilmaz SN. 2018. Toxic effect of acetamiprid on Rana ridibunda sciatic nerve (electrophysiological and histopathological potential). Drug Chem Toxicol. 42(3):264–269. 10.1080/01480545.2018.1442475 29536770
Carmichael SL, Yang W, Roberts E, Kegley SE, Padula AM, English PB, Lammer EJ, Shaw GM. 2014. Residential agricultural pesticide exposures and risk of selected congenital heart defects among offspring in the San Joaquin Valley of California. Environ Res. 135:133–138. 10.1016/j.envres.2014.08.030 25262086
Caron-Beaudoin E, Denison MS, Sanderson JT. 2016. Effects of neonicotinoids on promoter-specific expression and activity of aromatase (CYP19) in human adrenocortical carcinoma (H295R) and primary umbilical vein endothelial (HUVEC) cells. Toxicol Sci. 149(1):134–144. 10.1093/toxsci/kfv220 26464060
Caron-Beaudoin E, Viau R, Hudon-Thibeault AA, Vaillancourt C, Sanderson JT. 2017. The use of a unique co-culture model of fetoplacental steroidogenesis as a screening tool for endocrine disruptors: The effects of neonicotinoids on aromatase activity and hormone production. Toxicol Appl Pharmacol. 332:15–24. 10.1016/j.taap.2017.07.018 28750898
Cartereau A, Martin C, Thany SH. 2017. Neonicotinoid insecticides differently modulate acetycholine-induced currents on mammalian alpha7 nicotinic acetylcholine receptors. Br J Pharmacol. 175(11):1987–1998. . 10.1111/bph.14018 28853147
ChemIDplus.2017. ChemIDplus – a TOXNET database. Bethesda, MD: National Institutes of Health, National Library of Medicine. https://chem.nlm.nih.gov/chemidplus/.
Chen M, Tao L, McLean J, Lu C. 2014. Quantitative analysis of neonicotinoid insecticide residues in foods: Implication for dietary exposures. J Agric Food Chem. 62(26):6082–6090. 10.1021/jf501397m 24933495
Christen V, Rusconi M, Crettaz P, Fent K. 2017. Developmental neurotoxicity of different pesticides in PC-12 cells in vitro. Toxicol Appl Pharmacol. 325:25–36. 10.1016/j.taap.2017.03.027 28385489
Cimino AM, Boyles AL, Thayer KA, Perry MJ. 2017. Effects of neonicotinoid pesticide exposure on human health: A systematic review. Environ Health Perspect. 125(2):155–162. 10.1289/EHP515 27385285
Douglas MR, Tooker JF. 2015. Large-scale deployment of seed treatments has driven rapid increase in use of neonicotinoid insecticides and preemptive pest management in US field crops. Environ Sci Technol. 49(8):5088–5097. 10.1021/es506141g 25793443
Dwyer JB, McQuown SC, Leslie FM. 2009. The dynamic effects of nicotine on the developing brain. Pharmacol Ther. 122(2):125–139. 10.1016/j.pharmthera.2009.02.003 19268688
European Food Safety Authority (EFSA). 2013. Scientific opinion on the developmental neurotoxicity potential of acetamiprid and imidacloprid. EFSA J. 11(12):3471.10.2903/j.efsa.2013.3471
Gawade L, Dadarkar SS, Husain R, Gatne M. 2013. A detailed study of developmental immunotoxicity of imidacloprid in Wistar rats. Food Chem Toxicol. 51:61–70. 10.1016/j.fct.2012.09.009 23000444
Gu YH, Li Y, Huang XF, Zheng JF, Yang J, Diao H, Yuan Y, Xu Y, Liu M, Shi HJ, 2013. Reproductive effects of two neonicotinoid insecticides on mouse sperm function and early embryonic development in vitro. PLoS One. 8(7):e70112. 10.1371/journal.pone.0070112 23922925
Gyori J, Farkas A, Stolyar O, Szekacs A, Mortl A, Wehovsky A. 2017. Inhibitory effects of four neonicotinoid active ingredients on acetylcholine esterase activity. Acta Biol Hung. 68(4):345–357. 10.1556/018.68.2017.4.1 29262703
Higgins J, Green S. 2011. Cochrane handbook for systematic reviews of interventions. The Cochrane Collaboration.
Hladik ML, Kolpin DW, Kuivila KM. 2014. Widespread occurrence of neonicotinoid insecticides in streams in a high corn and soybean producing region, USA. Environ Pollut. 193:189–196. 10.1016/j.envpol.2014.06.033 25042208
Hogg RC, Raggenbass M, Bertrand D. 2003. Nicotinic acetylcholine receptors: From structure to brain function. Rev Physiol Biochem Pharmacol. 147:1–46. 10.1007/s10254-003-0005-1 12783266
Jeschke P, Nauen R, Schindler M, Elbert A. 2011. Overview of the status and global strategy for neonicotinoids. J Agric Food Chem. 59(7):2897–2908. 10.1021/jf101303g 20565065
Kara M, Yumrutas O, Demir CF, Ozdemir HH, Bozgeyik I, Coskun S, Eraslan E, Bal R. 2015. Insecticide imidacloprid influences cognitive functions and alters learning performance and related gene expression in a rat model. Int J Exp Pathol. 96(5):332–337. 10.1111/iep.12139 26568164
Kawahata I, Yamakuni T. 2018. Imidacloprid, a neonicotinoid insecticide, facilitates tyrosine hydroxylase transcription and phenylethanolamine N-methyltransferase mRNA expression to enhance catecholamine synthesis and its nicotine-evoked elevation in PC12D cells. Toxicology. 394:84–92. 10.1016/j.tox.2017.12.004 29246838
Keil AP, Daniels JL, Hertz-Picciotto I. 2014. Autism spectrum disorder, flea and tick medication, and adjustments for exposure misclassification: The CHARGE (CHildhood Autism Risks from Genetics and Environment) case-control study. Environ Health. 13(1):3. 10.1186/1476-069X-13-3 24456651
Khan DA, Hashmi I, Mahjabeen W, Naqvi TA. 2010. Monitoring health implications of pesticide exposure in factory workers in Pakistan. Environ Monit Assess. 168(1-4):231–240. 10.1007/s10661-009-1107-2 19669582
Kimura-Kuroda J, Komuta Y, Kuroda Y, Hayashi M, Kawano H. 2012. Nicotine-like effects of the neonicotinoid insecticides acetamiprid and imidacloprid on cerebellar neurons from neonatal rats. PLoS One. 7(2):e32432. 10.1371/journal.pone.0032432 22393406
Kimura-Kuroda J, Nishito Y, Yanagisawa H, Kuroda Y, Komuta Y, Kawano H, Hayashi M. 2016. Neonicotinoid insecticides alter the gene expression profile of neuron-enriched cultures from neonatal rat cerebellum. Int J Environ Res Public Health. 13(10):987. 10.3390/ijerph13100987 27782041
Krupke CH, Hunt GJ, Eitzer BD, Andino G, Given K. 2012. Multiple routes of pesticide exposure for honey bees living near agricultural fields. PLoS One. 7(1):e29268. 10.1371/journal.pone.0029268 22235278
Kudelska MM, Holden-Dye L, O’Connor V, Doyle DA. 2017. Concentration-dependent effects of acute and chronic neonicotinoid exposure on the behaviour and development of the nematode Caenorhabditis elegans. Pest Manag Sci. 73(7):1345–1351. 10.1002/ps.4564 28261957
Kugathas S, Audouze K, Ermler S, Orton F, Rosivatz E, Scholze M, Kortenkamp A. 2016. Effects of common pesticides on prostaglandin D2 (PGD2) inhibition in SC5 mouse Sertoli cells, evidence of binding at the COX-2 active site, and implications for endocrine disruption. Environ Health Perspect. 124(4):452–459. 10.1289/ehp.1409544 26359731
Lansdell SJ, Millar NS. 2000. The influence of nicotinic receptor subunit composition upon agonist, alpha-bungarotoxin and insecticide (imidacloprid) binding affinity. Neuropharmacology. 39(4):671–679. 10.1016/S0028-3908(99)00170-7 10728888
Latli B, D’Amour K, Casida JE. 1999. Novel and potent 6-chloro-3-pyridinyl ligands for the alpha4beta2 neuronal nicotinic acetylcholine receptor. J Med Chem. 42(12):2227–2234. 10.1021/jm980721x 10377228
Levin ED. 2002. Nicotinic receptor subtypes and cognitive function. J Neurobiol. 53(4):633–640. 10.1002/neu.10151 12436426
Li P, Ann J, Akk G. 2011. Activation and modulation of human alpha4beta2 nicotinic acetylcholine receptors by the neonicotinoids clothianidin and imidacloprid. J Neurosci Res. 89(8):1295–1301. 10.1002/jnr.22644 21538459
Liu X, Zhang Q, Li S, Mi P, Chen D, Zhao X, Feng X. 2018. Developmental toxicity and neurotoxicity of synthetic organic insecticides in zebrafish (Danio rerio): A comparative study of deltamethrin, acephate, and thiamethoxam. Chemosphere. 199:16–25. 10.1016/j.chemosphere.2018.01.176 29427810
Marfo JT, Fujioka K, Ikenaka Y, Nakayama SM, Mizukawa H, Aoyama Y, Ishizuka M, Taira K. 2015. Relationship between urinary N-desmethyl-acetamiprid and typical symptoms including neurological findings: A prevalence case-control study. PLoS One. 10(11):e0142172. 10.1371/journal.pone.0142172 26535579
Mason R, Tennekes H, Sánchez-Bayo F, Jepsen PU. 2013. Immune suppression by neonicotinoid insecticides at the root of global wildlife declines. J Environ Immunol Toxicol. 1(1):3–12.10.7178/jeit.1
Meijer M, Brandsema JA, Nieuwenhuis D, Wijnolts FM, Dingemans MM, Westerink RH. 2015. Inhibition of voltage-gated calcium channels after subchronic and repeated exposure of PC12 cells to different classes of insecticides. Toxicol Sci. 147(2):607–617. 10.1093/toxsci/kfv154 26187449
Meijer M, Dingemans MM, van den Berg M, Westerink RH. 2014. Inhibition of voltage-gated calcium channels as common mode of action for (mixtures of) distinct classes of insecticides. Toxicol Sci. 141(1):103–111. 10.1093/toxsci/kfu110 24913802
Methfessel C. 1992. Effect of imidacloprid on the acetylcholine receptor of rat muscle. Pflanzenschutz-Nachr Bayer. 45:369–380.
Morrissey CA, Mineau P, Devries JH, Sanchez-Bayo F, Liess M, Cavallaro MC, Liber K. 2015. Neonicotinoid contamination of global surface waters and associated risk to aquatic invertebrates: A review. Environ Int. 74:291–303. 10.1016/j.envint.2014.10.024 25454246
Nagata K, Aistrup GL, Song JH, Narahashi T. 1996. Subconductance-state currents generated by imidacloprid at the nicotinic acetylcholine receptor in PC 12 cells. Neuroreport. 7(5):1025–1028. 10.1097/00001756-199604100-00014 8804044
Nagata K, Song JH, Shono T, Narahashi T. 1998. Modulation of the neuronal nicotinic acetylcholine receptor-channel by the nitromethylene heterocycle imidacloprid. J Pharmacol Exp Ther. 285(2):731–738. 9580620
National Toxicology Program (NTP).2019. Tableau data on the scoping review of health effects of neonicotinoid pesticides. .10.22427/NTP-DATA-002-00069-0001-0000-8
Osterauer R, Kohler HR. 2008. Temperature-dependent effects of the pesticides thiacloprid and diazinon on the embryonic development of zebrafish (Danio rerio). Aquat Toxicol. 86(4):485–494. 10.1016/j.aquatox.2007.12.013 18281107
Özdemir HH, Kara M, Yumrutas O, Uckardes F, Eraslan E, Demir CF, Bal R.2014. Determination of the effects on learning and memory performance and related gene expressions of clothianidin in rat models. Cogn Neurodyn. 8(5):411-416. 10.1007/s11571-014-9293-1
Pisa LW, Amaral-Rogers V, Belzunces LP, Bonmatin JM, Downs CA, Goulson D, Kreutzweiser DP, Krupke C, Liess M, McField M, 2015. Effects of neonicotinoids and fipronil on non-target invertebrates. Environ Sci Pollut Res Int. 22(1):68–102. 10.1007/s11356-014-3471-x 25223353
Role LW, Berg DK. 1996. Nicotinic receptors in the development and modulation of CNS synapses. Neuron. 16(6):1077–1085. 10.1016/S0896-6273(00)80134-8 8663984
Rooney AA, Boyles AL, Wolfe MS, Bucher JR, Thayer KA. 2014. Systematic review and evidence integration for literature-based environmental health science assessments. Environ Health Perspect. 122(7):711–718. 10.1289/ehp.1307972 24755067
Rundlof M, Andersson GK, Bommarco R, Fries I, Hederstrom V, Herbertsson L, Jonsson O, Klatt BK, Pedersen TR, Yourstone J, 2015. Seed coating with a neonicotinoid insecticide negatively affects wild bees. Nature. 521(7550):77–80. 10.1038/nature14420 25901681
Sano K, Isobe T, Yang J, Win-Shwe TT, Yoshikane M, Nakayama SF, Kawashima T, Suzuki G, Hashimoto S, Nohara K, 2016. In utero and lactational exposure to acetamiprid induces abnormalities in socio-sexual and anxiety-related behaviors of male mice. Front Neurosci. 10:228. 10.3389/fnins.2016.00228 27375407
Scheil V, Kohler HR. 2009. Influence of nickel chloride, chlorpyrifos, and imidacloprid in combination with different temperatures on the embryogenesis of the zebrafish Danio rerio. Arch Environ Contam Toxicol. 56(2):238–243. 10.1007/s00244-008-9192-8 18661094
Senyildiz M, Kilinc A, Ozden S. 2018. Investigation of the genotoxic and cytotoxic effects of widely used neonicotinoid insecticides in HepG2 and SH-SY5Y cells. Toxicol Ind Health. 34(6):375–383. 10.1177/0748233718762609 29591886
Shaw GM, Yang W, Roberts E, Kegley SE, Padula A, English PB, Carmichael SL. 2014. Early pregnancy agricultural pesticide exposures and risk of gastroschisis among offspring in the San Joaquin Valley of California. Birth Defects Res A Clin Mol Teratol. 100(9):686–694. 10.1002/bdra.23263 24910073
Simon-Delso N, Amaral-Rogers V, Belzunces LP, Bonmatin JM, Chagnon M, Downs C, Furlan L, Gibbons DW, Giorio C, Girolami V, 2015. Systemic insecticides (neonicotinoids and fipronil): Trends, uses, mode of action and metabolites. Environ Sci Pollut Res Int. 22(1):5–34. 10.1007/s11356-014-3470-y 25233913
Skandrani D, Gaubin Y, Beau B, Murat JC, Vincent C, Croute F. 2006. Effect of selected insecticides on growth rate and stress protein expression in cultured human A549 and SH-SY5Y cells. Toxicol In Vitro. 20(8):1378–1386. 10.1016/j.tiv.2006.06.001 16884889
Sugiyama C, Kotake Y, Yamaguchi M, Umeda K, Tsuyama Y, Sanoh S, Okuda K, Ohta S. 2015. Development of a simple measurement method for GluR2 protein expression as an index of neuronal vulnerability. Toxicol Rep. 2:450–460. 10.1016/j.toxrep.2014.12.014 28962381
Tan J, Galligan JJ, Hollingworth RM. 2007. Agonist actions of neonicotinoids on nicotinic acetylcholine receptors expressed by cockroach neurons. Neurotoxicology. 28(4):829–842. 10.1016/j.neuro.2007.04.002 17561262
Tanaka T. 2012 a. Effects of maternal clothianidin exposure on behavioral development in F(1) generation mice. Toxicol Ind Health. 28(8):697–707. 10.1177/0748233711422726 22025502
Tanaka T. 2012 b. Reproductive and neurobehavioral effects of clothianidin administered to mice in the diet. Birth Defects Res B Dev Reprod Toxicol. 95(2):151–159. 10.1002/bdrb.20349 22311678
Tennekes HA, Sanchez-Bayo F. 2011. Time-dependent toxicity of neonicotinoids and other toxicants: Implications for a new approach to risk assessment. J Environment Analytic Toxicol. S4:001.
Tomizawa M, Casida JE. 1999. Minor structural changes in nicotinoid insecticides confer differential subtype selectivity for mammalian nicotinic acetylcholine receptors. Br J Pharmacol. 127(1):115–122. 10.1038/sj.bjp.0702526 10369463
Tomizawa M, Casida JE. 2000. Imidacloprid, thiacloprid, and their imine derivatives up-regulate the alpha 4 beta 2 nicotinic acetylcholine receptor in M10 cells. Toxicol Appl Pharmacol. 169(1):114–120. 10.1006/taap.2000.9057 11076703
Tomizawa M, Cowan A, Casida JE. 2001. Analgesic and toxic effects of neonicotinoid insecticides in mice. Toxicol Appl Pharmacol. 177(1):77–83. 10.1006/taap.2001.9292 11708903
U.S. Department of Agriculture (USDA). 2014. Pesticide Data Program—Annual Summary, Calendar Year 2013.
U.S. Food and Drug Administration (FDA).2016. Pesticide Monitoring Program: Fiscal Year 2012 Pesticide Report. Food and Drug Administration.https://www.fda.gov/downloads/Food/FoodborneIllnessContaminants/Pesticides/UCM432758.pdf. [Accessed: 28 April 2017]
Van der Sluijs JP, Amaral-Rogers V, Belzunces LP, Bijleveld van Lexmond MFIJ, Bonmatin JM, Chagnon M, Downs CA, Furlan L, Gibbons DW, Giorio C, 2015. Conclusions of the Worldwide Integrated Assessment on the risks of neonicotinoids and fipronil to biodiversity and ecosystem functioning. Environ Sci Pollut Res Int. 22:148–154. 10.1007/s11356-014-3229-5 25296936
Velisek J, Stara A. 2018. Effect of thiacloprid on early life stages of common carp (Cyprinus carpio). Chemosphere. 194:481–487. 10.1016/j.chemosphere.2017.11.176 29232641
Whitehorn PR, O’Connor S, Wackers FL, Goulson D. 2012. Neonicotinoid pesticide reduces bumble bee colony growth and queen production. Science. 336(6079):351–352. 10.1126/science.1215025 22461500
Yang W, Carmichael SL, Roberts EM, Kegley SE, Padula AM, English PB, Shaw GM. 2014. Residential agricultural pesticide exposures and risk of neural tube defects and orofacial clefts among offspring in the San Joaquin Valley of California. Am J Epidemiol. 179(6):740–748. 10.1093/aje/kwt324 24553680
Yoneda N, Takada T, Hirano T, Yanai S, Yamamoto A, Mantani Y, Yokoyama T, Kitagawa H, Tabuchi Y, Hoshi N.2018. Peripubertal exposure to the neonicotinoid pesticide dinotefuran affects dopaminergic neurons and causes hyperactivity in male mice. J Vet Med Sci. 10.1292/jvms.18-0014