# Appendix A Literature Search Strategy

Table A-1 Literature Search Strategy

Database | Search Terms
PubMed (Date of search: July 20, 2015; 2,051 results. Literature updates: November 17, 2015 (136 results); March 24, 2017 (672 results); April 10, 2018 (454 results)) | Acetamiprid[nm] OR acetamiprid[tiab] OR mospilan[tiab] OR clothianidin[tiab] OR “((e)-1-(2-chloro-1,3-thiazol-5-ylmethyl)-3-methyl-2-nitroguanidine)”[nm] OR Dantop[tiab] OR Dinotefuran[nm] OR dinotefuran[tiab] OR 165252-70-0[rn] OR “1-methyl-2-nitro-3-(tetrahydro-3-furylmethyl)guanidine”[tiab] OR Imidacloprid[nm] OR imidacloprid[tiab] OR 105827-78-9[rn] OR premise-75[tiab] OR “1-((6-Chloro-3-pyridinyl)methyl)-N-nitro-2-imidazolidinimine”[tiab] OR comodor[tiab] OR confidor[tiab] OR coretect[tiab] OR couraze[tiab] OR imicide[tiab] OR proagro[tiab] OR provado[tiab] OR Nitenpyram[nm] OR nitenpyram[tiab] OR Capstar[tiab] OR Thiacloprid[nm] OR thiacloprid[tiab] OR Biscaya[tiab] OR Thiamethoxam[nm] OR thiamethoxam[tiab] OR 153719-23-4[rn] OR Actara[tiab]