# Perspectives: Responding to Medical Emergencies When Flying

Airplane aisle and seats.

## Introduction

You find your seat, buckle up, and the plane takes off. An hour or so into the flight, you hear the flight attendant’s request over the public address system, “If there are any medical personnel on the flight, please press your flight attendant call button.” As medical personnel on the flight, you ask yourself, “Can I respond? Should I respond?”

Per the Federal Aviation Administration (FAA), 2.9 million airline passengers travel on an average of 45,000 flights daily in the United States. Globally, >3.5 billion passengers traveled on commercial aircraft in 2022, nearly returning to pre-COVID-19 pandemic levels.

Medical emergencies occur on approximately 1 of every 604 commercial flights. The most common emergencies include syncope or presyncope, respiratory symptoms, or nausea and vomiting. For 90% of these emergencies, aircraft continue to their destination. For the remaining 10%, however, aircraft divert to an alternative landing site, most frequently for cardiac arrest, cardiac symptoms (e.g., chest pain), obstetric or gynecologic issues, or possible stroke. The death rate for medical emergencies on commercial flights is approximately 0.3%.

## Medical supplies on aircraft

### U.S. carriers

The FAA mandates which medical supplies U.S. carrier aircraft flying domestically or internationally must have available onboard. Required medical supplies on U.S. carrier aircraft are listed in the Code of Federal Regulations (14 CFR, Part 121; subpart X, 121.803 (https://www.ecfr.gov/current/title-14/chapter-I/subchapter-G/part-121/subpart-X/section-121.803) and Appendix A (https://www.ecfr.gov/current/title-14/chapter-I/subchapter-G/part-121/appendix-Appendix%20A%20to%20Part%20121)). U.S. carrier aircrafts with ≥1 flight attendant are required to have a U.S. Food and Drug Administration–approved automated external defibrillator, ≥1 first aid kit, and an emergency medical kit (EMK) in the passenger cabin. The number of first aid kits available on an aircraft corresponds to the number of seats: one kit for 0–50 seats; two for 51–150 seats; three for 151–250 seats; four for >250 seats. Travelers should be aware that supplemental oxygen may not be available on board.

A first aid kit must contain the items listed in Box 7.2.1.

Box 7.2.1 First aid kit contents ★

- Adhesive tape (1-inch) Antiseptic swabs
- Ammonia inhalants
- Bandage compresses (1-inch adhesive, 4-inch and 40-inch triangular) Bandage scissors
- Roller bandage (4-inch)
- Splints (arm and leg)

A list of medications required in the EMK and equipment for administration can be found in Box 7.2.2. A blood pressure cuff, stethoscope, cardiopulmonary resuscitation masks, oropharyngeal airways, and a manual resuscitator for ventilation are included for use in the event of a cardiac or pulmonary event.

Box 7.2.2 Emergency medical kit ★

##### Medications

- Antihistamine (25 mg tablets and 50 mg injectable)
- Aspirin (325 mg)
- Atropine (0.5 mg)
- Bronchodilator, for inhalation
- Dextrose (50%)
- Epinephrine (1:1,000 and 1:10,000)
- Lidocaine (20 mg/mL)
- Nitroglycerin tablets (0.4 mg)
- Non-narcotic analgesic (325 mg)
- Saline (500 cc)

##### Supplies

- Airways, oropharyngeal (3 sizes)
- Cardiopulmonary resuscitation masks (3 sizes)
- Intravenous line set (tubing, alcohol sponges, adhesive tape, tape scissors, tourniquet)
- Needles (for medication administration)
- Protective gloves
- Self-inflating manual resuscitation device with mask (3 sizes) Sphygmomanometer
- Stethoscope
- Syringes (for medication administration)

### International carriers

EMK contents may vary among international carriers, despite guidance from the International Civil Aviation Organization (ICAO).

## Infection control supplies on aircraft

ICAO provides guidance for commercial aircraft to carry one or more “Universal Precaution Kits” containing standard personal protective equipment and supplies to clean contaminated surfaces. As these kits are not regulated by the FAA, their presence or completeness on any given aircraft cannot be guaranteed.

## Legal considerations

### U.S. domestic flights

The 1998 Aviation Medical Assistance Act (AMAA) of the United States protects medical personnel from damages in federal or state court for providing good-faith medical care in the event of a medical emergency. The AMAA does not cover gross negligence or willful misconduct.

### International flights

Air carriers flagged in some countries (e.g., Canada, the United Kingdom, the United States) do not require medical personnel to respond to in-flight medical emergencies. Other countries state that healthcare professionals have an obligation to respond.

When responding to a medical emergency on an international flight, the AMAA might not apply. Furthermore, it is unclear what entity has jurisdiction over liability for care rendered; the country where the aircraft is registered might have jurisdiction, or jurisdiction could be based on the aircraft’s geographic location at the time an incident occurs. In other cases, the medical responder’s licensure country is the jurisdiction for liability. Jurisdiction might also depend on whether the aircraft was in the air or on the ground when the incident occurred. Although most airlines and countries offer protection for Good Samaritans, medical personnel responding to an emergency, even if an act of goodwill, might be at risk of litigation.

### Things to consider before responding

Am I eligible to respond? For U.S. domestic flights, the 1998 AMAA defines a medically qualified individual as “any person who is licensed, certified, or otherwise qualified to provide medical care in a state, including a physician, nurse, physician assistant, paramedic, and emergency medical technician.” You may be asked to provide documentation of your level of training and licensure. For international flights, which medical personnel are accepted as medically qualified may vary by country and airline.

Should I respond if I consumed alcohol (or any other substance or medication that may affect judgment) on the flight or before boarding? If you have, reconsider responding—you might be at risk for misconduct.

What is my personal level of comfort and clinical competence in evaluating a person with a medical issue? Most commercial aircraft use ground-based medical services to assist with clinical assessment and make decisions regarding severity and flight diversion. If multiple medical personnel volunteer to assist, determine who has the most relevant experience to assist the person efficiently and competently. Because responding to a mid-flight medical event may be stress-inducing for the responder, anxiety level may also impact a responder’s willingness and degree of involvement.

Should I respond if I am flying on an international carrier whose flag is not the United States? The legal ramifications of delivering care to a fellow passenger or a crew member are not always clear.

Box 7.2.3 provides a checklist for medical personnel responding to in-flight medical emergencies.

Box 7.2.3 Responding to in-flight medical emergencies: a checklist for medical personnel ★

- Be calm and confident.
- Ask ill persons who are alert and oriented for verbal consent to treat. If they are a minor, ask their guardian, if available.
- Determine the ill person’s primary language and obtain translation support from flight attendants or other passengers if necessary.
- Use flight attendants as assistants, as appropriate. Flight attendants are certified in cardiopulmonary resuscitation and in the use of an automated external defibrillator (AED). Ask them for needed items from the first aid kit, emergency medical kit (EMK), and the AED.
- Obtain a medical history, check vital signs, and perform a physical examination appropriate to the problem. Auscultation in an aircraft using a stethoscope may be difficult due to ambient noise.
- As necessary, ask for ground-based medical consultation; ask for other onboard clinical support (e.g., obstetrician if a pregnancy-related issue).
- Inquire about what (if any) medical equipment the ill person has in their carry-on (e.g., glucometer, medications), especially for items that are not available in the EMK. Other travelers may also have supplies available (e.g., glucometer), but avoid administering medications obtained from others due to lack of quality control.
- Move ill persons to an area with more room (and privacy) if it can be done safely.
- Notify a crew immediately if the ill person is suspected to have a communicable disease or is severely ill.
- Communicate with the pilot via the flight attendants about the ill person’s condition. Ultimately, the pilot and the ground-based emergency medical services contracted through the carrier have the responsibility to make a decision about diverting the flight.
- Document your clinical encounter on airline-specific forms, if available. Keep a copy for your own record.

## Additional considerations

### Deciding to respond

For U.S.-licensed medical personnel, the decision to respond is a personal one, grounded in ethical obligation. Although the United States offers protections for medical personnel who aid ill persons in good faith, the nature of the medical issue and the possibility that the optimal medications or equipment may not be included in the first aid kit or EMK could create a difficult situation. Always be honest with the flight attendants and the pilot regarding your assessment of the ill person’s condition and your degree of comfort with assisting; if needed supplies are not available aboard the aircraft, communicate this immediately. If traveling on an international carrier’s flight, consider both ethics and the flight’s legal jurisdiction. Also consider that if the medical event occurs at the start of a long-haul flight, volunteering may result in hours of ongoing clinical monitoring.

### Do not resuscitate

If a traveler has a “Do Not Resuscitate” order, you may choose to heed this. Be aware that individual airline policies might require flight attendants to attempt resuscitation despite this documentation.

## For the traveler

Travelers play a role in the prevention of in-flight emergencies. Box 7.2.4 provides recommendations for travelers to help ensure they are fit to fly.

Box 7.2.4 Recommendations for travelers to prevent in-flight emergencies ★

Do not fly while acutely ill. Additionally, if you appear ill you may not be permitted to board. Always carry your medications, medical devices, and supplies (e.g., glucometer, glucose strips) with you on the plane in your carry-on luggage.

Review if you have any medical conditions with contraindications that preclude you from flying. Specific conditions and considerations are listed in Table 2.4.2 in the Travelers with Chronic Illnesses (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/travelers-with-chronic-illnesses.html) chapter. If you have a chronic medical condition, review the checklist in Box 2.4.1 while preparing for international travel.

## Disclaimer

Perspectives chapters supplement the clinical guidance in this book with additional content, context, and expert opinion. The views expressed do not necessarily represent the official position of the Centers for Disease Control and Prevention (CDC).

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Federal Aviation Administration (2023, April 10). Federal Aviation Administration: Air traffic by the numbers. Retrieved January 18, 2024, from https://www.faa.gov/air_traffic/by_the_numbers
• International Civil Aviation Organization. International Civil Aviation Organization: Safety. Retrieved January 18, 2024, from https://www.icao.int/
• Martin-Gill, C., Doyle, T. J., & Yealy, D. M. (2018). In-flight medical emergencies: A review. JAMA, 320(24), 2580–2590. 10.1001/jama.2018.19842 30575886
• Nable, J. V., Tupe, C. L., Gehle, B. D., & Brady, W. J. (2015). In-flight medical emergencies during commercial travel. The New England Journal of Medicine, 373(10), 939–945. 10.1056/NEJMra1409213 26332548
• National Archives and Regulations Administration. Emergency medical equipment. 14 CFR §121.803. Code of Federal Regulations. Retrieved January 18, 2024, from https://www.ecfr.gov/current/title-14/chapter-I/subchapter-G/part-121/subpart-X/section-121.803
• Peterson, D. C., Martin-Gill, C., Guyette, F. X., Tobias, A. Z., McCarthy, C. E., Harrington, S. T., … Yealy, D. M. (2013). Outcomes of medical emergencies on commercial airline flights. The New England Journal of Medicine, 368(22), 2075–2083. 10.1056/NEJMoa1212052 23718164
• U.S. Government Publishing Office. (1998, April 24). Aviation Medical Assistance Act of 1998, HR 2843, 105th Congress. Retrieved January 18, 2024, from https://www.congress.gov/105/plaws/publ170/PLAW-105publ170.pdf