# Post-Travel Respiratory Infections

Traveler sneezing into arm on a plane.

## Introduction

Respiratory infections are a major reason for returning travelers to seek medical care. Upper respiratory infection is more common than lower respiratory infection. In general, the respiratory infections that affect travelers are like those in non-travelers, but it is important for healthcare professionals to be vigilant for travelers’ potential exposure to novel, emerging, or geographically restricted respiratory pathogens. When evaluating a returning traveler with a respiratory infection, inquire about the details of travel, including type of travel and travel destinations.

## Infectious agent

### Bacteria

Bacterial causes of respiratory illnesses include

- Bordetella pertussis
- Burkholderia pseudomallei (the cause of melioidosis)
- Chlamydia pneumoniae
- Corynebacterium diphtheriae
- Haemophilus influenzae
- Mycoplasma pneumoniae
- Staphylococcus aureus
- Streptococcus pneumoniae

Coxiella burnetii and Legionella species can cause outbreaks and sporadic cases of respiratory illness. Group A streptococcus can cause pharyngitis.

### Viruses

Viral pathogens are the most common causes of respiratory infection in travelers. Causative agents include

- Adenoviruses
- Coronaviruses (e.g., severe acute respiratory syndrome coronavirus 2 [SARS-CoV-2], the cause of coronavirus disease 2019 [COVID-19], and the common human coronaviruses [including types 229E, NL63, OC43, and HKU1])
- Human metapneumovirus
- Influenza virus
- Measles virus
- Mumps virus
- Rubella virus
- Parainfluenza virus
- Respiratory syncytial virus
- Rhinoviruses
- Varicella virus

Other viruses of special concern to travelers include Middle East respiratory syndrome (MERS) coronavirus and highly pathogenic avian influenza viruses; consider these viruses in travelers with new-onset respiratory illness, including people requiring hospitalization, when no alternative cause has been identified.

#### Coronaviruses

Include COVID-19 (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/covid-19.html) in the differential diagnosis of travelers who develop upper or lower respiratory tract symptoms, anosmia, diarrhea, fever, or myalgia ≤14 days after international travel. Travelers can be a source of translocation of new SARS-CoV-2 variants from one geographic region to another.

Include MERS (https://www.cdc.gov/coronavirus/mers/index.html) in the differential diagnosis of travelers who develop fever and pneumonia ≤14 days after traveling from countries in or near the Arabian Peninsula. Contact with a confirmed or suspected case of MERS, or with healthcare facilities in a MERS transmission area, is of special concern, even in the absence of confirmed pneumonia.

#### Avian influenza virus

Consider a diagnosis of highly pathogenic avian influenza virus (e.g., H5N1, H7N9) in patients with new onset of severe acute respiratory illness requiring hospitalization when no alternative cause has been identified. A history of recent (≤10 days) travel to a country with confirmed human or animal cases—especially if the traveler had contact with poultry or sick or dead birds—increases the likelihood of the diagnosis.

For more information, see

- The Influenza (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/influenza.html) chapter
- CDC’s influenza (https://www.cdc.gov/flu/about/index.html) website

### Fungi

Fungal pathogens (https://www.cdc.gov/fungal/index.html) associated with travel include

- Blastomyces dermatitidis
- Coccidioides spp.
- Cryptococcus gattii
- Histoplasma capsulatum
- Paracoccidioides spp.
- Talaromyces marneffei (formerly Penicillium marneffei)

### Parasites

Involvement of the respiratory tract by parasites (https://www.cdc.gov/parasites/index.html) acquired during international travel is rare. Individuals can develop a transient illness characterized by reactive airways, bronchospasm, cough, and peripheral eosinophilia during the larval alveolar migratory phase of acute hookworm, ascariasis, and strongyloidiasis. Lung flukes, such as Paragonimus westermani, can be acquired through ingestion of undercooked crabs and crayfish or their juices and can cause pulmonary cavitary nodules, cough, and hemoptysis.

## Epidemiologic considerations

Outbreaks can occur after common-source exposures on cruise ships (https://www.cdc.gov/yellow-book/hcp/travel-air-sea/cruise-ship-travel.html), in hotels, among tour groups, or during international mass gatherings (https://www.cdc.gov/yellow-book/hcp/travel-for-work-other/mass-gatherings.html). H. capsulatum, influenza virus, measles, Legionella species, and SARS-CoV-2 are some of the pathogens associated with respiratory tract outbreaks in travelers. Introduction into home communities with ongoing transmission can occur, a not infrequent scenario with measles. Groups having a greater risk for respiratory tract infection include children, older adults, people with comorbid pulmonary conditions (e.g., asthma, chronic obstructive pulmonary disease [COPD]), and immunosuppressed individuals. For Legionella species, the most common sources of transmission include potable water (via showerheads and faucets), cooling towers, hot tubs, and decorative fountains.

### Air quality

The air quality (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/air-quality-and-ionizing-radiation-during-travel.html) at many travel destinations might be poor, and exposure to carbon monoxide, nitrogen dioxide, ozone, sulfur dioxide, and particulate matter is associated with health risks, including respiratory tract inflammation, exacerbations of asthma or COPD, impaired lung function, bronchitis, and pneumonia.

### Air travel

Air pressure changes during ascent and descent of aircraft can result in barotrauma and facilitate the development of sinusitis and otitis media.

Transmission of respiratory pathogens during air travel can occur via several pathways, including direct droplet spread, direct physical contact, fomites, and suspended small particles (droplet nuclei). Airborne transmission of pathogens aboard commercial aircraft can be limited by air filtration systems, and cabin air generally circulates within limited zones or areas of the aircraft. Despite this, COVID-19, influenza, measles, tuberculosis (TB), and other diseases have been transmitted on aircraft.

Intermingling of large numbers of people in airports and other travel-related settings also can facilitate transmission of respiratory pathogens.

### Seasonality

The peak influenza season in the temperate Northern Hemisphere is during the winter months, typically December–February. In the temperate Southern Hemisphere, peak influenza season runs from late spring or early summer into the fall. Tropical climates have no peak season for influenza, and the risk for infection is year-round. Exposure to an infected person traveling from another hemisphere (e.g., on a cruise ship) can lead to an influenza outbreak at any time or place.

### Tuberculosis

Risk for TB infection (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/tuberculosis.html) among most travelers is low and correlates with the incidence of the disease in the destination country, behavior during travel, and length of stay.

## Clinical presentation

Most respiratory infections, especially those of the upper respiratory tract, are mild. Upper respiratory tract infections often cause pharyngitis or rhinorrhea. Lower respiratory tract infections, particularly pneumonia, can be more severe. Lower respiratory tract infections are more likely than upper respiratory tract infections to cause chest pain, dyspnea, or fever. Cough is often present in either upper or lower respiratory tract infections. Rash may be present, especially in measles, rubella, and varicella.

People with influenza commonly have acute onset of cough, fever, headache, and myalgias. People with COVID-19 might have a similar clinical presentation, but mild disease and asymptomatic infection also are common. Similar symptoms can be seen in a number of bacterial infections, including legionellosis. Consider pulmonary embolism (https://www.cdc.gov/yellow-book/hcp/travel-air-sea/deep-vein-thrombosis-and-pulmonary-embolism.html) in the differential diagnosis of travelers who present with cough, dyspnea, tachycardia, or fever and pleurisy, especially those who have recently been on long car or plane trips.

## Diagnosis

Give special consideration to diagnosing patients with suspected avian influenza, or illnesses caused by coronaviruses (e.g., COVID-19 or MERS). Identifying a specific etiologic agent in immunocompetent hosts, especially in the absence of pneumonia or serious disease, is not always clinically necessary. If indicated, the following diagnostic methods can be used.

### Microbiology

Gram stain and culturing of sputum can help identify a causative respiratory pathogen. Microbiologic culturing of blood, while insensitive, is also recommended as part of a diagnostic workup if there is evidence of severe disease.

### Molecular methods

Molecular methods are available to detect certain respiratory viruses, including adenovirus, human metapneumovirus, influenza virus, parainfluenza virus, respiratory syncytial virus, SARS-CoV-2, and certain nonviral pathogens. Molecular tests for measles, mumps, and rubella are often supplemented with serologic analysis, often working with the local department of public health.

### Rapid diagnostic tests

Rapid tests are available to detect some bacterial (e.g., L. pneumophila, S. pneumoniae, group A Streptococcus), viral (e.g., influenza virus, respiratory syncytial virus, SARS-CoV-2), and fungal (e.g., H. capsulatum) pathogens.

## Treatment

Manage travelers with respiratory infections similarly to non-travelers but evaluate those who are severely ill for diseases specific to their travel destinations and exposure history. Most viral respiratory infections are mild and do not require specific treatment.

Treat travelers with pneumonia of uncertain etiology, as established by the presence of an infiltrate on chest radiography, with antibiotics in accordance with existing guidelines for community-acquired pneumonia.

For travelers with influenza who have severe disease or who are at greater risk for complications, treat with antiviral medications. Antiviral treatment for influenza is most effective if begun ≤48 hours of symptom onset.

Treat people with COVID-19 per current guidance (https://www.cdc.gov/covid/hcp/clinical-care/).

## Prevention

Vaccines are available to prevent or reduce severity of a number of respiratory diseases, including COVID-19, diphtheria, H. influenzae type b (in young children), influenza, measles, mumps, rubella, pertussis, pneumococcal disease, varicella, and respiratory syncytial virus. Unless contraindicated, travelers should be up to date with COVID-19 and influenza vaccines and other routine immunizations, especially against S. pneumoniae, RSV, and measles.

Preventing respiratory illness while traveling might not be possible, but travelers can follow common-sense measures, including adhering to current recommendations regarding advisability of travel and any indicated precautions (e.g., mask wearing, physical distancing); minimizing close contact with people who are coughing or sneezing; avoiding live animal markets; frequently washing hands, either with soap and water or alcohol-based hand sanitizers containing ≥60% alcohol when soap and water are not available; and, if the traveler has a preexisting eustachian tube dysfunction, using a vasoconstricting nasal spray immediately before air travel, which might decrease the likelihood of otitis or barotrauma.

Healthcare workers should use recommended infection control measures while managing any patient with a respiratory infection (https://www.cdc.gov/flu/professionals/infectioncontrol).

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Brown, M. L., Henderson, S. J., Ferguson, R. W., & Jung, P. (2015). Revisiting tuberculosis risk in Peace Corps Volunteers, 2006-13. Journal of Travel Medicine, 23(1), 10.1093/jtm/tav005
• Gautret, P., Angelo, K. M., Asgeirsson, H., Duvignaud, A., van Genderen, P. J. J., Bottieau, E., Chen, L. H., Parker, S., Connor, B. A., Barnett, E. D., Libman, M., Hamer, D. H., & GeoSentinel Network (2019). International mass gatherings and travel-associated illness: A GeoSentinel cross-sectional, observational study. Travel Medicine and Infectious Disease, 32, 101504. 10.1016/j.tmaid.2019.101504 31707112
• German, M., Olsha, R., Kristjanson, E., Marchand-Austin, A., Peci, A., Winter, A. L., & Gubbay, J. B. (2015). Acute Respiratory Infections in Travelers Returning from MERS-CoV-Affected Areas. Emerging Infectious Diseases, 21(9), 1654–1656. 10.3201/eid2109.150472 26291541
• Hertzberg, V. S., Weiss, H., Elon, L., Si, W., Norris, S. L., & FlyHealthy Research Team (2018). Behaviors, movements, and transmission of droplet-mediated respiratory diseases during transcontinental airline flights. Proceedings of the National Academy of Sciences of the United States of America, 115(14), 3623–3627. 10.1073/pnas.1711611115 29555754
• Kakoullis, L., Steffen, R., Osterhaus, A., Goeijenbier, M., Rao, S. R., Koiso, S., Hyle, E. P., Ryan, E. T., LaRocque, R. C., & Chen, L. H. (2023). Influenza: seasonality and travel-related considerations. Journal of Travel Medicine, 30(5), taad102. 10.1093/jtm/taad102 37535890
• Lovey, T., Hasler, R., Gautret, P., & Schlagenhauf, P. (2023). Travel-related respiratory symptoms and infections in travellers (2000-22): a systematic review and meta-analysis. Journal of Travel Medicine, 30(5), taad081. 10.1093/jtm/taad081 37310895
• Plucinski, M. M., Wallace, M., Uehara, A., Kurbatova, E. V., Tobolowsky, F. A., Schneider, Z. D., Ishizumi, A., Bozio, C. H., Kobayashi, M., Toda, M., Stewart, A., Wagner, R. L., Moriarty, L. F., Murray, R., Queen, K., Tao, Y., Paden, C., Mauldin, M. R., Zhang, J., Li, Y., . (2021). Coronavirus Disease 2019 (COVID-19) in Americans Aboard the Diamond Princess Cruise Ship. Clinical Infectious Diseases, 72(10), e448–e457. 10.1093/cid/ciaa1180 32785683
• Speake, H., Phillips, A., Chong, T., Sikazwe, C., Levy, A., Lang, J., Scalley, B., Speers, D. J., Smith, D. W., Effler, P., & McEvoy, S. P. (2020). Flight-Associated Transmission of Severe Acute Respiratory Syndrome Coronavirus 2 Corroborated by Whole-Genome Sequencing. Emerging Infectious Diseases, 26(12), 2872–2880. 10.3201/eid2612.203910 32990563
• Trimble, A., Moffat, V., & Collins, A. M. (2017). Pulmonary infections in the returned traveller. Pneumonia, 9, 1. 10.1186/s41479-017-0026-1 28702303