# Preface

The CDC Yellow Book 2026: Health Information for International Travel continues a long-standing tradition of providing guidance for the practice of travel medicine. It compiles the U.S. government's travel medicine recommendations, which include immunization and prophylaxis for international travel. The goal for this edition is to serve healthcare professionals seeking answers to travel health-related questions. We believe the CDC Yellow Book 2026 lives up to the high standards set by its predecessors.

The editorial team for the CDC Yellow Book 2026 has intended to provide the most evergreen travel health recommendations. Because the field of travel medicine and the epidemiology of travel-associated diseases will continue to evolve, the information in this book may change.

Centers for Disease Control and Prevention

Mandy Cohen, MD, MPH, Director

National Center for Emerging and Zoonotic Infectious Diseases

Daniel Jernigan, MD, MPH, Director

Division of Global Migration Health

CAPT David Fitter, MD, Director

Travelers' Health Branch

Lisa Rotz, MD, Acting Chief