# Post-Arrival Medical Screening of Newly Arrived Refugees, Immigrants, and Migrants

Healthcare professional talking to a young boy.

## Introduction

Ideally, a new arrival medical evaluation for people in refugee, immigrant, and migrant (RIM) communities should occur shortly after arrival to the United States. A new arrival medical evaluation is made up of medical screening for communicable and non-communicable diseases, a medical and migration history, a physical examination, immunizations, and establishing care with a primary care medical home. Screening for diseases specific to country of origin, migration route, and individual epidemiologic risk is important. No standard guidelines are available for post-arrival screening of immigrants or migrants for the United States; however, this chapter provides an approach, with evidence-based guidance largely informed by data from refugee populations (https://www.cdc.gov/immigrant-refugee-health/index.html). An interactive clinical assessment tool, Clinical Assessment for Refugees (CareRef (https://careref.web.health.state.mn.us/)), customizes screening guidance for refugees based on their age, sex, and country of origin.

Because there are RIM population-based differences in access to and coverage for medical services, healthcare professionals should carefully evaluate the individual patient’s health coverage, social determinants of health, infection and disease risk based on their history, and availability of treatment or intervention for conditions identified. These factors will influence the scale and scope of the screening encounter.

For definitions of terms related to RIM populations and to better understand the pre-arrival experience of people in RIM communities, see Pre-Arrival Medical Screening and Interventions for Newly Arrived Refugees, Immigrants, and Migrants (https://www.cdc.gov/yellow-book/hcp/refugees-immigrants-migrants/pre-arrival-medical-screening-and-interventions.html).

## Medical evaluation

Healthcare professionals should follow best practices (https://www.cdc.gov/yellow-book/hcp/refugees-immigrants-migrants/health-communication-with-refugee-immigrant-and-migrant-communities.html) in the clinical approach to RIM patients (e.g., language access, addressing social determinants of health, male/female concordance). Information about country of birth and migration route is important; a guide called “Ask Where” (https://www.health.state.mn.us/communities/rih/coe/askwhere.pdf) is available for primary healthcare professionals to ask questions about where people they provide care for were born. The initial medical evaluation is an important place to: learn about the individual’s medical, migration, and family history; review medications and treatments received before and during migration; and review immunization records. The comprehensive physical examination confirms existing diagnoses and provides the opportunity to identify other conditions, including scarring from cultural health practices or trauma. The history and physical examination will determine if additional evaluation or testing are needed. General age- and risk-based preventive guidelines provided by the United States Preventive Services Task Force (USPSTF) for the general U.S. population apply to foreign-born individuals as well as those born in the United States unless alternative evidence-based guidance exists.

### Communicable diseases

Solicitation of symptoms (e.g., cough) and examination for signs (e.g., skin lesions) of infectious disease are important parts of the initial medical examination. Many infections, such as malaria, leishmaniasis, lice, scabies, leprosy, and upper respiratory infections, can be detected through a history and physical examination.

Infections with long latency (e.g., Chagas disease, cysticercosis, hepatitis B, HIV, strongyloidiasis, schistosomiasis, tuberculosis [TB]) are important causes of morbidity and mortality in RIM populations and should be addressed regardless of the duration of time the individual has been in the United States. Most refugees arriving through the U.S. Refugee Admissions Program receive presumptive treatment for soil-transmitted helminths with albendazole, Strongyloides with ivermectin (in non-Loa loa-endemic areas), and, for those from Sub-Saharan Africa, schistosomiasis (praziquantel) and malaria (artemether-lumefantrine); some may have had screening and/or treatment for other diseases. Non-refugee populations do not receive this pre-departure treatment. Presumptive treatment (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/intestinal-parasites.html) or laboratory testing is encouraged for non-refugee populations and for refugees who have lived in, or migrated through, highly endemic areas who did not receive presumptive treatment before arrival. Additional diagnostic testing for parasitic diseases (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/intestinal-parasites.html) is appropriate for people who present with symptoms (e.g., fever, splenomegaly, eosinophilia, diarrhea) of parasitic diseases which may have been acquired in the country of origin or along the migration route. Although routine screening is not currently recommended, due to a high prevalence of Helicobacter pylori gastritis in RIM populations in the United States, there should be a low threshold for evaluation when symptomatic following criteria outlined by the American College of Gastroenterology (https://journals.lww.com/ajg/fulltext/2017/02000/acg_clinical_guideline__treatment_of_helicobacter.12.aspx).

Hepatitis B is the most common chronic viral hepatitis in RIM populations and is the leading risk factor for hepatocarcinoma. All individuals should have at least one documented negative screening test (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/viral-hepatitis.html) for infection (e.g., hepatitis B surface antigen test) regardless of vaccine status. Hepatitis C rates are variable in RIM groups; testing is recommended (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/viral-hepatitis.html) for all adults ≥18 and children with risk factors (e.g., blood transfusion, history of surgery, or mother with hepatitis C) and in groups with known high prevalence rates.

Testing for sexually transmitted infections in adolescents and adults is recommended in accordance with the USPSTF (https://odphp.health.gov/healthypeople/tools-action/browse-evidence-based-resources/chlamydia-and-gonorrhea-screening) and refugee domestic screening guidance (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/sexual-and-reproductive-health.html). Screening infants or children for sexually transmitted or congenital infections (e.g., chlamydia, gonorrhea, hepatitis B, hepatitis C, HIV, syphilis) beyond what is recommended for the U.S. general population may be appropriate if the person’s social or migration history places them at risk for sexual trauma or other risk factors for infection.

### Non-communicable diseases

Certain RIM populations are disproportionately affected by chronic diseases, such as hypertension, diabetes, and cardiovascular disease, compared to the general U.S. population. Many individuals will have no symptoms on initial evaluation and may have limited access to family history, making physical examination and screening tests particularly important. Abnormal basic physical examination findings and vital signs can identify elevated blood pressure or other signs of cardiopulmonary disease. General recommended laboratory screening includes a complete blood count with differential which can reveal anemia, hemoglobinopathy, eosinophilia, thrombocytopenia, or blood dyscrasia (see Post-Travel Parasitic Disease Including Evaluation of Eosinophilia (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-parasitic-disease.html)). Some RIM populations have a higher risk of diabetes compared to non-refugee matched controls. A random blood sugar, fasting blood sugar, or hemoglobin A1C (https://www.diabetesjournals.org/clinical/article/41/1/4/148029/Standards-of-Care-in-Diabetes-2023-Abridged-for) should be considered for: (1) individuals 35–70 years old who are overweight or obese; or (2) individuals of any age who are overweight or obese with risk factors. A non-fasting lipid panel (https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/statin-use-in-adults-preventive-medication#tab) is an appropriate baseline screen for cardiovascular disease for individuals 40–75 years old with one or more cardiovascular risk factors, including hypertension, smoking, or other conditions.

Children should have routine anthropometric measurement (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/nutrition-and-growth.html) performed at their medical evaluation. Findings of acute malnutrition or stunting should trigger additional review and consideration for diagnostic testing, including assessment for infectious diseases, thyroid disease, hemoglobinopathies, congenital heart disease, and conditions causing feeding difficulties such as cerebral palsy. Additionally, anthropometrics may identify children who are overweight or obese upon arrival. Routine newborn screening is not available in most of the world, and healthcare professionals should be alert for conditions, such as hypothyroidism, that may not have been diagnosed at birth as they would have for children in the United States. Therefore, consider sending a newborn screening panel for children <1 years old (this should be discussed with the state testing lab) and thyroid screening for children <6 years old due to global prevalence of iodine deficiency and subtlety of thyroid disease. RIM communities are disproportionately exposed to lead, both pre-arrival and after arriving to the United States. Pregnant and lactating women and children should be screened for elevated lead levels.

See Table 9.2.1 for a summary of screening tests to consider for medical evaluation of foreign-born individuals.

Table 9.2.1 Recommended laboratory testing for medical evaluation of people in refugee, immigrant, and migrant communities

Test | Age Range | Population | Comments
Chagas disease serology | ≥ 9 months^1^ | Born or lived for a prolonged period (>6 months) in endemic areas in Mexico, Central America, and South America | Confirmation of infection relies on positive results on two or more different serologic tests using different antigen preparations; see guidance (https://pubmed.ncbi.nlm.nih.gov/34623435/)
Complete blood count with differential | All | All | Can identify anemia, thrombocytopenia, and eosinophilia (suggests possible parasitic infection), possible hemoglobinopathy (see Post-Travel Parasitic Disease Including Evaluation of Eosinophilia (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-parasitic-disease.html))
Hepatitis B surface antigen (consider also: hepatitis B surface antibody and core antibody) | All | All not previously tested^2^; see Viral Hepatitis (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/viral-hepatitis.html) | Test for hepatitis B surface antigen regardless of vaccination status; if negative and obtained before a vaccine series is complete, finish the vaccine series; Hepatitis B surface antibody can be interpreted as positive only after a completed vaccine series; hepatitis B antibody testing before completion of the series is not recommended; Hepatitis B surface antibody and core antibody may be used in determining immune status by experienced providers
Hepatitis C | 18–79 years | All (https://www.uspreventiveservicestaskforce.org/uspstf/recommendation/hepatitis-c-screening) | Risk factors (https://www.cdc.gov/mmwr/volumes/69/rr/rr6902a1.htm) include, but are not limited to, perinatal exposure, blood transfusion, intranasal or injection drug use, female genital mutilation/cutting (limited data), and HIV infection
Hepatitis C | < 18 years | Individuals with risk factors (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/viral-hepatitis.html) | Guidelines (https://www.cdc.gov/mmwr/volumes/72/rr/rr7204a1.htm) for testing infants exposed perinatally
HIV | All | Encouraged for all with an opt-out approach (Who Should Get Tested? (https://www.hiv.gov/hiv-basics/hiv-testing/learn-about-hiv-testing/who-should-get-tested/)) | Test and evaluate based on standard guidelines (https://www.cdc.gov/hiv/testing/index.html)
Lead (blood) | <16 years and women who are pregnant or lactating | All | It is important to consider pre- and post-departure risk factors ininterpreting results:; - Lived in highly industrialized city with potential exposure to industrial waste; - Developmental delay; - Medical conditions consistent with lead exposure; - Arriving from a country with history of elevated lead levels E (https://www.publications.aap.org/pediatrics/article/143/5/e20182591/77064/Blood-Lead-Levels-Among-Resettled-Refugee-Children)
Malaria (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/malaria.html) blood smear or PCR | All | Consider screening (or presumptive treatment) for individuals from highly endemic areas of Sub-Saharan Africa up to 3 months after arrival; all others from malaria endemic areas who have symptoms should be tested for malaria, especially in the first year after arrival; If signs or symptoms of acute malaria or hyperreactive malarial splenomegaly syndrome, individuals should be tested for malaria for up to two years after arrival | Testing is not needed for individuals who received pre-departure presumptive treatment unless symptomatic; Testing modalities include malaria blood films, PCR and rapid antigen test, each of which has limitations; See guidance (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/malaria.html) for more details
Schistosoma IgG (see Schistosomiasis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/schistosomiasis.html)) | All | Individuals arriving from endemic areas in Africa; Consider testing if unexplained eosinophilia (or other concerning signs or symptoms) in individuals from endemic areas in the Middle East, South America, and Asia | Testing is not needed for individuals who received pre-departure presumptive treatment
Strongyloides IgG (presumptive treatment is an alternative approach in groups with known high prevalence rates) | All | From endemic areas in the Sub-Saharan Africa, Asia, Middle East, North Africa, Latin America, or Caribbean; Consider testing if unexplained eosinophilia (see Post-Travel Parasitic Disease Including Evaluation of Eosinophilia (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-parasitic-disease.html)); Anyone who will start steroids or other immunosuppressive treatment | Screening or presumptive treatment is not needed for individuals who received pre-departure presumptive treatment.; Caution: Individuals from or who have lived in places endemic for Loa loa: do not treat presumptively for Strongyloides with ivermectin until high microfilarial load from Loa loa has been ruled out.
Soil-transmitted helminths, stool ova, and parasite preparation (see Post-Travel Parasitic Disease Including Evaluation of Eosinophilia (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-parasitic-disease.html)) | All | From endemic areas in the Sub-Saharan Africa, Asia, Middle East, North Africa, Latin America, or Caribbean | Screening or presumptive treatment is not needed for individuals who received pre-departure presumptive treatment.
Tuberculosis screen: IGRA | ≥2 years | All (unless they have a prior positive test) | See Tuberculosis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/tuberculosis.html) chapter
Tuberculosis screen: TST or IGRA | <2 years | | IGRA preferred if the infant has received the Bacillus Calmette-Guérin (BCG) vaccine; Guidance from CDC (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/tuberculosis.html), which favors TST in this age group, differs from the American Academy of Pediatrics (https://publications.aap.org/redbook/book/347/chapter/5749712/Medical-Evaluation-for-Infectious-Diseases-for), which equally recommends TST or IGRA

Notes

Abbreviations: IGRA, interferon-gamma release assay; TST, tuberculin skin test; USPTF, United States Preventive Services Task Force.

1 Screening infants <9 months may be done in consultation with an expert

2 Children (i.e., 1–17 years of age) without other hepatitis B risk factors who do not need to be screened include: 1) those born in regions with hepatitis B virus infection prevalence of <2%; 2) children not vaccinated as infants who were born in the U.S. and whose parents were born in regions with hepatitis B virus infection prevalence of <8% (for more information, see Screening and Testing for Hepatitis B Virus Infection: CDC Recommendations — United States, 2023 (https://www.cdc.gov/mmwr/volumes/72/rr/rr7201a1.htm%23F2_down))

## Vaccinations

Immunization (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/immunizations.html) records provided by patients can be considered valid if the month and year of the vaccine are documented and the vaccine was given at an appropriate age according to the U.S. vaccination schedule. Age-appropriate and catch-up immunizations can be provided according to Advisory Committee on Immunization Practices’ immunization schedules (https://www.cdc.gov/vaccines/hcp/imz-schedules/) during initial and subsequent encounters with newly arrived individuals. A vaccine series does not need to be restarted if documentation of prior doses is available and shows the series was given according to the U.S. vaccination schedule.

Serologic testing (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/immunizations.html#cdc_generic_section_6-serologic-testing-before-vaccination) to document immunity to vaccine-preventable diseases is an acceptable alternative to immunization in specific circumstances. Choice of testing or immunization involves factors such as availability of appropriate test, likelihood of previous infection or immunization, relative cost of test and vaccine, likelihood that the patient will return for vaccine if needed, and preference of provider and patient.

## Mental health and developmental screening

Mental health screening includes gathering information about coping strategies and support systems and creating an opportunity for appropriate and timely referral to resources. It is important to perform a brief mental health screening during the initial medical evaluation to determine need for acute intervention. More thorough testing should only be done when there is care available for conditions identified. The Refugee Health Screener-15 (https://www.refugeehealthta.org/2012/02/08/refugee-health-screener-15-rhs-15/), a linguistically and culturally validated tool in certain groups, may be used for assessment of emotional distress for anyone aged 14 years or older as long as follow-up care and treatment are available for conditions identified. CDC’s Refugee Health Domestic Guidance (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/index.html) includes a section on mental and behavioral health screening that provides additional tools for mental health screening (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/mental-health.html) in adults. The guidance also describes mental health screening in children and explains there is no “gold standard.” The guidance for children recommends focusing on symptoms and functional impairment as well as conducting a developmental assessment for children under the age of 5 years. Developmental assessments can be conducted in the primary care office using the Survey of Wellbeing of Young Children (https://pediatrics.tuftsmedicalcenter.org/The-Survey-of-Wellbeing-of-Young-Children/Translations), an open-access tool available in 16 languages, or consider other tools shared in the Refugee Health Domestic Guidance (https://www.cdc.gov/immigrant-refugee-health/hcp/domestic-guidance/index.html). Health professionals may elect to delay mental and developmental screening until a subsequent second visit as they develop a relationship and build trust with the patient and family.

## Future travel

RIM populations are likely to travel back to their country of origin (https://www.cdc.gov/yellow-book/hcp/refugees-immigrants-migrants/visiting-friends-and-relatives-vfr-travel.html) and are the highest-risk population for many travel-associated infectious diseases. Patients should be counseled that if they plan to travel “home,” that preexisting immunity to some diseases may have waned and they should see a healthcare professional prior to travel. When seeing RIM patients in the clinic, the healthcare professional should routinely ask about future travel plans to alert patients to the need for pre-travel medical preparation (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/the-pre-travel-consultation.html) and to allow time to plan appropriate travel vaccines, medications, and advice.

## Internationally adopted children

The Red Book: Report of the Committee on Infectious Diseases (https://publications.aap.org/redbook/book/755/chapter/14074847/Medical-Evaluation-for-Infectious-Diseases-for?searchresult=1), published by the American Academy of Pediatrics, and the American Academy of Pediatrics Policy Statement on Caring for the Newly Adopted Child (https://www.publications.aap.org/pediatrics/article/143/5/e20190657/37176/Comprehensive-Health-Evaluation-of-the-Newly), offers guidance to pediatricians and other healthcare professionals who will serve newly adopted children after their arrival to the United States.

## Access to care

Refugees qualify for medical benefits through Refugee Medical Assistance (https://www.acf.hhs.gov/orr/programs/refugees/cma) and state Medicaid programs. Non-refugee immigrant communities will have varying access to medical coverage depending on the state where they reside. In some states, people who migrated to the United States may be ineligible for any public programs (e.g., Medicaid; Medicare; Women, Infants, and Children [WIC] Program) for a prolonged period after arrival and dependent on their legal status. Healthcare professionals should consider a patient’s health coverage, social determinants, infectious and other disease risk based on history, and individual patient needs when determining the feasibility of individual elements of the new arrival medical evaluation.

## Acknowledgements

The following authors contributed to the previous version of this chapter: Elizabeth D. Barnett, Jenna Beeler, Tarissa Mitchell, and Joanna Regan.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Asundi, A., Beliavsky, A., Liu, X. J., Akaberi, A., Schwarzer, G., Bisoffi, Z., … Greenaway, C. (2019). Prevalence of strongyloidiasis and schistosomiasis among migrants: A systematic review and meta-analysis. The Lancet: Global Health, 7(2), e236–e248. 10.1016/S2214-109X(18)30490-X 30683241
• Berkowitz, S. A., Fabreau, G. E., Raghavan, S., Kentoffio, K., Chang, Y., He, W., … Percac-Lima, S. (2016). Risk of developing diabetes among refugees and immigrants: A longitudinal analysis. Journal of Community Health, 41(6), 1274–1281. 10.1007/s10900-016-0216-4 27363825
• Kroening, A. L. H., & Dawson-Hahn, E. (2019). Health considerations for immigrant and refugee children. Advances in Pediatrics, 66, 87–110. 10.1016/j.yapd.2019.04.003 31230701
• Kumar, G. S., Beeler, J. A., Seagle, E. E., & Jentes, E. S. (2021). Long-term physical health outcomes of resettled refugee populations in the United States: A scoping review. Journal of Immigrant and Minority Health, 23(4), 813–823. 10.1007/s10903-021-01146-2 33515162
• Liu, Y., Phares, C. R., Posey, D. L., Maloney, S. A., Cain, K. P., Weinberg, M. S., … Cetron, M. S. (2020). Tuberculosis among newly arrived immigrants and refugees in the United States. Annals of the American Thoracic Society, 17(11), 1401–1412. 10.1513/AnnalsATS.201908-623OC 32730094
• Mitchell, T., Lee, D., Weinberg, M., Phares, C., James, N., Amornpaisarnloet, K., … Stauffer, W. M. (2018). Impact of enhanced health interventions for United States-bound refugees: Evaluating best practices in migration health. The American Journal of Tropical Medicine and Hygiene, 98(3), 920–928. 10.4269/ajtmh.17-0725 29260657
• Njeru, J. W., Tan, E. M., St. Sauver, J., Jacobson, D. J., Agunwamba, A. A., Wilson, P. M., … Wieland, M. L. (2016). High rates of diabetes mellitus, pre-diabetes and obesity among Somali immigrants and refugees in Minnesota: A retrospective chart review. Journal of Immigrant and Minority Health, 18(6), 1343–1349. 10.1007/s10903-015-0280-3 26416285
• Pezzi, C., Lee, D., Kennedy, L., Aguirre, J., Titus, M., Ford, R., … Mitchell, T. (2019). Blood lead levels among resettled refugee children in select U.S. states, 2010–2014. Pediatrics, 143(5), 1–10. 10.1542/peds.2018-2591
• Posey, D. L., Blackburn, B. G., Weinberg, M., Flagg, E. W., Ortega, L., Wilson, M., … Maguire, J. H. (2007). High prevalence and presumptive treatment of schistosomiasis and strongyloidiasis among African refugees. Clinical Infectious Diseases, 45(10), 1310–1315. 10.1086/522529 17968826
• Saif, N., Jensen, N., Farrar, E., Blackstone, S., & Hauck, F. R. (2022). Prevalence of Helicobacter pylori infection among resettled refugees presenting to a family medicine clinic in the United States. Helicobacter, 27(3), 1–8. 10.1111/hel.12894