# Measles (Rubeola)

Measles (Rubeola)

## Introduction

Infectious agent | Measles virus
Endemicity | Worldwide
Traveler categories at greatest risk for exposure and infection | All travelers, especially unvaccinated travelers
Prevention methods | Measles is a vaccine-preventable disease
Diagnostic support | A clinical laboratory certified in moderate complexity testing; state health department; or CDC Measles Virus Laboratory (https://www.cdc.gov/measles/php/laboratories/)

## Infectious agent

Measles virus is a member of the genus Morbillivirus of the family Paramyxoviridae.

## Transmission

Measles is transmitted from person to person via respiratory droplets and by the airborne route as aerosolized droplet nuclei. Infected people are usually contagious from 4 days before until 4 days after rash onset. Measles is among the most contagious viral diseases known; secondary attack rates are ≥90% among susceptible household and institutional contacts. Humans are the only natural host for sustaining measles virus transmission, which makes global eradication of measles feasible.

## Epidemiology

The United States has maintained elimination of measles status (defined as the absence of endemic measles virus transmission in a defined geographic area for ≥12 months in the presence of a well-performing surveillance system) since elimination was declared in 2000. However, measles virus continues to be imported into the country from other parts of the world, and recent prolonged outbreaks in the United States resulting from measles virus importations highlighted the challenges faced in maintaining measles elimination status.

Given the large global measles burden and high communicability of the disease, travelers could be exposed to the virus in any country they visit, particularly where measles remains endemic or where large outbreaks are occurring. Most measles cases imported into the United States occur in unvaccinated U.S. residents who become infected while traveling abroad, often to the World Health Organization (WHO)–defined European, Western Pacific, and South-East Asia Regions. These travelers become symptomatic after returning to the United States and sometimes infect others in their communities, causing outbreaks. An outbreak of measles in the United States is defined as a chain of transmission within the country that includes three or more measles cases.

Nearly 90% of imported measles cases in the United States are considered preventable by vaccination (i.e., the travelers lacked recommended age- and travel-appropriate vaccination). Furthermore, observational studies in travel clinics in the United States have shown that 59% of pediatric and 53% of adult travelers eligible for measles-mumps-rubella (MMR) vaccine at the time of pre-travel consultation were not vaccinated at the visit, highlighting missed opportunities to prevent infection and reduce the likelihood of measles virus introductions and subsequent spread. Medical professionals should encourage all eligible travelers to receive appropriate measles vaccination. Response activities following imported cases and outbreak investigations are costly and resource intensive. In addition to personal productivity losses, infected people can incur direct costs for the management of their illness, including treatment, isolation, and caregiving, and their susceptible close contacts may be subject to quarantine requirements.

## Clinical presentation

The incubation period for measles averages 11–12 days from exposure to onset of prodrome; rash usually appears approximately 14 days after exposure. Prodromal symptoms can include fever, with temperature ≤40.6°C (≤105°F); conjunctivitis; coryza (i.e., runny nose); cough; and small spots with white or bluish-white centers on an erythematous base appearing on the buccal mucosa (Koplik spots). A characteristic red, blotchy (maculopapular) rash appears 3–7 days after onset of prodromal symptoms. The rash begins on the face and subsequently becomes generalized to the trunk and extremities and typically lasts 4–7 days.

Common measles complications include diarrhea (8%), middle ear infection (7–9%), and pneumonia (1–6%). Encephalitis, which can result in permanent brain damage, occurs in approximately 1 per 1,000–2,000 cases of measles. Approximately 25% of patients who develop acute measles require hospitalization, generally for management of complications. The risk for serious complications or death is highest for infants, children aged ≤5 years, adults aged ≥20 years, and in populations with poor nutritional status or that lack access to health care.

Subacute sclerosing panencephalitis (SSPE) is a progressive neurologic disorder that usually presents 7–10 years after recovery from the initial primary measles virus infection. SSPE manifests as mental and motor deterioration, which can progress to coma and death. SSPE occurs in approximately 7–11 per 100,000 reported measles cases; rates are higher among children who contract measles at <2 years of age.

## Diagnosis

Measles is a nationally notifiable disease. Laboratory criteria for diagnosis include a positive serologic test for measles-specific IgM, IgG seroconversion, or a significant rise in measles IgG level by any standard serologic assay; isolation of measles virus; or detection of measles virus RNA by real-time reverse transcription polymerase chain reaction (rRT-PCR) testing. CDC’s Measles Virus Laboratory is the national reference laboratory; it provides serologic and molecular testing for measles and technical assistance to state public health laboratories for the collection and shipment of clinical samples for molecular diagnostics and genetic analysis. Four public health laboratories (California, Minnesota, New York State, and Wisconsin) also serve as Association of Public Health Laboratories Vaccine Preventable Disease (https://www.aphl.org/programs/infectious_disease/Pages/VPD.aspx) Reference Centers and can support state public health laboratories to perform specialized molecular testing for measles. See detailed information on diagnostic support (https://www.cdc.gov/measles/php/laboratories/) on CDC’s Measles website.

A clinical case of measles illness is characterized by generalized maculopapular rash lasting ≥3 days; temperature ≥38.3°C (≥101°F); and at least 1 of the “3 Cs” (cough, coryza, or conjunctivitis). A confirmed case is defined as one with an acute febrile rash illness with laboratory confirmation or direct epidemiologic linkage to a laboratory-confirmed case. In a laboratory-confirmed or epidemiologically linked case, the patient’s temperature does not need to reach ≥38.3°C (≥101°F) and the rash does not need to last ≥3 days.

## Treatment

Treatment is supportive. The WHO recommends vitamin A for all children with acute measles, regardless of their country of residence, to reduce the risk for complications. Administer vitamin A orally as follows:

- For infants <6 months old, give 50,000 IU once a day for 2 days
- For infants 6–11 months of age, give 100,000 IU once a day for 2 days
- For children ≥12 months old give 200,000 IU once a day for 2 days.

For children with clinical signs and symptoms of vitamin A deficiency, administer an additional (i.e., a third) age-specific dose of vitamin A at 2–4 weeks following the first round of dosing. There is no need to measure vitamin A concentrations.

## Prevention

Measles has been preventable through vaccination since a vaccine was licensed in 1963. People who do not have evidence of measles immunity should be considered at risk for measles, particularly during international travel.

### Vaccination

Measles vaccine contains live, attenuated measles virus, which in the United States is available only in combination formulations (i.e., measles-mumps-rubella [MMR] and measles-mumps-rubella-varicella [MMRV] vaccines). MMR is licensed for all people aged 6 months or older. MMRV vaccine is licensed for children aged 12 months–12 years and can be used in place of MMR vaccine if vaccination for measles, mumps, rubella, and varicella is needed. The Advisory Committee on Immunization Practices recommends that separate MMR and varicella vaccines be given for the first dose in children aged 12–47 months; however, MMRV may be used if parents or caregivers express a preference (see Precautions later in the chapter).

International travelers who do not have presumptive evidence of measles immunity and who have no contraindications to MMR or MMRV should receive MMR or MMRV before travel per the schedule listed below. Written documentation of receipt of this schedule of measles vaccination with a licensed, live-attenuated measles vaccine is considered presumptive evidence of immunity, and repeat vaccination is not required. Apart from vaccination, international travelers may also have presumptive evidence of immunity to measles if they have any of the following: birth before 1957; laboratory confirmation of prior measles disease; or laboratory proof of immunity (i.e., positive IgG). From 1963–1967, a formalin-inactivated measles vaccine was available in the United States and was administered to approximately 600,000–900,000 people. It was discontinued when it became apparent that the immunity it produced was short-lived. Consider people who received this vaccine unvaccinated. A 2-dose MMR schedule was introduced as standard in 1989; therefore, adults born during 1957–1989 may have received only a single dose of MMR. Verbal or self-reported history of vaccination is not considered valid presumptive evidence of immunity. Vaccination should ideally be completed at least 2 weeks before travel to ensure protection, but it can be received closer to travel if this is not possible (Box 4.11.1).

One dose of MMR is estimated to be approximately 84% effective for preventing measles when administered at 9–11 months of age and a single dose of MMR or MMRV is estimated to be 93–94% effective when administered at age ≥12 months. Vaccine effectiveness of two doses is estimated to be 97%. Box 4.11.1

Box 4.11.1 Measles vaccination recommendations for international travelers based on age ★

Infants (between 6–12 months of age): 1 MMR dose. Infants vaccinated before age 12 months should be revaccinated on or after the first birthday with 2 doses of MMR or MMRV per the recommended schedule. MMRV is not licensed for children aged <12 months.

Children (aged ≥12 months): 2 doses of MMR separated by ≥28 days. If MMRV is used, the interval between doses is ≥3 months.

Adults born in or after 1957: 2 doses of MMR separated by ≥28 days. MMRV is not licensed for persons aged ≥13 years.

#### Adverse reactions

MMR is generally well tolerated and rarely associated with serious adverse events. Common side effects include fever (up to 15%) and a brief, self-limited rash (up to 5%). In rare circumstances, MMR vaccination has been associated with anaphylaxis (approximately 2–14 occurrences per million doses administered); febrile seizures (approximately 1 occurrence per 3,000–4,000 doses administered, but overall, the rate of febrile seizures after measles-containing vaccine is much lower than the rate with measles disease); thrombocytopenia (approximately 1 occurrence per 40,000 doses during the 6 weeks after immunization); or joint symptoms (arthralgia develops among approximately 25% of nonimmune post-pubertal females but symptoms are generally self-limited and chronic symptoms are considered rare). No evidence supports a causal link between MMR vaccination and autism, type 1 diabetes mellitus, or inflammatory bowel disease.

#### Contraindications

##### Allergy

People who experienced a severe allergic reaction (difficulty breathing, hives, hypotension, shock, swelling of the mouth or throat) following a prior dose of MMR or MMRV vaccine, who had an anaphylactic reaction to topically or systemically administered neomycin, or who had a severe allergic reaction to any vaccine component, should not be vaccinated or revaccinated. People who are allergic to eggs can receive MMR or MMRV vaccine without prior routine skin testing or the use of special protocols.

##### Immunosuppression

Enhanced replication of live vaccine viruses can occur in people who have immune deficiency disorders. Death related to vaccine-associated measles virus infection has been reported among severely immunocompromised people; thus, severely immunosuppressed people (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/immunocompromised-travelers.html) should not be vaccinated with MMR or MMRV vaccine.

##### HIV

MMR vaccination is recommended for all people with HIV infection (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/travelers-with-hiv.html) aged ≥12 months who do not have evidence of measles, mumps, and rubella immunity, and who do not have evidence of severe immunosuppression. The assessment of severe immunosuppression can be based on CD4 values (count or percentage); absence of severe immunosuppression is defined as CD4 ≥15% for ≥6 months for children aged ≤5 years, or CD4 ≥15% and CD4 count ≥200 cells/mL for ≥6 months for people aged >5 years.

##### Leukemia

People with leukemia in remission and off chemotherapy, who were not immune to measles when diagnosed with leukemia, may receive MMR vaccine. At least three months should elapse after termination of chemotherapy before administering the first dose of vaccine. Recipients of bone marrow transplantation should be revaccinated after transplantation in accordance with guidance for this specific population.

##### Steroids and other immunosuppressive therapies

Avoid vaccinating people who have received high-dose corticosteroid therapy (in general, considered to be ≥20 mg or 2 mg/kg body weight of prednisone, or its equivalent, daily for ≥14 days) with MMR or MMRV for at least 1 month after cessation of steroid therapy. Corticosteroid therapy usually is not a contraindication when administration is short-term (<14 days) or a low to moderate dose (<20 mg of prednisone or equivalent per day).

In general, withhold MMR or MMRV vaccine for at least 3 months after cessation of other immunosuppressive therapies and remission of the underlying disease.

See Immunocompromised Travelers (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/immunocompromised-travelers.html) for more details.

##### Pregnancy

MMR vaccines should not be administered to pregnant women or women attempting to become pregnant. Because of the theoretical risk to the fetus, women should be counseled to avoid becoming pregnant for 28 days after receiving a live-virus (e.g., MMR) vaccine.

#### Precautions

##### Personal or family history of seizures of any etiology

Compared with administration of separate MMR and varicella vaccines at the same visit, use of MMRV vaccine is associated with a higher risk for fever and febrile seizures 5–12 days after the first dose among children aged 12–23 months. Approximately 1 additional febrile seizure occurs for every 2,300–2,600 MMRV vaccine doses administered. Use of separate MMR and varicella vaccines avoids this increased risk for fever and febrile seizures.

##### Thrombocytopenia

The benefits of primary immunization are usually greater than the potential risks for vaccine-associated thrombocytopenia. Avoid giving subsequent doses of MMR or MMRV vaccine, however, if an episode of thrombocytopenia occurred ≤6 weeks after a previous dose of vaccine.

### Post-exposure prophylaxis

Measles-containing vaccine or immune globulin (IG) can be effective as post-exposure prophylaxis. MMR administered ≤72 hours after initial exposure to measles virus might provide some protection against infection or modify the clinical course of disease.

When administered ≤6 days of exposure, IG can be used to confer temporary immunity in a susceptible person. IG received within 6 days of exposure might reduce the risk for measles or modify disease severity and limit severe complications. Those <12 months of age, pregnant, or severely immunosuppressed with prolonged exposures (i.e., healthcare settings, household, and daycares/classrooms) should be prioritized. If the exposure does not result in modified or typical measles, vaccination is still necessary to provide long-lasting protection. Six months after receiving intramuscularly administered IG or 8 months after receiving intravenously administered IG, administer MMR or MMRV vaccine per the recommended schedule, provided the patient is aged ≥12 months and the vaccine is not otherwise contraindicated.

## Acknowledgments

The following author contributed to the previous version of this chapter: Paul Gastañaduy.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Gastañaduy, P., Redd, S., Clemmons, N., Lee, A. D., Hickman, C. J., Rota, P. A., & Patel, M. (2019). Manual for the surveillance of vaccine-preventable diseases. CDC.gov. https://www.cdc.gov/surv-manual/php/table-of-contents/chapter-7-measles.html
• Hyle, E. P., Fields, N. F., Fiebelkorn, A. P., Walker, A. T., Gastañaduy, P., Rao, S. R., Ryan, E. T., LaRocque, R. C., Walensky, R. P. (2019). The clinical impact and cost-effectiveness of measles-mumps-rubella vaccination to prevent measles importations among international travelers from the United States. Clinical Infectious Diseases, 69(2), 306–315. 10.1093/cid/ciy861 30312374
• Hyle, E. P., Rao, S. R., Bangs, A. C., Gastañaduy, P., Fiebelkorn, A. P., Hagmann, S. H. F., … LaRocque, R. C. (2020). Clinical practices for measles-mumps-rubella vaccination among U.S. pediatric international travelers. JAMA Pediatrics, 174(2), e194515. 10.1001/jamapediatrics.2019.4515 31816033
• Hyle, E. P., Rao, S. R., Jentes, E. S., Parker Fiebelkorn, A., Hagmann, S. H. F., Taylor Walker, A., Walensky, R. P., Ryan, E. T., LaRocque, R. C. (2017). Missed opportunities for measles, mumps, rubella vaccination among departing U.S. adult travelers receiving pretravel health consultations. Annals of internal Medicine, 167(2), 77–84. 10.7326/M16-2249 28505632
• Lee, A. D., Clemmons, N. S., Patel, M., & Gastañaduy, P. A. (2019). International importations of measles virus into the United States during the postelimination era, 2001–2016. The Journal of Infectious Diseases, 219(10), 1616–1623. 10.1093/infdis/jiy701 30535027
• McLean, H. Q., Fiebelkorn, A. P., Temte, J. L., Wallace, G. S., & Centers for Disease Control and Prevention (2013). Prevention of measles, rubella, congenital rubella syndrome, and mumps, 2013: Summary recommendations of the Advisory Committee on Immunization Practices (ACIP). MMWR: Morbidity and Mortality Weekly Report, 62(RR-04), 1–34 23302815
• Patel, M. K., Goodson, J. L., Alexander, J. P., Jr, Kretsinger, K., Sodha, S. V., Steulet, C., Gacic-Dobo, M., Rota, P. A., McFarland, J., Menning, L., Mulders, M. N., Crowcroft, N. S. (2020). Progress toward regional measles elimination—worldwide, 2000–2019. MMWR: Morbidity and Mortality Weekly Report, 69(45), 1700–1705. 10.15585/mmwr.mm6945a6 33180759
• Pike, J., Leidner, A. J., & Gastañaduy, P. A. (2020). A review of measles outbreak cost estimates from the United States in the postelimination era (2004–2017): Estimates by perspective and cost type. Clinical Infectious Diseases, 71(6), 1568–1576. 10.1093/cid/ciaa070 31967305
• Rota, P. A., Moss, W. J., Takeda, M., de Swart, R. L., Thompson, K. M., & Goodson, J. L. (2016). Measles. Nature Reviews: Disease Primers, 2, 1–16. 10.1038/nrdp.2016.49
• Uzicanin, A., & Zimmerman, L. (2011). Field effectiveness of live attenuated measles-containing vaccines: A review of published literature. The Journal of Infectious Diseases, 204(Suppl 1), S133–S148. 10.1093/infdis/jir102 21666154