# Mass Gatherings

Crowd at a concert hall.

## Introduction

Mass gatherings are typically defined as large numbers of people at a specific location for a specific purpose, with the gathering being large enough to strain local resources. Travelers to mass gatherings face unique risks because these events are associated with both communicable diseases (from crowding, poor hygiene practices, sanitation issues, and population dynamics [i.e., specific events attract at-risk groups]) and non-communicable conditions (e.g., temperature extremes, stampedes, environmental hazards, and challenging security situations).

## Mass gathering characteristics

International travelers and their medical providers should understand the characteristics of mass gatherings. Some can be spontaneous (e.g., political protests); others are planned events. Some mass gatherings occur regularly at different locations (e.g., the Olympic Games, the Fédération Internationale de Football Association [FIFA] World Cup); other gatherings recur in the same location (e.g., Hajj (https://www.cdc.gov/yellow-book/hcp/africa-middle-east/saudi-arabia-hajj-and-umrah-pilgrimages.html), the annual Islamic pilgrimage to Mecca). The Kumbh Mela, a major Hindu pilgrimage and festival in India (https://www.cdc.gov/yellow-book/hcp/asia/india.html) held approximately every 12 years, is the world’s largest gathering of humans, attracting 100–200 million participants, including up to 50 million on a single day. Table 8.6.1 provides a brief list of mass gatherings planned in 2026, including type (religious observance, sporting event, or cultural festival), location, and anticipated attendance numbers. Most mass gatherings can be described effectively in terms of their activities, capacity, duration, location, participants, purpose, size, timing, and venue (see Table 8.6.2). Understanding health outcomes previously associated with a recurring mass gathering can help countries, event organizers, and travelers prepare for future events.

Table 8.6.1 Examples of international mass gathering events, 2026

Event Type | Event Name | Host Country | Typical Attendance
Sporting | Olympic Games, Winter | Italy | 1.5 million
Religious | Hajj | Saudi Arabia | 2.5 million
Sporting | FIFA World Cup | Canada, Mexico, and the United States | 3 million
Cultural (arts/music) | Carnival | Brazil (also worldwide) | 7 million
Religious | Arbaeen pilgrimage | Iraq | 15–25 million

Table 8.6.2 Mass Gatherings, Characteristic Features, and Potential Risks

Feature | Potential Risk Considerations
Activities | Some activities can be risky or strenuous (e.g., walking long distances in extreme temperatures) or could involve alcohol or drug use.
Capacity | Surveillance: Host locations differ in their ability to detect, respond to, and prevent public health emergencies.; Security: Arrangements vary.
Duration | The longer an event lasts, the more likely local resources will be depleted and become strained.
Location | Environment and infrastructure affect health and safety of events; some host countries and cities have better natural or engineered resources to handle large numbers of people than others.
Participants | Attendees can represent a unique demographic (e.g., religious, political groups) or vary by sex or age (e.g., older adults attempting to complete a religious pilgrimage toward the end of their life).
Purpose | Mass gatherings can be political, religious, cultural, or sporting events. The purpose of an event can determine the activities and affect the mood of participants.
Size | The density of crowds, not just the number of attendees, contributes to health and safety risks. More densely packed crowds can facilitate disease spread, induce riots, or cause stampedes.
Timing | Mass gatherings and local capacity are affected by the timing of an event.; Season or weather can influence the number in attendance, environmental conditions, and the types of venues needed (indoor versus outdoor), which affect the host location’s ability to organize a safe mass gathering.; Last-minute events (e.g., political rallies) may not have adequate preparation and lead to poor issue mitigation.
Venue | Indoor versus outdoor events create different sets of challenges for mass gathering organizers. Food, water, housing, and sanitation can be of varying quality.

## Mass gathering-associated health concerns

Attendance at a mass gathering can exacerbate a traveler’s existing medical conditions. Emergency medical services often are involved in preparations for gatherings and are usually equipped to address acute medical conditions (e.g., asthma, gastrointestinal infections, heat exhaustion, injuries, myocardial infarction).

### Catastrophic incidents

Catastrophic incidents are of particular concern during mass gatherings, especially with extremely dense crowds. Numerous casualties have occurred at mass gatherings due to poor crowd management, structural collapses, fires, or violence. Crush injuries and death can result from crowding and stampedes. Stampedes are usually the result of overcapacity, poor crowd control, event spaces that lack space and unobstructed exits, inadequate support or attendee destruction of structures, and fire hazards. Recent stampedes that have resulted in deaths occurred at the 2015 Hajj pilgrimage in Saudi Arabia, at the annual Lag BaOmer festival in Israel in 2021, at a soccer match in East Java, Indonesia, in 2022, and during Halloween festivities in Seoul, South Korea, in 2022.

Ensuring personal safety (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/safety-and-security-overseas.html) during mass gatherings is necessary. Travelers should remain aware of their surroundings. If their travel plans include attendance at a mass gathering, providing travelers with information on what to do in a stampede may be beneficial (Figure 8.6.1). Although the risk for large-scale incidents (e.g., terror attacks) are low, they are impossible to predict or eliminate.

Figure 8.6.1 How to protect yourself during a stampede

- Keep your hands up like a boxer.
- Plant your feet firmly on the ground. Try not to fall.
- Don’t resist the force of the crowd.
- When there is a lull in movement, work your way diagonally to the edge of the crowd.
- If you fall, protect yourself by curling into a ball.
- Stay calm and get up as soon as you can.

### Infectious diseases

Mass gathering attendees are at risk for infections, including vaccine-preventable diseases (e.g., COVID-19, influenza, pneumococcal disease). Past mass gatherings have been associated with outbreaks of influenza, meningococcal disease, and norovirus illness. Mass gatherings also have implications for global health security.

Travelers who import infectious diseases to mass gathering host sites can infect both their fellow attendees and the local population. Depending on routes of transmission, incubation periods, and other disease-specific factors, concentrations of people attending mass gatherings may amplify disease transmission. Travelers can also export communicable diseases internationally from the host location to other destinations after departing from a mass gathering.

## Clinician guidance

All elements of the pre-travel consultation (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/the-pre-travel-consultation.html) should be applied to travelers attending mass gatherings. Additional considerations specific to mass gathering attendees are provided below.

### Risk assessment

#### Activities and itineraries

Ask travelers about their activities and itineraries. Review a traveler’s itinerary to identify risks at the destination, in addition to those associated with the event itself. Travelers might add side trips or extend travel beyond the mass gathering.

#### Patient characteristics

Consider the patient’s unique characteristics. Chronic health conditions can be exacerbated while participating in a mass gathering. Counsel patients on the importance of having adequate supplies of medication for the duration of their trip and documentation for any prescriptions. For mass gatherings that require physical activity (e.g., pilgrimages, processions), ensure that the traveler is capable of participating.

### Risk mitigation

#### Vaccines

Encourage vaccination. Ensure that travelers have all appropriate pre-travel vaccinations (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/vaccination-and-immunoprophylaxis-general-principles.html), including routine and required vaccines.

Identify requirements for mass gathering attendees beyond those required for entry to a country. For example, whereas the Kingdom of Saudi Arabia mandates that all participants in the Hajj be vaccinated against meningococcal disease, this requirement does not apply to other travelers visiting the country. Check the Kingdom of Saudi Arabia’s Nusuk Hajj (https://hajj.nusuk.sa/nusuk/health/guidelines) website for up-to-date information.

In addition to any host-country requirements, some destinations and venues can have recommendations for mass gathering attendees based on public health concerns (e.g., demonstrating proof of COVID-19 vaccination). Be prepared to provide documentation as requested.

#### Provide education and guidance to travelers

Educate travelers on preventive measures, including regular application of sunscreen (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/sun-exposure-in-travelers.html) and insect repellent (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html) and advice on how to choose safe food and beverages (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/food-and-water-precautions-for-travelers.html) from vendors. Emphasize the importance of regular handwashing with soap and water and the use of hand sanitizer with ≥60% alcohol content when sanitation facilities are not available.

#### Stay current

CDC regularly updates its Travelers’ Health (https://wwwnc.cdc.gov/travel/) website with Travel Health Notices (notifications of disease outbreaks in countries around the world) and information on select mass gatherings (e.g., Hajj, the Olympic Games).

## Traveler checklist

Box 8.6.2 provides a checklist for travelers planning to attend a mass gathering.

Box 8.6.2 Mass gathering events: a planning checklist for travelers ★

#### Before travel

Check host nation requirements.

- In addition to the entry requirements of the host nation, become informed about all requirements for participating in the mass gathering (e.g., laboratory tests, proof of vaccination, use of smartphone applications).

See a travel medicine provider.

- Make an appointment to see a travel medicine specialist at least 4 weeks before travel—this should allow enough time for you to receive necessary vaccinations, to review your chronic medical conditions, and to receive advice about your planned activities.

Register with the U.S. Department of State’s Smart Traveler Enrollment Program (STEP) (https://step.state.gov/step).

- STEP provides travelers with notifications (e.g., travel warnings, travel alerts, other destination-specific information).
- STEP also makes sure that the State Department can find you if you experience serious legal, medical, or financial difficulties overseas.
- In case of emergency at home, STEP can help friends and family contact you.

Visit the CDC Travelers’ Health (https://wwwnc.cdc.gov/travel/) website.

- Learn more about health and safety issues at specific destinations.
- Find out if CDC has posted a Travel Health Notice for your destination or mass gathering event.

#### During travel

Check the weather before leaving for the venue. Dress appropriately (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/heat-and-cold-illness-in-travelers.html) for the conditions and be prepared in the event of changes.

Dress for the occasion. If appropriate, wear bright, recognizable clothing so people can find you in the event of an emergency. Avoid wearing long, flowing clothes or jewelry that can get caught or tangled. Wear comfortable shoes and ensure that laces remain tied.

Drink plenty of fluids.

Always carry identification on your person.

Designate a meeting place for yourself and your travel companions in the event you are separated.

Stay safe in crowds.

- Note the location of exits and medical assistance or first aid stations.
- Remain toward the edges of crowds or in less crowded spaces.
- Avoid trip or fall hazards, such as trash, potholes, etc.
- Stand on level, dry ground.
- Walk at the same speed as the rest of the crowd.
- If children are with you, always ensure they have enough space.

## Acknowledgements

The following authors contributed to the previous version of this chapter: Joanna Gaines.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Gautret, P., Angelo, K. M., Asgeirsson, H., Duvignaud, A., van Genderen, P. J. J., Bottieau, E., … GeoSentinel Network (2019). International mass gatherings and travel-associated illness: A GeoSentinel cross-sectional, observational study. Travel Medicine and Infectious Disease, 32, 1–5. 10.1016/j.tmaid.2019.101504
• Memish, Z. A., Steffen, R., White, P., Dar, O., Azhar, E. I., Sharma, A., & Zumla, A. (2019). Mass gatherings medicine: Public health issues arising from mass gathering religious and sporting events. Lancet, 393(10185), 2073–2084. https://www.thelancet.com/journals/lancet/article/PIIS0140-6736%2819%2930501-X/fulltext 31106753
• Ranse, J., Beckwith, D., Khan, A., Yezli, S., Hertelendy, A. J., Hutton, A., & Zimmerman, P. A. (2021). Novel respiratory viruses in the context of mass-gathering events: A systematic review to inform event planning from a health perspective. Prehospital and Disaster Medicine, 36(5), 599–610. 10.1017/S1049023X21000662 34261546
• Tavan, A., Tafti, A. D., Nekoie-Moghadam, M., Ehrampoush, M., Vafaei Nasab, M. R., Tavangar, H., & Fallahzadeh, H. (2019). Risks threatening the health of people participating in mass gatherings: A systematic review. Journal of Education and Health Promotion, 8, 209. 10.4103/jehp.jehp_214_19 31807599
• World Health Organization. (2015). Public health for mass gatherings: Key considerations. https://www.who.int/publications/i/item/public-health-for-mass-gatherings-key-considerations