# Template Letters

## Traveling Abroad with Medication(s)

[Healthcare Professional's Letterhead]

[Date]

To whom it may concern,

This letter serves to certify that [Patient's Full Name], [Date of Birth], is under my care and requires the following medications for their health condition(s) during travel:

[Medication Name]: [Dosage or Strength, Frequency, and Route of Administration]

[Medication Name]: [Dosage or Strength, Frequency, and Route of Administration]

[Medication Name]: [Dosage or Strength, Frequency, and Route of Administration]

[Patient's Full Name] has been diagnosed with a medical condition (or conditions) for which these medications are essential to manage symptoms and maintain health stability. The aforementioned medications have been prescribed based on thorough medical evaluation and are crucial for my patient to maintain their health while traveling.

It is important to note that some of these medications may be restricted or prohibited in certain countries. Therefore, I kindly request that my patient be allowed to carry these medications with them during travel without any restriction or interference.

Please do not hesitate to reach me at the contact information provided below should you require any further clarification or information regarding my patient and their medical condition(s) and required medications.

Thank you for your attention to this matter.

Sincerely,

[Healthcare Professional's Full Name]

[Healthcare Professional's Title/Position]

[Healthcare Professional's Contact Information]

## Yellow Fever Vaccine Waiver

[Healthcare Professional's Letterhead]

[Date]

To whom it may concern,

This letter is to certify that [Patient's Full Name], [Date of Birth], is under my care and has a medical contraindication to receive the yellow fever vaccine.

I have performed a thorough medical evaluation of this patient. Based on their medical history and current health status, administering the yellow fever vaccine poses significant risks to their health and well-being. Therefore, I strongly advise against administering the yellow fever vaccine.

I kindly request that this traveler be granted entry into your country without the yellow fever vaccine requirement. Please do not hesitate to reach me at the contact information provided below should you require any further clarification or information regarding my patient and their medical condition.

Thank you for your attention to this matter.

Sincerely,

[Healthcare Professional's Full Name]

[Healthcare Professional's Title/Position]

[Healthcare Professional's Contact Information]

## Disclaimer

Letters created using this template may not be accepted by every international authority.