# Japanese Encephalitis

This image shows microscopic Japanese Encephalitis virus as blue, green, and gray colored spheres.

## Introduction

Infectious agent | Japanese encephalitis (JE) virus
Endemicity | Asia and parts of the western Pacific
Traveler categories at greatest risk for exposure and infection | - Long-term travelers and expatriates; - Persons living in or traveling to rural areas
Prevention methods | - Avoid mosquito bites; - Japanese encephalitis is a vaccine-preventable disease
Diagnostic support | State health department; or contact CDC’s Division of Vector-Borne Diseases, Arboviral Diseases Branch (https://www.cdc.gov/vector-borne-diseases/php/laboratories/submitting-arboviral-specimens.html) (970-221-6400)

## Infectious agent

Japanese encephalitis (JE) virus is a single-stranded RNA virus that belongs to the genus Flavivirus and is closely related to dengue, West Nile, and St. Louis encephalitis viruses.

## Transmission

JE virus is transmitted to humans through the bite of an infected mosquito, primarily Culex species. The virus is maintained in an enzootic cycle between mosquitoes and amplifying vertebrate hosts, primarily pigs and wading birds. Humans are incidental or dead-end hosts because they usually do not develop a level or duration of viremia sufficient to infect mosquitoes. Other documented, but rare, modes of transmission include through blood transfusion, laboratory exposure, organ transplantation, and transplacental transmission.

## Epidemiology

JE virus is the most common vaccine-preventable cause of encephalitis in Asia, occurring throughout most of Asia and parts of the western Pacific. The area of transmission of JE virus has expanded in recent years, most notably in Australia, with widespread areas of transmission detected during 2021–2022.

Transmission of JE virus principally occurs in rural agricultural areas, often associated with rice cultivation and flood irrigation. In some areas of Asia, these ecologic conditions can occur near, or occasionally within, urban centers. In temperate areas of Asia, transmission is seasonal, and human disease usually peaks in summer and fall. In the subtropics and tropics, seasonal transmission varies with monsoon rains and irrigation practices and might be prolonged or even occur year-round.

In endemic countries, where adults have acquired immunity through natural infection, JE is primarily a disease of children. However, travel-associated JE can occur among people of any age. For most travelers to Asia, the risk for JE is extremely low but varies based on travel duration, season, location, activities, and accommodations.

Before 1973, over 300 cases of JE were reported among soldiers from the United States, the United Kingdom, Australia, and Russia. During 1973–2022, 90 JE cases among travelers or expatriates from non-endemic countries were reported in the literature or to CDC. Since 1993, when a JE vaccine became available in the United States, only 16 JE cases among U.S. travelers have been reported to CDC (1993–2024).

The overall incidence of JE among people from non-endemic countries traveling to Asia is estimated to be <1 case per 1 million travelers. However, expatriates and travelers who stay for prolonged periods in rural areas with active JE virus transmission might be at similar risk as the susceptible pediatric resident population, which is 6–11 cases per 100,000 children per year. Travelers, even those on brief trips, might be at increased risk if they have extensive outdoor or nighttime exposure in rural areas during periods of active transmission. Shorter-term (e.g., <1 month) travelers whose visits are restricted to major urban areas are at minimal risk for JE. In some endemic areas, few human cases occur among residents because of immunization or natural immunity among older people, but JE virus is still maintained locally in an enzootic cycle between animals and mosquitoes. Therefore, susceptible visitors could be at risk for infection.

## Clinical presentation

Most human infections with JE virus are asymptomatic; <1% of people infected with JE virus develop neurologic disease. Acute encephalitis is the most recognized clinical manifestation of JE virus infection. Milder forms of disease (e.g., aseptic meningitis, undifferentiated febrile illness) also can occur. The incubation period is 5–15 days. Illness usually begins with fever, headache, and vomiting. Mental status changes, focal neurologic deficits, generalized weakness, and movement disorders might develop over the next few days. The classical description of JE includes a parkinsonian syndrome with mask-like facies, tremor, cogwheel rigidity, and choreoathetoid movements. Acute flaccid paralysis, with clinical and pathological features like those of poliomyelitis, also has been associated with JE virus infection. Seizures are common, especially among children. The case-fatality rate for patients with encephalitis is approximately 20–30%. Among survivors, 30–50% have serious neurologic, cognitive, or psychiatric sequelae.

Common clinical laboratory findings include a moderate leukocytosis as well as mild anemia and hyponatremia. Cerebrospinal fluid (CSF) typically has a mild to moderate pleocytosis with a lymphocytic predominance, slightly elevated protein, and normal ratio of CSF to plasma glucose.

## Diagnosis

Healthcare professionals should suspect JE in a patient with evidence of a neurologic infection (e.g., encephalitis, meningitis, acute flaccid paralysis) who recently traveled to or resided in an endemic country in Asia or the western Pacific. Laboratory diagnosis of JE virus infection should be performed using a JE virus-specific IgM-capture ELISA on CSF or serum. JE virus-specific IgM can be detected in the CSF of most patients ≥4 days after symptom onset and in serum ≥7 days after symptom onset.

Plaque reduction neutralization tests can be performed to confirm the presence of JE virus-specific neutralizing antibodies and to discriminate between cross-reacting antibodies from closely related flaviviruses (e.g., dengue virus, West Nile virus). A ≥4-fold rise in JE virus-specific neutralizing antibodies between acute- and convalescent-phase serum specimens can be used to confirm recent infection. When interpreting laboratory results, healthcare professionals must consider vaccination history, date of symptom onset, and information regarding other flaviviruses known to circulate in the geographic area that might cross-react in serologic assays.

Humans have low levels of transient viremia and usually have neutralizing antibodies by the time distinctive clinical symptoms are recognized. Virus isolation and nucleic acid amplification tests are insensitive in detecting JE virus or viral RNA in blood or CSF and should not routinely be used but might be useful for diagnosing illness in immunocompromised persons. Contact the state or local health department or CDC’s Arboviral Diseases Branch, Division of Vector-Borne Diseases (970-221-6400) for assistance with diagnostic testing. See instructions for submitting CSF and serum specimens (https://www.cdc.gov/vector-borne-diseases/php/laboratories/submitting-arboviral-specimens.html) to CDC for testing.

## Treatment

No specific antiviral treatment for JE is available; therapy consists of supportive care and management of complications.

## Prevention

### Personal protective measures

Travelers can best prevent mosquito-borne diseases, including JE, by avoiding mosquito bites (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html).

### Vaccine

One JE vaccine is licensed and available in the United States, an inactivated Vero cell culture-derived vaccine, IXIARO, manufactured by Valneva Austria GmbH. IXIARO was approved in March 2009 for use in people aged ≥17 years, and in May 2013 for use in children aged 2 through 16 years. Other inactivated and live attenuated JE vaccines are manufactured and used in other countries but are not licensed for use in the United States.

#### Indications for travelers

Based on each traveler’s planned itinerary, assess the risks for mosquito exposure and JE virus infection and discuss ways to reduce these risks. Advise all travelers going to JE-endemic countries of the importance of personal protective measures to reduce the risk for mosquito bites. The decision whether to vaccinate should be individualized and should include consideration of the risks related to the specific travel itinerary, likelihood of future travel to JE-endemic countries, the high rate of death and disability when JE occurs, availability of an effective vaccine, the possibility but low probability of serious adverse events after immunization, and the traveler’s personal perception and tolerance of risk.

Travel location, duration, activities, accommodations, and seasonal patterns of disease in the areas to be visited each influence risk for exposure. Interpret the data in Table 4.7.1 cautiously because JE virus transmission activity varies within countries and from year to year and surveillance data are often incomplete. Additional information on factors that increase risk is provided in Japanese encephalitis vaccine: Recommendations of the Advisory Committee on Immunization Practices (https://www.cdc.gov/mmwr/volumes/68/rr/rr6802a1.htm).

The Advisory Committee on Immunization Practices (ACIP) recommends JE vaccine for people moving to a JE-endemic country, longer-term (e.g., ≥1 month) travelers to JE-endemic areas, and frequent travelers to JE-endemic areas. Consider JE vaccine for shorter-term (e.g., <1 month) travelers with an increased risk for JE based on planned travel duration, season, location, activities, and accommodations. In addition, consider vaccination for travelers going to JE-endemic areas but who are uncertain of specific destinations, activities, or duration of travel.

ACIP does not recommend JE vaccine for travelers with very low-risk itineraries (e.g., shorter-term travel limited to urban areas, travel that occurs outside a well-defined JE virus transmission season).

Table 4.7.1 Risk areas and transmission season for Japanese encephalitis, by destination^1,2,3^

Country | Risk Areas | Transmission Season | Comments
Australia | Outer Torres Strait Islands, Tiwi Islands, and mainland Australia | Most cases reported November–April | Prior to 2021, only 5 cases reported, including from Outer Torres Strait Islands and Far North Queensland (1995–1998); In 2021–2022, 45 cases reported from widespread areas, with outbreak focused in rural areas surrounding Murray River; no further cases reported in 2023 but cases reported again from December 2024; Most travelers at very low risk as no transmission risk in main tourist areas; vaccination recommended for longer-term (i.e., ≥1 month) travel to key risk areas of Outer Torres Strait Islands and Murray River region
Bangladesh | Widespread | Year-round; Most cases reported July–November | Disease incidence is greatest in northwest Bangladesh
Bhutan | Presumed widespread in non-mountainous areas | Unknown | Risk likely greatest in southern districts that share similar ecologic conditions with bordering JE-endemic states of India
Brunei Darussalam | Presumed widespread | Unknown | Limited data, but outbreak reported in 2013; Proximity to Sarawak, Malaysia, suggests ongoing transmission likely
Burma (Myanmar) | Widespread | Year-round; Most cases reported May–September | Greatest risk in delta and lowland areas
Cambodia | Widespread | Year-round; Peak season May–October | Cases reported from most provinces, so transmission likely countrywide
China | All provinces except Qinghai | Peak season June–October
India | Andhra Pradesh, Arunachal Pradesh, Assam, Bihar, Goa, Haryana, Himachal Pradesh, Jharkhand, Karnataka, Kerala, Madhya Pradesh, Maharashtra, Manipur, Meghalaya, Nagaland, Odisha, Punjab, Tamil Nadu, Telangana, Tripura, Uttar Pradesh, Uttarakhand, West Bengal | Peak season May–November, especially in northern India; season can be extended or year-round in some areas, especially in southern India
Indonesia | Widespread | Year-round; Peak season varies by island | Cases reported from many islands, including Bali, Java, Kalimantan, Nusa Tenggara, Papua, Sumatra; transmission likely on all islands; several cases reported among travelers to Bali in recent years
Japan | All islands | June–October | Rare sporadic cases reported from all islands except Hokkaido; enzootic transmission without reported human cases on Hokkaido
Laos | Widespread | Year-round; Peak season June–September
Malaysia | Widespread | Year-round; Peak season in Sarawak is October–December | Much higher rates of disease reported from Sarawak than peninsular Malaysia
Nepal | Southern lowlands (Terai), some hill and mountain districts | Peak season June–October | Highest rates of disease reported from southern lowlands (Terai); vaccine not routinely recommended for those trekking in high-elevation areas
North Korea | Presumed widespread | Unknown; Proximity to South Korea suggests peak transmission May–November
Pakistan | Unknown | Unknown | Very limited data; Previous case report and serosurvey data suggest transmission possible at least in Sindh Province
Papua New Guinea | Widespread | Presumed year-round | Sporadic cases reported from Western Province; Serologic evidence of disease from Gulf and Southern Highland Provinces; One case reported from near Port Moresby; Transmission likely countrywide
Philippines | Widespread | Year-round; Peak season April–August | Human, animal, and mosquito studies indicate transmission in at least 32 provinces; Transmission likely on all islands
Russia | Primorsky Krai | June–September | Cases previously reported from Primorsky Krai but no recent reports; Vaccine not routinely recommended
Singapore | Presumed in very focal areas | Year-round | Very rare sporadic cases reported; Vaccine not routinely recommended
South Korea | Widespread | May–November
Sri Lanka | Widespread, except in mountainous areas | Year-round; Peak season November–February
Taiwan | Widespread | Peak season May–October
Thailand | Widespread | Year-round; Peak season May–October, especially northern Thailand | Highest rates of disease reported from Chiang Mai Valley; Several traveler cases reported in recent years from resort and coastal areas of southern Thailand
Timor-Leste | Presumed widespread | No data; Proximity to West Timor suggests year-round transmission
Vietnam | Widespread | Year-round; Peak season May–October, especially northern Vietnam

Notes

Abbreviation: JE, Japanese encephalitis.

1 When making decisions on vaccination, consider destination and transmission season in association with travel duration and activities.

2 Data are based on published and unpublished reports. Perform risk assessments cautiously; risk can vary within areas and from year to year, and surveillance data regarding human cases and JE virus transmission are often incomplete. In some endemic areas, human cases among residents are limited because of vaccination or natural immunity among older people. Because JE virus is maintained in an enzootic cycle between animals and mosquitoes, susceptible visitors to these areas still might be at risk for infection.

3 Outbreaks previously occurred in the Western Pacific Islands of Guam (1947–1948) and Saipan (1990), but these islands are no longer considered risk areas and are not included in the table.

#### Administration

The primary vaccination dose and schedule for IXIARO varies by age (Table 4.7.2). To administer a 0.25 mL dose, expel and discard half of the volume from the 0.5 mL prefilled syringe by pushing the plunger stopper up to the edge of the red line on the syringe barrel before injection. For all age groups, the 2-dose series should be completed ≥1 week before travel.

Table 4.7.2 Administration information for the inactivated Vero cell culture-derived Japanese encephalitis vaccine, IXIARO

Age | Dose | Route | Schedule | Booster^1^
2 months–2 years | 0.25 mL | IM | 0, 28 days | ≥1 year after primary series
3–17 years | 0.5 mL | IM | 0, 28 days | ≥1 year after primary series
18–65 years | 0.5 mL | IM | 0, 7–28 days | ≥1 year after primary series
>65 years | 0.5 mL | IM | 0, 28 days | ≥1 year after primary series

Notes

1 Administer a booster when potential for Japanese encephalitis virus exposure continues (e.g., repeated travel to endemic areas).

Abbreviations: IM, intramuscular; mL, milliliter.

#### Booster doses

A booster dose (third dose) should be given at ≥1 year after completion of the primary IXIARO series if ongoing exposure or re-exposure to JE virus is expected. A study showed that at approximately 6 years after a booster dose, 96% of persons were still protected.

Limited data are available on the use of IXIARO as a booster dose after a primary series with the mouse brain-derived inactivated JE vaccine. Three studies have been conducted, two in U.S. military personnel and the other at two travel clinics in Europe. Results indicated that among adults who had previously received at least a primary series of mouse brain-derived inactivated JE vaccine, a single dose of IXIARO provided good protection through 12–23 months.

#### Safety and adverse reactions

Among adults, the most common local reactions are pain and tenderness, reported in about one-third of adults after the first or second dose, and the most common systemic reactions are headache (approximately 28%) and myalgia (approximately 16%). In children, the most common systemic reaction is fever, with higher rates (>20%) in children aged 2 months to 2 years compared with older children and adolescents. Serious adverse events are reported only rarely.

#### Precautions and contraindications

A severe allergic reaction after a previous dose of IXIARO or any other JE vaccine, or to any component of IXIARO, is a contraindication to administration of IXIARO. IXIARO contains protamine sulfate, a compound known to cause hypersensitivity reactions in some people.

No studies of IXIARO in pregnant women have been conducted. Pregnancy is a precaution against the use of IXIARO and, in most instances, healthcare professionals should defer vaccinating pregnant women. However, pregnant women who cannot delay travel should be vaccinated when the risk for JE virus infection outweighs the theoretical risk from immunization.

## Acknowledgments

The following author contributed to the previous version of this chapter: Marc Fischer.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Deshpande, B. R., Rao, S. R., Jentes, E. S., Hills, S. L., Fischer, M., Gershman, M. D., Brunette, G. W., Ryan, E. T., LaRocque, R. C., The Global TravEpiNet Consortium. (2014). Use of Japanese encephalitis vaccine in U.S. travel medicine practices in Global TravEpiNet. The American Journal of Tropical Medicine and Hygiene, 91(4), 694–698. 10.4269/ajtmh.14-0062 25070999
• Halstead, S. B., Hills, S. L., Marfin, A. A., & Solomon, T. (2023). Plotkin’s Vaccines: Japanese encephalitis (8th ed., pp. 577–607). Elsevier
• Hills, S. L., Walter, E. B., Atmar, R. L., Fischer, M., & ACIP Japanese Encephalitis Vaccine Work Group. (2019). Japanese encephalitis vaccine: Recommendations of the Advisory Committee on Immunization Practices. MMWR: Morbidity and Mortality Weekly Report, 68(2), 1–33. https://www.cdc.gov/mmwr/volumes/68/rr/rr6802a1.htm?s_cid=rr6802a1_w 30629574
• Hills, S. L., Wong, J. M., & Staples, J. E. (2023). Arboviral vaccines for use in pregnant travelers. Travel Medicine and Infectious Disease, 55, 1–8. https://www.sciencedirect.com/science/article/pii/S1477893923000844
• Janatpour, Z. C., Boatwright, M. A., Yousif, S. M., Bonilla, M. F., Fitzpatrick, K. A., Hills, S. L., & Decker, C. F. (2023). Japanese encephalitis in a U.S. traveler returning from Vietnam, 2022. Travel Medicine and Infectious Disease, 52, 1–3. https://www.sciencedirect.com/science/article/pii/S1477893922002824
• Jelinek, T., Burchard, G. D., Dieckmann, S., Bühler, S., Paulke-Korinek, M., Nothdurft, H. D., … Pellegrini, M. (2015). Short-term immunogenicity and safety of an accelerated pre-exposure prophylaxis regimen with Japanese encephalitis vaccine in combination with a rabies vaccine: A phase III, multicenter, observer-blind study. Journal of Travel Medicine, 22(4), 225–231. 10.1111/jtm.12210 25997707
• Paulke-Korinek, M., Kollaritsch, H., Kundi, M., Zwazl, I., Seidl-Friedrich, C., & Jelinek, T. (2015). Persistence of antibodies six years after booster vaccination with inactivated vaccine against Japanese encephalitis. Vaccine, 33(30), 3600–3604. https://www.sciencedirect.com/science/article/pii/S0264410X15006891 26036947
• Walker, W. L., Hills, S. L., Miller, E. R., Fischer, M., & Rabe, I. B. (2018). Adverse events following vaccination with an inactivated, Vero cell culture-derived Japanese encephalitis vaccine in the United States, 2012–2016. Vaccine, 36(29), 4369–4374. https://www.sciencedirect.com/science/article/pii/S0264410X18305218 29891351