# Travelers with HIV

Traveler talking to a healthcare professional.

## Introduction

With many effective antiretroviral therapy (ART) options available to treat human immunodeficiency virus (HIV), people with HIV who take their medications regularly can live long, healthy lives. When considering how to counsel a traveler with HIV, healthcare professionals should first consider a patient’s HIV control and immune status.

- People with well-controlled HIV who are on ART and are regularly engaged in HIV care should feel comfortable traveling—many thousands do so each year.
- Individuals with poorly controlled HIV (i.e., viral load is not suppressed) or advanced HIV (CD4 cell count <200 cells/mm^3^, a history of an acquired immunodeficiency syndrome (AIDS)-defining illness without subsequent immune reconstitution, or current clinical manifestations of symptomatic HIV), particularly those who are newly diagnosed and treatment naïve, may face increased infectious disease risks when traveling.

Recommend to patients with advanced HIV to delay travel if possible pending immune reconstitution and, ideally, viral suppression to minimize the risk of infectious diseases and immune reconstitution inflammatory syndrome during travel. Additionally, healthcare professionals should be aware of general considerations unique to travelers with HIV and be prepared to address them with patients.

## History of HIV-related travel restrictions

Since the earliest years of the HIV epidemic, countries have implemented travel restrictions for travelers with HIV. Travel restrictions increased significantly following the approval of the first HIV antibody test, which enabled screening of travelers. In 1987, the United States added HIV to its list of “dangerous contagious diseases” and instituted a travel ban for all travelers with HIV. Disclosure of HIV status became mandatory for temporary visitors, and HIV testing was instituted for persons applying for permanent residence. This decision led to widespread protest and criticism that the decision was not supported by public health principles. In 2004, the Joint United Nations Programme on HIV/AIDS (UNAIDS) and the International Organization for Migration released a joint statement declaring that HIV-related travel restrictions have no public health justification. Following the removal of regulatory language about travel and immigration restrictions by Congress in 2008, President Barack Obama rescinded all HIV-related travel restrictions in 2010.

## Current state of HIV-related travel restrictions

Today, approximately 50 countries still require HIV testing or restrict entry, stay, or residence based on HIV status. Healthcare professionals should encourage travelers to be aware of the laws and policies in countries they plan to visit. Table 2.1.1 lists countries that may deport a traveler if that person is found to have HIV. Additional testing requirements or travel restrictions may apply for short- or long-term stays. Non-legal barriers, such as employer policies or lack of protections for the confidentiality of one’s HIV status, may also affect travel. For those planning long-term stays, often classified as more than 90 days or requiring a residency or work permit, medical documentation (including HIV status) may be required prior to entry, whereas such a requirement is not common for short business or tourist stays.

For more information on entry and residence restrictions, consult these additional resources:

- Positive Destinations (https://www.positivedestinations.info/countries-database/)
- UNAIDS HIV-related travel restrictions (https://travelrestrictions.unaids.org/)
- Additionally, U.S. citizens and residents may contact the U.S. Embassy (https://www.usembassy.gov/) or consulate in the country of travel.

Table 2.1.1 Countries that may deport a traveler if they are found to have HIV^1^

Bahrain
Brunei
Cook Islands
Egypt
Iraq
Jordan
Kuwait
Lebanon
Malaysia
North Korea
Oman
Qatar
Russia
Saudi Arabia
Singapore
Solomon Islands
Sudan
Syria
Turkmenistan
United Arab Emirates
Yemen

Notes

1 This list of countries was developed using the following sources: (1) Positive Destinations (https://www.positivedestinations.info/countries-database/) and (2) UNAIDS HIV-related travel restrictions (https://travelrestrictions.unaids.org/). Countries presented in this list may change; refer to the online sources for the latest information.

## Tips for travelers with HIV

Instruct travelers to carry their HIV medications (and all other medications) in their original packaging with labels that identify the medication, dosing, and patient information. Travelers should bring at least a few extra days’ supply of their HIV medications. These medications and any other necessary medical supplies should be kept in the traveler’s carry-on luggage whenever possible. See the Travel Health Kits (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travel-health-kits.html) chapter for additional information about suggested items to bring. Additionally, provide the traveler with an official letter that outlines medications prescribed and any required medical equipment. To prevent disclosure of the patient’s HIV status, healthcare professionals may consider documenting that the ART regimen is prescribed for a medical condition but not specifically stating that it is for HIV treatment.

Encourage travelers to review their health insurance coverage to understand whether their policy covers medical care outside of the United States. Travelers may wish to consider supplemental travel health insurance and medical evacuation coverage (https://www.cdc.gov/yellow-book/hcp/health-care-abroad/travel-insurance.html). Advise travelers to carry a copy of their insurance policy card and copies of claim forms with them. See the Travelers with Chronic Illnesses (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/travelers-with-chronic-illnesses.html) chapter for more information.

## Considerations for long-term travel

When traveling for an extended period, travelers should maintain an adequate supply of HIV medications. Counsel the traveler about the importance of identifying a location at their destination where the individual can access HIV care and potentially receive medications, if needed. Healthcare professionals might also consider increasing the amount of medication in a prescription (e.g., from a 30-day to 90-day supply) in advance of extended travel. Travelers should be aware that countries may restrict the quantity of medicine imported (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/traveling-with-prohibited-or-restricted-medications.html). U.S. citizens and residents may contact the U.S. country embassy or consulate (https://www.usembassy.gov/) in the country of travel for more information regarding medication restrictions.

## Travel vaccines

For travelers with HIV, travel planning should begin several months ahead of departure to allow sufficient time for any necessary immunizations. Generally, immunizations are most effective in asymptomatic persons with undetectable viral loads and restored CD4 cell counts.

Vaccines for travelers, including those with HIV (Table 2.1.2), can generally be separated into three categories:

1. Routine vaccines (e.g., measles, mumps, and rubella)
2. Recommended vaccines based on travel destination and activities (e.g., Japanese encephalitis or rabies)
3. Required vaccines for entry (e.g., yellow fever).

Inactivated vaccines are generally safe for people with HIV. Some live vaccines have sufficient safety data to recommend their use in people with HIV who have a CD4 cell count ≥200 cells/mm^3^. However, live replicating vaccines should not be given to individuals with advanced HIV. Live vaccines include the following:

- Cholera
- Ebola
- Live attenuated influenza
- Measles, mumps, rubella
- Monkeypox (ACAM-2000; however, JYNNEOS is replication-incompetent and therefore may be given to patients with HIV)
- Typhoid (Ty21a)
- Varicella
- Yellow fever

For some vaccines, antibody titers should be checked following vaccine administration to ensure adequate immune response (e.g., hepatitis A and B vaccines). Some vaccines have not specifically been studied in people with HIV; this information is noted in Table 2.1.2.

If a person has a contraindication to yellow fever vaccination and cannot change travel plans, provide them a medical waiver and emphasize the importance of avoiding mosquito bites (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html). Refer to the Yellow Fever (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/yellow-fever.html) chapter for information on how to complete the medical waiver. A sample waiver can be found in Appendix Template Letter 2: Yellow Fever Vaccine Waiver (https://www.cdc.gov/yellow-book/hcp/template-letters/index.html#cdc_report_pub_study_section_2-yellow-fever-vaccine-waiver).

For additional details about vaccine schedules and considerations, refer to the Vaccination and Immunoprophylaxis—General Principles (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/vaccination-and-immunoprophylaxis-general-principles.html) chapter. The annual immunization schedules, which are recommended by the Advisory Committee on Immunization Practices (ACIP) and approved by CDC, also summarize important vaccine recommendations for persons with HIV. Refer to these schedules (https://www.cdc.gov/vaccines/hcp/imz-schedules/index.html) when counseling patients with HIV on recommended vaccines.

Table 2.1.2 Immunizations for travelers with HIV

| HIV Immune Status
| ≥200 cells/mm^3^ | <200 cells/mm^3^
Routine Immunizations
COVID-19^1^ | Recommended | Recommended
Hepatitis A^2^ | Recommended | Recommended
Hepatitis B^3^ | Recommended | Recommended
Haemophilus influenzae type b (Hib)^4^ | Use as indicated | Use as indicated
Human papillomavirus (HPV)^5^ | Use as indicated | Use as indicated
Influenza, inactivated or recombinant | Recommended | Recommended
Influenza, live attenuated | Contraindicated | Contraindicated
Measles, mumps, and rubella (MMR)^6^ | Recommended | Contraindicated
Meningococcus serogroup A, C, W, Y (MenACWY) | Recommended | Recommended
Meningococcus serogroup B (MenB) | Use as indicated | Use as indicated
Monkeypox (JYNNEOS)^7^ | Use as indicated | Use as indicated
Monkeypox (ACAM2000)^7^ | Contraindicated | Contraindicated
Pneumococcal (PCV20, PCV15) | Recommended | Recommended
Pneumococcal polysaccharide (PPSV23)^8^ | Use as indicated | Use as indicated
Polio (IPV) | Use as indicated | Use as indicated
Respiratory syncytial virus (RSV)^9^ | Use as indicated | Use as indicated
Tetanus, diphtheria, and pertussis (DTaP, Td, Tdap) | Use as indicated | Use as indicated
Varicella (VAR)^10^ | Use as indicated | Contraindicated
Zoster recombinant (RZV)^11^ | Recommended | Recommended
Immunizations for travel
Chikungunya (IXCHIQ) | No data | Contraindicated
Cholera (CVD 103-HgR)^12^ | No data | No data
Ebola^13^ | Consider | Consider
Japanese encephalitis (JE-VC)^14^ | No data | No data
Rabies (HDCV, PCECV)^15^ | Use as indicated | Other considerations
Tick-borne encephalitis (TICOVAC)^16^ | No data | No data
Typhoid (Ty21a) | Contraindicated | Contraindicated
Typhoid (Vi) | Use as indicated | Use as indicated
Yellow fever^17^ | Precaution | Contraindicated

Notes

1 Please see Staying Up to Date with COVID-19 Vaccines (https://www.cdc.gov/covid/vaccines/stay-up-to-date.html) for the most up-to-date COVID-19 vaccine recommendations.

2 Hepatitis A vaccination is indicated for all people with HIV. Post-vaccination serologic testing should be performed ≥1 month after completion of the vaccine series.

3 Hepatitis B vaccination is indicated for all persons aged <60 years and adults aged ≥60 with risk factors for hepatitis B (including HIV infection). Post-vaccination serologic testing should be performed 1 to 2 months after completion of the vaccine series.

4 Hib vaccine is not routinely recommended for patients with HIV. However, if a patient with HIV has another medical condition that would warrant Hib vaccination (like anatomic or functional asplenia), then they may receive Hib vaccine for that other condition.

5 HPV vaccination is recommended for persons aged 9–26 years. For some adults aged 27–45 who are not adequately vaccinated, shared clinical decision-making is recommended.

6 MMR vaccination is recommended for all people with HIV aged ≥1 year with no evidence of measles, mumps, and rubella immunity, and who do not have severe immunosuppression. Absence of severe immunosuppression is defined as CD4 cell count ≥15% for ≥6 months for children aged ≤5 years, or CD4 ≥15% and CD4 cell count ≥200 cells/mm^3^ for ≥6 months for people aged >5 years.

7 Monkeypox vaccination is recommended for people with HIV who have had recent (or anticipate potential) monkeypox exposure. JYNNEOS is considered safe in people with HIV, although effectiveness may be lower among severely immunocompromised individuals. ACAM2000 should not be used in people with HIV.

8 If PCV15 is administered, patient should receive 1 dose of PPSV23 afterward.

9 Regardless of HIV status, RSV vaccine is recommended for persons 75 years of age and older. RSV vaccine is also recommended for adults 60–74 years of age who are at increased risk of severe RSV disease, which includes persons with moderate or severe immunocompromise. Additionally, based on RSV seasonality, RSV vaccine is recommended for pregnant women at 32–36 weeks gestation to protect the newborn from RSV infection.

10 Varicella vaccine should not be administered to people who have cellular immunodeficiencies, but people with impaired humoral immunity (including congenital or acquired hypoglobulinemia or dysglobulinemia) can be vaccinated. HIV-positive adults with CD4 cell counts ≥200 cells/mm^3^ can receive 2 doses of vaccine spaced at 3-month intervals. VariZIG (varicella zoster–specific immune globulin) is recommended for people exposed to varicella or herpes zoster if they do not have evidence of varicella immunity and have contraindications to vaccination.

11 RZV is recommended for all people with HIV aged ≥18 years old.

12 No safety or efficacy data exist regarding use of the current formulation of CVD 103-HgR (Vaxchora) vaccine in people with HIV. Limited data from an older formulation of CVD 103-HgR suggest no association between the vaccine and serious or systemic adverse events, and slightly lower immunogenicity of the vaccine in people with HIV.

13 Safety and efficacy have not been adequately assessed in immunocompromised adults. Providers should weigh the risk associated with vaccination against the risk for Ebola disease in people with HIV.

14 No safety or efficacy data exist regarding the use of JE-VC (IXIARO) in immunocompromised people. In general, inactivated vaccines can be administered safely to people with altered immunocompetence, using the usual doses and schedules, but the effectiveness might be suboptimal. The inactivated, Vero cell-derived Japanese encephalitis vaccine, IXIARO, is the only Japanese encephalitis vaccine available in the United States; other types of Japanese encephalitis vaccines, including live vaccines, are available internationally but are not included here.

15 For post-exposure prophylaxis, both vaccine (5 doses at day 0, 3, 7, 14, 28) and immune globulin should be given to immunocompromised people regardless of previous vaccination status.

16 For risk-benefit considerations, see Tick-Borne Encephalitis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/tick-borne-encephalitis.html) chapter.

17 For details, see Yellow Fever (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/yellow-fever.html) chapter. Yellow fever (YF) vaccination is a precaution for asymptomatic HIV-infected people with CD4 cell count of 200–499 cells/mm^3^. YF vaccination is not a precaution for people with asymptomatic HIV infection and CD4 cell count of ≥500 cells/mm^3^. ACIP also considers YF vaccine contraindicated for patients with symptomatic HIV without AIDS and those with CD4 cell count <200 cells/mm^3^. ACIP guidelines differ from WHO guidelines by specifying that YF vaccine should be administered every 10 years in people with HIV at continued risk for YF.

## Prevention of malaria and other vector-borne pathogens

Pre-travel consultation for people with HIV should include an assessment of travel destinations and risk of exposure to malaria and other vector-borne pathogens in those locations. The risk of malaria and disease severity are increased in people with HIV. This is especially the case for people with advanced HIV. People with HIV who have a low CD4 count and HIV-infected women who are pregnant (or likely to become pregnant), regardless of CD4 count, should consider delaying travel to malaria-endemic areas. If travel cannot be deferred, use of effective malaria prophylaxis, although options are limited in pregnancy (https://www.cdc.gov/yellow-book/hcp/family-travel/pregnant-travelers.html), and precautions to avoid mosquito bites (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html) are essential.

Preventive measures when traveling to malaria-endemic areas (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/malaria.html) include chemoprophylaxis and mosquito-avoidance measures. Healthcare professionals should be aware of potential drug interactions between malaria chemoprophylaxis and common ART regimens (Table 2.1.3). Mosquito avoidance measures include sleeping under insecticide-treated bed nets, the use of DEET (N,N-diethyl-3-methyl-benzamide)-containing repellants, and wearing clothes that cover most of the body. Mosquito-avoidance measures can also prevent exposure to arboviral diseases, including chikungunya, dengue, Japanese encephalitis, yellow fever, and Zika. Used in combination, these preventive measures are highly effective. However, any febrile traveler returning from a malaria-endemic area should be tested for malaria, even if they took chemoprophylaxis.

Table 2.1.3 Drug interactions for common travel medications and antiretroviral therapy regimens^1^

| Antiretroviral Therapy Regimens
Travel Medication | BIC/; TAF/; FTC^2^ | DTG Plus (TAF or TDF) Plus (FTC or 3TC)^2^ | DTG/; 3TC^2^ | DRV/c or DRV/r With (TAF or TDF) Plus (FTC or 3TC)^2,3^ | CAB/RPV^4^
Anti-diarrheal
Bismuth subsalicylate | Potential interaction | Potential interaction | Potential interaction | No known interaction | No known interaction^5^
Diphenoxylate/atropine^6^ | No known interaction | No known interaction | No known interaction | No known interaction | No known interaction
Loperamide | No known interaction | No known interaction | No known interaction | Potential interaction | No known interaction
Malaria prophylaxis
Atovaquone-proguanil | No known interaction | No known interaction | No known interaction | Potential interaction (DRV/r only) | No known interaction
Chloroquine | Potential interaction | No known interaction | No known interaction | Potential weak interaction | Potential interaction
Doxycycline | No known interaction | No known interaction | No known interaction | No known interaction | No known interaction
Hydroxychloroquine | Potential interaction | No known interaction | No known interaction | Potential weak interaction | Potential interaction
Mefloquine | No known interaction | No known interaction | No known interaction | Potential interaction | Potential weak interaction
Primaquine | No known interaction | No known interaction | No known interaction | Potential interaction | Potential weak interaction
Tafenoquine^6^ | No known interaction | Avoid with 3TC^7^ | Avoid^7^ | Avoid with 3TC^7^ | No known interaction
Motion Sickness
Chlorphenamine | No known interaction | No known interaction | No known interaction | Potential weak interaction | No known interaction
Dimenhydrinate^6^ | No known interaction | No known interaction | No known interaction | No known interaction | No known interaction
Diphenhydramine | No known interaction | No known interaction | No known interaction | Potential weak interaction | No known interaction
Meclizine^6^ | No known interaction | No known interaction | No known interaction | No known interaction | No known interaction
Promethazine | No known interaction | No known interaction | No known interaction | Potential weak interaction | Potential weak interaction
Scopolamine | No known interaction | No known interaction | No known interaction | Potential interaction | No known interaction
Sleep Aids
Melatonin | No known interaction | No known interaction | No known interaction | Potential interaction (DRV/r only) | No known interaction
Zolpidem | No known interaction | No known interaction | No known interaction | Potential interaction | No known interaction
Travelers’ Diarrhea
Azithromycin | No known interaction | No known interaction | No known interaction | No known interaction | Potential interaction
Ciprofloxacin | No known interaction | No known interaction | No known interaction | No known interaction | Potential interaction
Levofloxacin | No known interaction | No known interaction | No known interaction | No known interaction | Potential interaction
Rifaximin | No known interaction | No known interaction | No known interaction | No known interaction | No known interaction
Rifamycin^6^ | No known interaction | No known interaction | No known interaction | No known interaction | No known interaction

Notes

Abbreviations: 3TC, lamivudine; BIC, bictegravir; c, cobicistat; CAB, cabotegravir; DRV, darunavir; DTG, dolutegravir; r, ritonavir; RPV, rilpivirine; TAF, tenofovir alafenamide; TDF, tenofovir disoproxil fumarate.

1 Drug interactions were sourced from the University of Liverpool HIV Drug Interactions Checker. When a drug was not listed in this resource, the UpToDate Drug Interactions and Epocrates Interaction Check tools were used, which is denoted by footnote.

2 These ART regimens represent the recommended initial regimens for most people with HIV in the U.S. Department of Health and Human Services Guidelines for the Use of Antiretroviral Agents in Adults and Adolescents with HIV (https://clinicalinfo.hiv.gov/en/guidelines/hiv-clinical-guidelines-adult-and-adolescent-arv/what-start-initial-combination).

3 The DRV-based regimen is a recommended initial regimen specifically for people who have a history of using injectable CAB for pre-exposure prophylaxis and for whom genotype resistance testing (including integrase strand transfer inhibitor resistance) has not yet resulted.

4 This refers to the injectable formulation of CAB/RPV.

5 Although there is no interaction with the injectable formulation of CAB/RPV, there is a potential interaction with the oral formulation of CAB.

6 This medication interaction was sourced from the UpToDate Drug Interactions and Epocrates Interaction Check tools (i.e., the travel medication was not included in the University of Liverpool HIV Drug Interactions Checker).

7 Tafenoquine may increase serum concentration of OCT2 and MATE1/2-K substrates, which include lamivudine. If co-administration cannot be avoided, monitor for lamivudine-related toxicities and consider dosage reduction based on product labeling for lamivudine.

## Foodborne and waterborne illness

People with HIV should take appropriate precautions to avoid food- and waterborne infections (e.g., Campylobacter, Cryptosporidium, Escherichia coli, Giardia, Listeria, Salmonella, and Shigella), some of which can cause chronic or severe disease in people with advanced HIV. Instruct travelers about the importance of proper hand hygiene, including thorough handwashing with soap and water. Provide information on food and beverage precautions (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/food-and-water-precautions-for-travelers.html), such as consuming only boiled, treated, or bottled water in areas without adequate sanitation; only eating foods that are well-cooked and still hot; and avoiding unpasteurized dairy products. Antimicrobial prophylaxis to prevent bacterial enteric illness (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travelers-diarrhea.html) is not routinely recommended.

## Drug interactions with HIV medications

Today’s commonly used ART regimens are generally very well tolerated with fewer drug interactions compared to earlier regimens. However, healthcare professionals should be aware of and advise travelers of interactions (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/medication-and-vaccine-interactions-in-travel-medicine.html) between a patient’s ART and common travel medications. Table 2.1.3 describes drug interactions for common travel medications and ART regimens, including the first-line ART regimens recommended by the U.S. Department of Health and Human Services guidelines. For HIV drug-interaction questions, reference the University of Liverpool HIV Drug Interactions Checker (https://www.hiv-druginteractions.org/checker) page for more information.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Flateau, C., Le Loup, G., & Pialoux, G. (2011). Consequences of HIV infection on malaria and therapeutic implications: A systematic review. The Lancet: Infectious Diseases, 11(7), 541–556. 10.1016/S1473-3099(11)70031-7 21700241
• Gostin, L. O., Cleary, P. D., Mayer, K. H., Brandt, A. M., & Chittenden, E. H. (1990). Screening immigrants and international travelers for the human immunodeficiency virus. The New England Journal of Medicine, 322(24), 1743–1746. 10.1056/NEJM199006143222411 2342541
• International Organization for Migration. (2004). UNAIDS/IOM statement on HIV/AIDS-related travel restrictions. https://www.iom.int/sites/g/files/tmzbdl486/files/jahia/webdav/site/myjahiasite/shared/shared/mainsite/activities/health/UNAIDS_IOM_statement_travel_restrictions.pdf
• National Institutes of Health, Centers for Disease Control and Prevention, HIV Medicine Association, and Infectious Diseases Society of America. Guidelines for the prevention and treatment of opportunistic infections in adults and adolescents with HIV. Clinical Info HIV. https://clinicalinfo.hiv.gov/en/guidelines/hiv-clinical-guidelines-adult-and-adolescent-opportunistic-infections/whats-new. Accessed August 27, 2024