# Travel Health Kits

Traveler holds a packet of medication from a travel health kit.

## Introduction

This chapter will cover potential contents for two types of travel health kits:

1. Basic personal travel health kit
2. Extended kit for a group going to a remote area, including items which may be brought by a licensed medical professional

These contents are suggested items and should be personalized based on several factors, including:

- The availability of local medical care and evacuation
- Itinerary, planned activities, and duration of the trip
- The number of people who may be treated
- The medical expertise in the group
- Space and weight for medical supplies
- How the kit will be carried

## Personal travel health kit

All travelers should bring a personal first aid kit with basic medical supplies that depend on the traveler’s health history and the type of trip. The goal of this travel health kit is to allow management of common minor illnesses and injuries, treatment of recurring problems, and continuing treatment of chronic conditions (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/travelers-with-chronic-illnesses.html). It is common practice for travelers to carry some prescription medications for presumptive prophylaxis and treatment in certain regions; for example, travelers’ diarrhea (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travelers-diarrhea.html), malaria (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/malaria.html), or altitude illness (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/high-altitude-travel-and-altitude-illness.html). Narcotics and psychoactive medications for personal use should be carried in the original prescription container and are limited in many countries to a 30-day supply or less (see Traveling with Prohibited or Restricted Medications (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/traveling-with-prohibited-or-restricted-medications.html)). Store medications and first aid supplies in a durable, water-resistant container and keep it readily accessible during the journey. See Table 1.9.1 for suggested content.

Table 1.9.1 Personal travel health kit

Bandages and Wound Care
Items | Use, Indication, or Comments
Adhesive bandages in various sizes | Minor cuts and scrapes; include waterproof options
Adhesive felt or gel pads | Blister prevention and treatment
Elastic bandage for sprains | 4-inch and 2-inch are most useful; can also use to secure large dressings
Gauze pads and non-stick dressings: 2 × 2 and 4 × 4 inch gauze | To clean and cover larger wounds; regular gauze and ointment create a non-stick dressing
Medical adhesive tape | To secure dressings
Self-adhesive bandage wrap | May be preferable to gauze or elastic wrap
Small bandage scissors | To cut bandages or tape; if in carry-on luggage, TSA permits scissors with blades less than 4 inches from the pivot point
Wound closure strips (“butterfly”) | Requires some expertise; clean wound before attempting to close; can alternatively use pieces of tape

Topical Medicines
Items | Use, Indication, or Comments
Aloe vera gel | Sunburn, thermal burns, generally soothing for skin
Anti-itch lotion | May contain cortisone, antihistamine, moisturizers, or other soothing ingredients
Antifungal cream or powder | Treatment for presumed fungal skin infection or vaginal yeast infection
Antimicrobial ointment | Keeps dressings from sticking to wet scrapes or burns; softens dry, cracking wounds and crusts
Antiseptic wipes or solution | Benzalkonium chloride or alcohol wipes
Hydrocortisone cream | For rashes

Medicines for Common Problems
Items | Use, Indication, or Comments
Acid blockers or antacid; (e.g., omeprazole, famotidine) | If prone to reflux or gastritis
Antihistamines | Allergies and allergic reactions; if using “sedating kinds,” such as diphenhydramine and hydroxyzine, may also be used for sleep or intestinal cramps (age >2 years)
Aspirin, acetaminophen, or ibuprofen | Pain relief, arthritis
Cough drops or throat lozenges; (with benzocaine) | Cough, sore throat, irritation from dry, cold air at altitude
Decongestant tablets or spray; (pseudoephedrine, not phenylephrine) | Nasal congestion, ear pressure when flying
Loperamide | Non-bloody diarrhea (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travelers-diarrhea.html)
Meclizine or scopolamine | Motion sickness (https://www.cdc.gov/yellow-book/hcp/travel-air-sea/motion-sickness.html)
Mild laxative such as; milk of magnesia tablets, stool softener, teas | If prone to constipation
Oral electrolyte solution powder | For rehydration of moderate-severe diarrhea or vomiting (available in low-income countries)

Prescription Medications—Include All Regular Personal Prescription Medications
Items | Use, Indication, or Comments
Acetazolamide and/or dexamethasone | Altitude illness (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/high-altitude-travel-and-altitude-illness.html) prevention and treatment
Albuterol inhaler | If history of asthma or wheezing
Antibiotic for travelers’ diarrhea, if prescribed | Presumptive treatment for moderate to severe travelers’ diarrhea (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travelers-diarrhea.html)
Antibiotic—specific for likely problem | If personal history of recurrent urinary, sinus, skin infections
Epinephrine auto-injector | If history of severe allergic reactions (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/severely-allergic-travelers.html) (anaphylaxis)
Malaria chemoprophylaxis | If traveling to an endemic area (see Malaria) (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/malaria.html)
Needles and syringes | If regularly self-administered injectable medication like insulin (carry copy of prescription)
Spare prescription glasses or contacts

Instruments and Equipment
Items | Use, Indication, or Comments
Digital thermometer | Bring plastic sheaths to use orally or rectally
Headlamp | Helpful for remote areas, power outages, or emergencies
Tweezers | Splinter or tick removal

Documentation (Hard Copy or Digital)
A medical summary stating diagnoses, regular medications (generic, not trade names), and allergies, in case medical care is necessary while traveling
Copy of advanced medical care directive, including DNR information
Electrocardiogram if previously abnormal, history of heart or lung disease, or older than 50 years
Emergency contact card
International Certificate of Vaccination or Prophylaxis (ICVP or Yellow Card)
Travel and healthcare insurance information
Travel-sized first aid manual or guide (Box 1.9.1); need 1 for a group

Preventive Items, as Applicable
Items | Use, Indication, or Comments
Condoms, other barrier precautions, or other contraceptives | See Sex and Travel (https://www.cdc.gov/yellow-book/hcp/travel-for-work-other/sex-and-travel.html)
Exam gloves | Infection control and personal protection
Face mask or N-95 respirator | Respiratory infection protection
Insect repellent | See Mosquitoes, Ticks, and Other Arthropods (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html)
Lip balm with sun protection | For dry, cracked lips
Mosquito net | Malaria and insect bite prevention
Personal hygiene items | Hand sanitizer, disinfectant or wet wipes, facial tissues, menstrual pads or tampons
Sunscreen (SPF 30 or greater) | Zinc oxide cream provides the most complete sun protection (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/sun-exposure-in-travelers.html) for nose, lips, and face
Water purification tablets or device | If clean water will not be available or if using surface water (see Water Disinfection for Travelers (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/water-disinfection-for-travelers.html))

Travel With Children (see Traveling Safely With Infants and Children (https://www.cdc.gov/yellow-book/hcp/family-travel/traveling-safely-with-infants-and-children.html))
Age-appropriate doses and products for malaria prevention, travelers’ diarrhea, and insect repellents
Medication for pain, fever, allergy, with syringe or medicine cup to measure
Safety equipment, including car seat, flotation device, or helmet

Notes

Abbreviations: TSA, U.S. Transportation Security Administration; DNR, do not resuscitate; SPF, sun protection factor.

## Expanded travel health kits

This list includes items to consider for extended remote travel or expedition (https://www.cdc.gov/yellow-book/hcp/travel-for-work-other/adventure-travel.html) in addition to items in the personal kit (Table 1.9.2). No kit will include all these items, and this list is not comprehensive. The traveler assembling the kit should add, substitute, or omit items based on the criteria listed above.

Guides and group leaders with advanced first aid training should begin with contents listed for the personal first aid kit and add items from the expanded kit, according to their level of training and the specific risks of the trip. In addition, they should carry safety and rescue items. Guides and leaders will often need to rely on medical expertise and supplies among the other group members.

In most cases, injectable medications provide little advantage over oral or topical drugs, but they can be added without significant bulk and weight. On the other hand, intravenous fluids are very heavy and bulky.

For certain expeditions or remote group travel, a medical professional may be designated. More often, in the event of illness or injury to a group member, another member of the group volunteers to help under the liability protection of a Good Samaritan. Typical requirements in the United States for acting as a Good Samaritan include:

- There is an emergency
- The provider is not responsible for the injury
- No prearranged duty to treat
- No reward or compensation for services
- No gross negligence

The standard of care provided in a remote location considers resources available, accessibility to a higher level of care, and ultimately what a healthcare professional with similar training would do in a similar situation.

Table 1.9.2 Expanded travel health kit

Bandages and Wound Care
Items | Use, Indication, or Comments
Adhesive tape (cloth-type, athletic) 1–2 inch | Very versatile tape: secure dressings, tape over blisters, tape sprains and sports injuries
Bandage scissors or larger “trauma” scissors | Can use a sharp knife or a pocketknife with small scissors; sewing stores sell small folding scissors; if in carry-on luggage, TSA permits scissors with blades less than 4 inches from the pivot point
Eye pads | Can use folded gauze
Gauze roll (3–4 inch wide) | Hold dressings more securely and comfortably than tape where there is hair, movement, or moisture; for narrower wrap, fold while wrapping
H-shaped adhesive strips (knuckle bandages) or large size (2–3 inch wide) adhesive strips | Convenient but tape and gauze can be used
Hypoallergenic medical tape (½–1 inch) | Easy to remove, does not cause skin irritation
Occlusive dressing | Provides sealed coverage of wounds
Scalpel blade (#15) | Incision and drainage of abscess; minor debridement
Small syringes and needles | For local anesthetic or other injectable medications
Splint (padded, flexible aluminum) | Splint any small to medium-size joint
Splinter forceps | A hypodermic needle can also be used for probing in the superficial skin layer
Suture material, non-absorbable and absorbable | Wound stapler is an alternative but is bulky
Suture set | Needle holder or straight clamp and forceps
Trauma pad (ABD-abdominal pad) | Can use large menstrual pad
Wound closure strips or cyanoacrylate skin adhesives | Hold together edges of small cuts; medical skin adhesives are easy to use but expensive; ethyl-cyanoacrylate (e.g., “super glue”) contains the same substance and may be the only option available

Miscellaneous Equipment
Items | Use, Indication, or Comments
Duct tape | Many uses; wrap some around a rod or tube
Emergency space blanket | An emergency thermal layer or ground tarp for injured or ill person
Exam gloves, non-sterile | Infection control and personal protection
Expandable foam nasal packing or silver nitrate sticks | Nosebleed requiring packing or cautery
First aid references | See Box 1.9.1 for options
Foley catheter (12–14 gauge) | Urinary retention (a true emergency)
Knife or multifunction tool | Standard guide equipment with many uses
Lubricant packets | For some examinations or for placement of foley catheter
Medication envelopes or plastic bags (small) | For providing medication to a group member
Nasal, oral, or supraglottic airway | Maintain airway in unconscious, breathing victim
Note paper and pencil | Recording medical and location information for communication or evacuation; could use phone note
Otoscope
Oxygen saturation fingertip monitor | Small, portable, inexpensive, and provides important information for respiratory problems and altitude illness
Packets of oral rehydration solution (ORS) | Diarrhea, significant dehydration; heat illness
Pocket CPR masks | Masks remove the need to do mouth to mouth resuscitation
Small nasogastric feeding tube | For fluids if severe dehydration
Small syringes and needles | For local anesthetic or other injectable medications
Stethoscope
Tactical or military-style tourniquet | For severe limb trauma with large vessel bleeding
Thermometer | Extended range thermometer to measure for fever or for hypothermia

Diagnostics
Items | Use, Indication, or Comments
Blood pressure cuff
COVID-19 rapid test kits
Fluorescein strips | Aid in diagnosis of corneal abrasion, UV keratitis, corneal ulcer
Pregnancy test kit
Urine dipsticks

Documents
Items | Use, Indication, or Comments
Medical certificates and licenses | For the healthcare professionals in the group
Pertinent medical information of group members | Allergies, medication lists, and active health problems (voluntarily provided)

Topical Medications
Items | Use, Indication, or Comments
Antifungal cream (miconazole, tinidazole, clotrimazole) | Treatment of presumed fungal dermatitis: irritating, itchy, red skin rashes; some products combine with cortisone cream
Benzoin ampule/swabs | Helps tape or moleskin stick to skin; apply to skin, wait 30–60 seconds until sticky, then apply tape
Glucose or dextrose paste | Hypoglycemia; could use honey or sugar under buccal mucosa
Hemorrhoid suppositories or ointment (contain various ingredients: zinc oxide, topical anesthetic, cortisone, phenylephrine) | Pain and itching of hemorrhoids
Permethrin cream 5%, lotion 1% | Treatment of scabies and lice
Temporary dental filling; or zinc oxide eugenol cements | Lost fillings, newly painful cavities, broken teeth
Tincture of iodine (2%) or betadine solution (10%) | Topical disinfectant for cleaning wounds; make a dilute (10:1) betadine solution to use directly on or in a wound but can use full strength on intact skin
Topical ophthalmic anesthetic | Corneal abrasion or removal of foreign body on cornea
Zinc oxide cream | Sun protection and generally soothing cream for irritated skin; the most complete sun protection for nose, lips, face

Prescription Drugs
Items | Use, Indication, or Comments
Bronchodilator inhaler | Asthmatic wheezing brought on by exertion, cold, allergy, smoke, or infection
Diazepam 5 mg | Sedation; also consider an antipsychotic (e.g., haloperidol or olanzapine)
Epinephrine 1 mg/mL self-injecting, ampule, or multi-dose vial | Life-threatening allergic reactions; include even if no known history of severe allergy (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/severely-allergic-travelers.html) or asthma in the group, since an individual may have a new reaction to bee sting or food allergy
Hydrocodone 5 mg or codeine 32 mg; both come combined with acetaminophen/paracetamol | Moderately severe pain; also effective for cough suppression, diarrhea, and abdominal cramps (see Traveling With Prohibited or Restricted Medications (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/traveling-with-prohibited-or-restricted-medications.html))
Injectable diazepam or lorazepam | Intractable seizure; intramuscular as effective as intravenous
Lidocaine 1% injectable | Wound closure with sutures, or incision and drainage
Naloxone | Narcotic overdose, if carrying injectable narcotic or for a group with unfamiliar members (see Substance Use and Substance Use Disorders in Travelers (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/substance-use.html))
Ondansetron 4–8 mg dissolving tablets | Nausea and vomiting
Prednisone 20 mg | Asthma, allergic reactions

Antibiotics and Other Anti-Infection Medication
The antibiotics below are suggested options because they are inexpensive, widely available in many countries, and have multiple overlapping uses. If a parenteral (injectable) antibiotic is desired, consider selecting one that can be given intramuscularly and has broad coverage (e.g., ceftriaxone). One approach is to consider common infections by organ system. For more detailed infectious diseases and antimicrobial considerations, see The Sanford Guide to Antimicrobial Therapy (Box 1.9.1) or the specified Yellow Book chapter below.; Travelers’ diarrhea (see Post-Travel Diarrhea (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-diarrhea.html)): 1st choice azithromycin; 2nd choice ciprofloxacin; Urinary tract infections: 1st choice nitrofurantoin or ciprofloxacin; 2nd choice trimethoprim-sulfamethoxazole; Respiratory infections (see Post-Travel Respiratory Infections (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-respiratory-infections.html)): 1st choice azithromycin, 2nd choice amoxicillin, tetracycline, or amoxicillin/clavulanate; Skin infections (see Post-Travel Dermatologic Conditions (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-dermatologic-conditions.html)): 1st choice cephalexin, 2nd choice dicloxacillin or flucloxacillin, doxycycline, or trimethoprim-sulfamethoxazole; Sexually transmitted infections (see Sex and Travel (https://www.cdc.gov/yellow-book/hcp/travel-for-work-other/sex-and-travel.html)): azithromycin, doxycycline, or ceftriaxone

Additional Anti-Infectives
Items | Use, Indication, or Comments
Fluconazole | Vaginal yeast infection; can also use cream (e.g., clotrimazole, miconazole)
Ophthalmic antibiotic ointment or drops: ofloxacin 0.3% or genoptic | Bacterial conjunctivitis or corneal ulcer
Otic (ear) drops: neomycin, polymyxin b and hydrocortisone solution; ciprofloxacin with dexamethasone | Otitis externa; could use ophthalmic drops but will not contain steroid
Tinidazole, metronidazole | Giardia and other protozoa

Cardiac Medications (Especially if a Group of Older Adults); see Travelers With Chronic Illnesses (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/travelers-with-chronic-illnesses.html)
Items | Use, Indication, or Comments
Aspirin 325 mg | Angina, suspected acute cardiac syndrome
Diltiazem or metoprolol | Blood pressure, angina, rhythm control; may need oral and injectable
Furosemide or bumetanide tablets | Diuresis with congestive heart failure; avoid if sulfonamide allergy
Nitroglycerine tabs, spray, patch or paste | Chest pain of presumed cardiac origin

Specific Environment Additional Considerations: High-altitude (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/high-altitude-travel-and-altitude-illness.html)
Items | Use, Indication, or Comments
Acetazolamide 125 or 250 mg tablets | Prevention and treatment of AMS
Dexamethasone 2 or 4 mg tablets | Prevention and treatment of AMS
Hyperbaric bag | Stabilize serious altitude illness; heavy and bulky, so for major expeditions or larger groups
Nifedipine, sildenafil, or tadalafil | High altitude pulmonary edema
Oxygen saturation monitor | Battery operated, fingertip monitor

Specific Environment Additional Considerations: Jungle and Forest
Items | Use, Indication, or Comments
Artemether-lumefantrine or atovaquone-proguanil | Breakthrough malaria treatment when diagnostics or local care are not available; appropriate malaria chemoprophylaxis is first approach (see Malaria, Reliable Supply (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/malaria.html#heading-pixf9ezm0l) section)
Doxycycline 100 mg | Presumptive treatment of tick-borne rickettsial infections; may also be used for prophylaxis of leptospirosis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/leptospirosis.html) in adults (200 mg orally, weekly) begun 1–2 days before and continuing through the period of exposure
Insect repellent; DEET; IR3535; permethrin | Topical repellents for skin; permethrin is to treat clothing or bed nets (see Mosquitoes, Ticks, and Other Arthropods (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html))
Malaria rapid antigen test kit | Helps determine need for treatment and evacuation (see Malaria, Diagnosis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/malaria.html#heading-rvjepac_lr) section)

Notes

Abbreviations: TSA, U.S. Transportation Security Administration; OR, oral rehydration solution; CPR, cardio-pulmonary resuscitation; UV, ultraviolet; AMS, acute mountain sickness; DEET, N,N-diethyl-meta-toluamide

Box 1.9.1 Travel-sized medical manuals ★

- Auerbach, P. S. Medicine for the outdoors: The essential guide to first aid and medical emergencies. Elsevier Health Sciences.
- Wilkerson, J. A., Moore, E., & Zafren, K., Eds. Medicine for mountaineering & other wilderness activities. Mountaineers Books.
- Wilderness Medical Society and National Safety Council. Wilderness first aid: Emergency care in remote locations. American Academyof Orthopedic Surgeons.
- Forgey, W. W. Wilderness medicine: Beyond first aid. Falcon Press.
- Anderson, C. S., Dallimore, J., Winser, S., & Warrell, D. A. Oxford handbook of expedition and wilderness medicine. Oxford University Press.
- Gilbert, D. N., Boucher, H. W., Saag, M. S., Pavia, A. T., Freedman, D. O., Black, D., … Kim, K. The Sanford guide to antimicrobial therapy (pocket edition). Antimicrobial Therapy.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Brandenburg, W. E., & Locke, B. W. (2017). Mountain medical kits: Epidemiology-based recommendations and analysis of medical supplies carried by mountain climbers in Colorado. Journal of Travel Medicine, 24(2), 1–9. 10.1093/jtm/taw088
• Dobiesz, V. A., & Sullivan, W. (2017). Medicolegal issues in expedition and wilderness medicine. Emergency Medicine Clinics of North America, 35(2), 485–494. 10.1016/j.emc.2017.01.004 28411938
• Iserson, K. V. (2013). Medical planning for extended remote expeditions. Wilderness & Environmental Medicine, 24(4), 366–377. 10.1016/j.wem.2013.05.005 24001390
• Keystone, J. S., Kozarsky, P. E., Connor, B. A., Northdurft, H. D., Mendelson, M., & Leder, K. (2019). Travel medicine (4th ed.). Elsevier