# External Contributors

Name | Professional Affiliations
Ansdell, Vernon E. | John A. Burns School of Medicine, University of Hawai‘i (Honolulu, HI)
Backer, Howard D. | University of California Student Health Service (Berkeley, CA)
Barkati, Sapha | McGill University Health Centre (Montreal, Canada)
Barnett, Elizabeth D. | Boston University Chobanian & Avedisian School of Medicine; Boston Medical Center (Boston, MA)
Bégué, Rodolfo E. | University of Hawai‘i (Honolulu, HI)
Blumberg, Lucille H. | National Institute for Communicable Diseases—Honorary (Johannesburg, South Africa)
Borwein, Sarah | Beacon Medical Centre (Central, Hong Kong)
Bourque, Daniel L. | Boston University Chobanian and Avedisian School of Medicine; Boston Medical Center (Boston, MA)
Cabada, Miguel M. | University of Texas Medical Branch (Galveston, TX); Universidad Peruana Cayetano Heredia (Lima, Peru)
Chen, Lin H. | Mount Auburn Travel Medicine Center (Cambridge, MA); Harvard Medical School (Boston, MA)
Chimiak, James | Diver’s Alert Network (Durham, NC)
Connor, Bradley A. | Weill Cornell Medical College; The New York Center for Travel and Tropical Medicine (New York, NY)
Coyle, Christina | Albert Einstein College of Medicine (New York, NY)
Dawson-Hahn, Elizabeth E. | University of Washington (Seattle, WA)
Ebelke, Catherine I. | Montana State University Student Health Partners (Bozeman, MT)
Evans, Derek P. | Evans Travel Health (South Wales, United Kingdom)
Fivenson, David | Trinity Health System; David Fivenson, MD, Dermatology, PLLC (Ann Arbor, MI)
Freedman, David | University of Alabama at Birmingham (Birmingham, AL)
Freer, Luanne | Everest ER Himalayan Rescue Association (Kathmandu, Nepal)
Golding, John F. | University of Westminster, London (London, United Kingdom)
Hackett, Peter H. | University of Colorado Anschutz Medical Campus (Aurora, CO)
Hagmann, Stefan H. F. | Hackensack Meridian School of Medicine (Nutley, NJ)
Hamer, Davidson H. | Boston University School of Public Health; Travel Clinic, Boston Medical Center (Boston, MA)
Hickey, Patrick W. | Uniformed Services University of the Health Sciences (Bethesda, MD)
Huits, Ralph | IRCCS Sacro Cuore Don Calabria Hospital (Negrar, Italy)
Hynes, Noreen A. | Johns Hopkins University School of Medicine; Johns Hopkins Bloomberg School of Public Health (Baltimore, MD)
Iamsirithaworn, Sopon | Ministry of Public Health (Nonthaburi, Thailand)
Kivlehan, Sean M. | Brigham and Women’s Hospital; Harvard Medical School (Boston, MA)
Kotton, Camille N. | Massachusetts General Hospital; Harvard Medical School (Boston, MA)
Kozarsky, Phyllis E. | Emory University - Emerita (Atlanta, GA)
LaRocque, Regina C. | Massachusetts General Hospital; Harvard Medical School (Boston, MA)
Lehner, Virginia M. | Bureau of Consular Affairs, US Department of State (Washington, DC)
Leung, Daniel T. | University of Utah School of Medicine (Salt Lake City, UT)
Libman, Michael | McGill University (Montreal, Canada)
Mann, Erin M. | University of Minnesota (Minneapolis, MN)
Nardell, Edward A. | Harvard Medical School (Boston, MA)
Nelson, Erica L. | Brigham and Women’s Hospital; Harvard Medical School (Boston, MA)
Nilles, Eric | Harvard Medical School (Boston, MA)
Nord, Daniel A. | Duke Center for Hyperbaric Medicine & Environmental Physiology; Duke University School of Medicine (Durham, NC)
Norton, Scott A. | Uniformed Services University of the Health Sciences (Bethesda, MD)
Parker, Salim | University of Cape Town (Cape Town, South Africa)
Quadri, Nasreen S. | University of Minnesota Medical School; University of Minnesota (Minneapolis, MN)
Quinn, James | Uniformed Services University of the Health Sciences (Bethesda, MD); San Antonio Military Medical Center (San Antonio, TX)
Riedy, Samantha M. | Walter Reed Army Institute of Research (Silver Spring, MD)
Rosselot, Gail | Travel Well of Westchester, Inc. (Briarcliff Manor, NY)
Ryan, Edward T. | Massachusetts General Hospital; Harvard Medical School (Boston, MA)
Sanchez, Katherine A. | ICF (Rockville, MD)
Shaughnessy, Megan K. | Hennepin Healthcare (Minneapolis, MN)
Shaw, Andrea V. | SUNY Upstate Medical University (Syracuse, NY)
Shlim, David R. | Jackson Hole Travel and Tropical Medicine (Wilson, WY)
Shurtleff, David | National Center for Complementary and Integrative Health, National Institutes of Health (Bethesda, MD)
Smith, Darvin Scott | San Mateo Medical Center (San Mateo, CA)
Stauffer, William M. | University of Minnesota (St. Paul, MN)
Stout, Shawn | National Center for Complementary and Integrative Health, National Institutes of Health (Bethesda, MD)
Valk, Thomas H. | Unaffiliated (Jupiter, FL)
Van Tilburg, Christopher | Providence Hood River Memorial Hospital (Hood River, OR)
Walker, Patricia F. | HealthPartners Travel & Tropical Medicine Center (St. Paul, MN); University of Minnesota Medical School (Minneapolis, MN)
Wanat, Karolyn A. | Medical College of Wisconsin (Milwaukee, WI)
Wangu, Zoon | University of Massachusetts T.H. Chan School of Medicine (Worcester, MA); Massachusetts Department of Public Health (Jamaica Plain, MA)
Wilkins, Syreeta L. | University of Minnesota (Minneapolis, MN)
Williams, Scott G. | Walter Reed Army Institute of Research (Silver Spring, MD); Uniformed Services University of the Health Sciences (Bethesda, MD)
Wu, Henry M. | Emory University School of Medicine (Atlanta, GA)
Youngster, Ilan | Shamir Medical Center; Tel Aviv University (Tel Aviv, Israel)
Zia, Mehmil | Bureau of Consular Affairs, US Department of State (Washington, DC)