# Scuba Diving: Decompression Illness and Other Dive-Related Injuries

Traveler scuba diving surrounded by a school of fish.

## Introduction

There are estimates of 0.6–3.5 million scuba divers in the United States that range from the regular to the occasional diver, with many traveling to remote tropical areas of the world to dive. Divers face a variety of medical challenges, but because dive injuries generally are rare, few healthcare professionals are trained to prevent, diagnose, or treat them. Therefore, the onus is on recreational divers to assess potential risks before diving, to be prepared to recognize signs of injury, and to seek qualified dive medicine help promptly when needed.

## Preparing for dive travel

When counseling travelers who are planning dive-related trips, take into consideration chronic health conditions, any recent changes in health (e.g., injuries, pregnancy, surgeries), and medication use (see Travelers with Chronic Illnesses (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/travelers-with-chronic-illnesses.html) chapter). Divers Alert Network (https://www.dan.org/) (DAN) is a resource to access for assistance with a diver (Box 3.4.1). Underlying respiratory conditions (e.g., asthma, chronic obstructive pulmonary disease, infections, history of spontaneous pneumothorax) can challenge the breathing capacity required of divers. Mental health disorders (e.g., anxiety, claustrophobia, substance abuse) and disorders affecting central nervous system higher function and consciousness (e.g., seizures) raise special concerns about diving fitness. While it is important to review patient medications for possible compatibility with diving, there are no scientific data that support the safe use of drugs while diving. Thus, the primary concerns are generally the underlying condition for which the patient takes medication, clinical stability on the drug, and the potential for unsafe adverse reactions. Considering and acting upon a list of non-diving-related conditions and medication effects is important because they may be overlooked when evaluating a diver.

Diving is a potentially strenuous activity that can put substantial demands on the cardiovascular system. Serious injury and death are associated with poor physical conditioning; regular, vigorous aerobic and strengthening exercise should be part of a diver’s routine before arriving for their pre-dive physical examination and subsequent diving. People with known risk factors for coronary artery disease, including, but not limited to, diabetes, hypertension, family history of heart disease, an abnormal lipid profile, smoking history, and significant frailty index indicators, who wish to either begin a dive program or continue diving, should undergo a physical examination to assess their cardiovascular fitness. This examination might include an electrocardiogram, pulmonary function testing, exercise treadmill test, or echocardiogram. Abnormal findings should be reviewed by an appropriate medical specialist (e.g., cardiologist, pulmonologist) and include a diving medicine physician.

During the travel medicine examination, remind divers (and would-be divers) of actions they can take in advance to reduce or eliminate risks. Identifying and assessing potential hazards (e.g., environment, water, and weather conditions, planned depth and bottom time) can help divers make decisions about acceptable risk. Preparing for a safe dive also includes having an up-to-date emergency action plan, on-hand first aid supplies (with ample oxygen), and reliable communication devices. Using correct and well-maintained protective equipment, diving with supervision, and ensuring that medical care is available in the event of an emergency are other controls that divers can implement. A diver should never feel compelled to make a dive, especially if feeling unwell or if conditions are unsafe.

Of special note, many dive operators routinely screen clients by requiring a medical statement signed by the diver’s physician with approval to dive. Divers should communicate with their dive operator ahead of travel to acquire the necessary form to share with their personal physician. By being prepared with properly signed documentation upon arrival at their dive destination, the traveling diver can forestall denial of dive privileges. In the event of an abnormal finding, the condition needs to be evaluated by their physician as to whether that condition is compatible with diving before travel to the dive site. Guidance can be obtained on both the DAN (https://www.dan.org/) and Undersea and Hyperbaric Medical Society (https://www.uhms.org/) (UHMS) websites, with the option of contacting DAN directly if further help is needed.

Box 3.4.1 Divers alert network ★

- Divers Alert Network (DAN) maintains 24-hour emergency consultation and evacuation assistance at +1-919-684-9111 (collect calls accepted).
- DAN can help with the medical management of injured divers by deciding if recompression is needed, providing the location of the closest recompression facility, and arranging patient transport.
- Divers and healthcare professionals also can contact DAN for routine, non-emergency consultation by telephone at 919-684-2948, extension 6222, or by accessing the DAN (https://www.dan.org/) website.

## Diving disorders

### Barotrauma

Barotrauma is an injury to soft tissues resulting from a pressure differential between an airspace in the body and the ambient pressure. The resultant expansion or contraction of that space can cause injury.

#### Ear and sinus

The most common injury in divers is middle ear barotrauma, or “middle ear squeeze” (Box 3.4.2). On descent, failure to equalize pressure changes within the middle ear space creates a pressure gradient across the eardrum. As the middle ear tissues swell with edema, a consequence of the increased pressure on the tissue surrounding this air space, some relative negative pressure difference across the eardrum can persist. Despite these fluid/edematous tissue injury responses, the eardrum is still pushed into the middle ear space, causing pain, bleeding, and possibly rupture and even injury to the inner ear.

Forceful equalization under these conditions can increase the pressure differential between the inner ear and the middle ear, resulting in round window rupture with perilymph leakage and inner ear damage. To avoid these pathologic processes, divers must learn proper equalization techniques. Healthcare professionals can coach this effort by observing movement of the tympanic membrane using simple otoscopy.

Paranasal sinuses, because of their relatively narrow connecting passageways, are especially susceptible to barotrauma, generally on descent. With small changes in pressure (depth), symptoms are usually mild and subacute but can be exacerbated by continued diving. Larger pressure changes can be more injurious, especially with forceful attempts at equilibration (e.g., the Valsalva maneuver). Additional risk factors for ear and sinus barotrauma include:

- Use of solid earplugs
- Medication (e.g., overuse or prolonged use of decongestants leading to rebound congestion)
- Ear or sinus surgery
- Nasal deformity or polyps
- Chronic nasal and sinus disease that interferes with equilibration during the large barometric pressure changes encountered while diving

Divers who suspect they have ear or sinus barotrauma should discontinue diving and seek medical attention.

Box 3.4.2 Symptoms of ear barotrauma ★

- Decreased hearing
- Pain
- Sensation of fullness
- Sensation of “water in the ear” (serous fluid/blood accumulation in the middle ear)
- Tinnitus (ringing in the ears)
- Vertigo (dizziness or sensation of spinning)

#### Pulmonary

Scuba divers can reduce the risk for lung overpressure problems by breathing normally and ascending slowly when breathing compressed gas. Overexpansion of the lungs can result if a scuba diver ascends toward the surface without exhaling, which can happen, for example, when a novice diver panics and kicks back toward the surface. During ascent, compressed gas trapped in the lung increases in volume until the expansion exceeds the elastic limit of lung tissue, causing damage and allowing gas bubbles to escape into 3 possible locations: the pleural space, mediastinum, or pulmonary vasculature. Gas entering the pleural space can cause lung collapse or pneumothorax. Gas entering the mediastinum causes mediastinal emphysema and frequently tracks under the skin (subcutaneous emphysema) or into the tissue around the larynx, sometimes precipitating a change in voice characteristics. Gas rupturing the alveolar walls can enter the pulmonary capillaries and pass via the pulmonary veins to the left side of the heart, resulting in arterial gas embolism (AGE).

Mediastinal or subcutaneous emphysema might resolve spontaneously, but pneumothorax generally requires specific treatment to remove the air and reinflate the lung. AGE is a medical emergency, requiring urgent intervention with hyperbaric oxygen therapy (recompression treatment).

Lung overinflation injuries from scuba diving can range from mild to dramatic and life threatening. Although pulmonary barotrauma is uncommon in divers, prompt medical evaluation is necessary, and healthcare professionals must rule out this condition in patients presenting with post-dive respiratory or neurologic symptoms shortly after surfacing.

### Decompression illness

Decompression illness (DCI) describes bubble-related dysbaric injuries, including AGE and decompression sickness (DCS). Because scientists consider these 2 conditions to result from separate causes, they are described here separately. From a clinical and practical standpoint, however, distinguishing between them in the field might be impossible and unnecessary because the initial treatment is the same for both (Table 3.4.1). DCI can occur even in divers who have carefully followed the standard decompression tables and the principles of safe diving. Serious permanent injury or death can result from AGE or DCS.

Table 3.4.1 Decompression illness syndromes and clinical manifestations

Arterial Gas Embolism | Decompression Sickness
- Ataxia; - Blurred vision; - Chest pain or bloody sputum; - Convulsions; - Dizziness; - Loss of consciousness; - Muscular weakness; - Numbness or paresthesia; - Paralysis; - Personality change, difficulty thinking, or confusion | - Collapse or unconsciousness; - Coughing spasms or shortness of breath; - Dizziness; - Itching; - Joint aches or pain; - Loss of bowel or bladder function; - Mottling or marbling of skin; - Numbness or tingling; - Paralysis; - Personality changes; - Staggering, loss of coordination, or tremors; - Unusual fatigue; - Weakness

#### Arterial gas embolism

Gas entering the arterial blood through ruptured pulmonary vessels can distribute bubbles into the body tissues, including the heart and brain, where they can disrupt circulation or damage vessel walls. The clinical presentation of AGE ranges from minimal neurologic findings to dramatic symptoms requiring urgent and aggressive hyperbaric oxygen treatment.

In general, suspect AGE in any scuba diver who surfaces unconscious or loses consciousness within 10 minutes after surfacing. Initiate basic life support, including administration of the highest fraction of oxygen. Because relapses can and do occur, divers suffering AGE should be rapidly evacuated to a hyperbaric oxygen treatment facility even if they appear to have recovered fully.

#### Decompression sickness (“the bends”)

Breathing air under pressure causes excess inert gas (usually nitrogen) to dissolve in and saturate body tissues. The amount of gas dissolved is proportional to, and increases with, the total depth and time a diver is below the surface. Depending on the amount of gas dissolved and the rate of ascent, some gas can supersaturate tissues, where it separates from solution to form bubbles, interfering with blood flow and tissue oxygenation. This excess dissolved gas must be cleared through respiration.

### Other conditions related to diving

### Drowning

Any incapacitation while underwater can result in drowning (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/injury-and-death-during-travel.html).

#### Hazardous marine life

Oceans and waterways are filled with marine animals, most of which are generally harmless unless threatened. Most injuries among divers are the result of chance encounters or defensive maneuvers of marine life. Wounds from marine life have many common characteristics, including bacterial contamination, foreign bodies, bleeding, and occasionally envenomation. See Zoonotic Exposures: Bites, Scratches, and Other Hazards (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/zoonotic-exposures.html) and Poisonings, Envenomations, and Toxic Exposures During Travel (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/poisonings-envenomations-and-toxic-exposures-during-travel.html) for prevention and injury-management recommendations.

#### Immersion (induced) pulmonary edema

The normal hemodynamic effects of water immersion account for a shift of fluid from peripheral to central circulation that can result in higher pressures within the pulmonary capillary bed, forcing excess fluid into the lungs. Cold water can cause peripheral vasoconstriction and augment this central fluid shift. Symptoms and signs of immersion (induced) pulmonary edema (IPE) generally begin on descent or at depth and include chest pain, dyspnea, wheezing, and productive cough with frothy, sometimes pink-tinged sputum. Although not entirely well understood, age, overhydration, overexertion, negative inspiratory pressure, and left ventricular hypertrophy are believed to increase IPE risk in otherwise healthy divers. Anyone experiencing acute pulmonary edema while diving requires a workup to rule out myocardial ischemia and evaluation of left ventricular function, hypertrophy, and valvular integrity.

#### Nitrogen narcosis

At increasing depths, generally 30 m (>100 ft), the partial pressure of nitrogen within the breathing gas increases, causing narcosis in all recreational divers. Nitrogen narcosis can be life threatening when it impairs a diver’s ability to make appropriate and proper decisions while underwater. This narcosis quickly clears on ascent and is not seen on the surface after a dive, which helps differentiate this condition from DCI.

#### Oxygen toxicity

At increasing partial pressures of oxygen, levels in the blood can become high enough to cause seizures. This condition is not seen when diving with compressed air within recreational depth limits. Seizure has been reported with diving that involves elevated partial pressures of oxygen that might occur breathing gas with a higher percentage of oxygen, oxygen decompression, or closed-circuit rebreather diving.

## Preventing diving disorders

Recreational divers should dive conservatively and well within the no-decompression limits of their dive tables or computers. When multiple dives are planned, strict guidelines, known as surface intervals, are prescribed to allow adequate time for dissolved inert gas to drop to acceptable levels before the next dive. Tables derived from human-tested algorithms have traditionally been used by divers to manually calculate dive times and surface intervals. Dive computers possess the reliability and computing power to use the same algorithms and compute individual guidance based on real-time depth and time inputs. Dive computers have largely replaced the use of tables for the manual process of dive planning.

Risk factors for DCI are primarily dive depth, dive time, and rates of ascent. Additional factors, such as altitude exposure too soon after a dive, difficult diving conditions (e.g., colder water, currents, decreased visibility, wave action), dives to depths 18 m (>60 ft), multiple consecutive days of diving or repetitive dives, overhead situations (e.g., diving in underwater caves or wrecks), strenuous exercise, and certain physiologic variables (e.g., dehydration), also increase risk. Caution divers to stay well-hydrated and rested and dive within the limits of their training. Diving is a skill that requires training and certification and should be done with a well-trained, attentive companion (i.e., dive buddy).

## Treatment of diving disorders

Definitive treatment of DCI begins with early recognition of symptoms, followed by recompression with hyperbaric oxygen. Be suspicious of any unusual symptoms occurring soon after a dive, especially neurological symptoms, and evaluate these properly. Provide a high concentration (100%) of supplemental oxygen; surface-level oxygen given for first aid might relieve the signs and symptoms of DCI and should be administered as soon as possible.

Divers are often dehydrated because of incidental causes, immersion, or DCI itself, which can cause capillary leakage. In most cases, treatment includes administering isotonic glucose-free intravenous fluids. Oral rehydration fluids also can be helpful if they can be administered safely (i.e., if the diver is conscious and can maintain their airway).

The definitive treatment of DCI is recompression and oxygen administration in a hyperbaric chamber. Stable or remitting symptoms of mild DCI (e.g., constitutional symptoms, some cutaneous sensory changes, limb pain, or rash) in divers reporting from remote locations without a hyperbaric facility might not require recompression. Medical management decisions made with the assistance of a qualified dive medicine physician also should account for the prevailing circumstances, logistics and hazards of evacuation, and the implications of failing to recompress. Serial neurologic exams are essential to the decision-making process.

Travelers who plan to scuba dive should ascertain whether recompression facilities are available at their destination before embarking on their trip, especially if there are significant risk factors or if planning long, deep, or multi-day repetitive dives.

## Diving and air travel

### Flying after diving

The risk of developing decompression sickness increases when divers ascend to increased altitude too soon after a dive. Commercial aircraft cabins are generally pressurized to the equivalent of approximately 1,830–2,440 m (6,000–8,000 ft) above sea level. Asymptomatic divers should wait before any altitude exposures >610 m (>2,000 ft), which includes most commercial aircraft travel. These recommended waiting periods following various dive exposures are:

- ≥12 hours after surfacing from a single no-decompression dive
- ≥18 hours after multiple dives or multiple days of diving
- 24–48 hours after a dive that required decompression stops

These recommended pre-flight surface intervals reduce, but do not eliminate, the risk for DCS. Longer surface intervals further reduce this risk. Symptomatic divers should seek evaluation to rule out possible decompression illness before attempting any exposure to increased altitude. A diagnosis of decompression illness generally requires appropriate treatment before any flight or ascent to altitude.

### Diving after flying

There are no guidelines for diving after flying. Divers should wait a sufficient period to acclimate mentally and physically to their new location to focus solely on the dive.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Burbakk, A. O., Neuman, T. S., Bennett, P. B., & Elliott, D. H. (2003). Bennett and Elliott’s Physiology and Medicine of Diving (5th ed.). Saunders.
• Denoble, P., & Chimiak, J. (2022). Travelers Medical Guide. Dan.org. https://www.dan.org/wp-content/uploads/2021/08/dan-travel-medical-guide.pdf
• Divers Alert Network. The Heart & Diving, Chapter 6: Pulmonary and Venous Disorders. Dan.org. https://www.dan.org/health-medicine/health-resource/dive.-medical-reference-books/the-heart-diving/pulmonary-and-venous-disorders/
• Divers Alert Network. (2003). Flying After Diving. Dan.org. https://www.dan.org/research-reports/research-studies/flying-after-diving
• Mitchell, S., & Doolette, D. J. (2005). Management of mild or marginal decompression illness in remote locations (C. J. Wacholz & R., Vann, Eds.). Journal of the South Pacific Underwater Medicine Society, 1–242.
• Moon, R. E. (2004). Treatment of Decompression Illness (4th ed., pp. 195–223). W. B. Saunders.
• Moon, R. E. (2019). Undersea and Hyperbaric Medical Society Hyperbaric Oxygen Therapy Indications. Best Publishing.
• Naval Sea Systems Command. (2018). U.S. Navy Diving Manual Revision 7, Change A. Naval Sea Systems Command.
• Neuman, T. S., & Thom, S. R. (2008). Physiology and Medicine of Hyperbaric Oxygen Therapy (1st ed.). Saunders.