# Disclaimers

All Centers for Disease Control and Prevention (CDC) material in this publication is in the public domain and may be used and reprinted without special permission; citation of source is appreciated.

Readers are invited to send comments and suggestions regarding this publication to yellowbook@cdc.gov.

## Authorship

CDC Yellow Book authors are identified by their respective CDC Centers as having subject-matter expertise in their field. Contributing authors external to CDC are identified by the editorial staff as experts in their fields. Prior to publication, all content is reviewed by a technical editor, a medical editor, the senior medical editor, and the editor in chief before undergoing final CDC review and clearance.

Newly invited authors are asked to rewrite chapters previously written by others. All authors (both new and continuing) are expected to conduct a thorough literature search and to update their topic based on currently available science and clinical practice guidelines and recommendations. All authors have provided a signed statement declaring whether they have financial interests in or other involvements (e.g., receipt of consulting fees, lecture fees, royalties, or grant support from a commercial sponsor; ownership of stock, employment, hold patents or serve as an expert witness on behalf of a commercial sponsor) that could be construed as a conflict of interest with the subject matter or materials discussed in the chapters they have written or reviewed for CDC Yellow Book 2026.

The following authors and editors have disclosed interests below:

Barnett, Elizabeth D.

- Consulting/Advisory Boards: Sobi
- Grant/Research/Clinical Trial Support: Boston Medical Center (Pfizer vaccine trials); GSK (MMRV vaccine study)
- Other Financial Interests: Elsevier (Royalties – immigrant medicine); AAP (Royalties – Nelson's antimicrobial therapy); UpToDate (Royalties – Medical care of adult refugees, immigrants, and migrants to the United States chapter)

Borwein, Sarah

- Consulting/Advisory Board: GSK (pneumococcal vaccines)

Chen, Lin H.

- Consulting/Advisory Boards: Merck, Shoreland Inc, Valneva
- Data and Safety Monitoring Board: Valneva

Golding, John F.

- Consulting/Advisory Boards: Defender Pharmaceuticals

Hackett, Peter H.

- Other Financial Interests: UpToDate (Royalties)

Hamer, Davidson H.

- Consulting/Advisory Boards: Takeda, Valneva
- Speaker's Bureau: Bavarian Nordic

Leung, Daniel T.

- Other Financial Interests: BMJ Best Practice (Honorarium)

Ostroff, Stephen

- Consulting/Advisory Boards: Pfizer

Rosselot, Gail

- Grant/Research/Clinical Trial Support: Bavarian Nordic (educational webinar on rabies and dengue), Takeda (educational webinars on rabies and dengue)

Stauffer, William

- Consulting/Advisory Boards: BCT Partners
- Other Financial Interests: UpToDate (Royalties - Medical care of adult refugees, immigrants, and migrants to the United States chapter)

Walker, Patricia F.

- Other Financial Interests: Elsevier (Royalties – immigrant medicine textbook); UpToDate (Royalties – Medical care of adult refugees, immigrants, and migrants to the United States chapter)

Wangu, Zoon

- Other Financial Interests: Dynamed (Royalties); Elsevier (Royalties); UpToDate (Royalties)

Despite these interests, they certify that the information that they have written or reviewed for this book to be objective and free from bias. All of the relevant financial relationships listed above have been mitigated.

The remaining others have no conflict of interest with the content they have written or reviewed for this text and have expressed the content to be objective and free from bias.

## Disclaimers

All CDC Yellow Book 2026 content was reviewed by subject matter experts, within and outside of CDC, and is determined to be accurate as of the date of submission of this manuscript for publication. The information that appears in this print edition, however, may not represent the most current science or public health recommendations available.

Maps: Names and boundary representation are not necessarily authoritative.

The United States takes no position as to which country has sovereignty over the islands in the South China Sea, which is not a matter governed by the law of the sea.

Names of drugs, biologics, and medical products: Both generic and trade names (without trademark symbols) are used throughout this text. The use of trade names and commercial sources is for identification only and does not imply endorsement by the US Department of Health and Human Services (HHS), the United States Public Health Service (USPHS), or the CDC.

Non-CDC references: References to non-CDC internet sites are provided as a service to readers and do not constitute or imply endorsement of these organizations or their programs by HHS, USPHS, or CDC. CDC is not responsible for the content of these sites. Uniform Resource Locator (URL) addresses provided in the text are current as of the date of publication.

Off-label use descriptions: Descriptions of drugs, biologics, or medical products used for an indication not in the approved labeling or packaging ("off-label" use) do not constitute official HHS approval or endorsement of those products or uses. Off-label uses described in this publication have been identified by subject matter experts based on published evidence and clinical experience. Clinicians who use a product off-label should be well-informed about the product, base its use on firm scientific rationale and sound medical evidence, and maintain records of the product's efficacy and effects.

## Notice

This material is not intended to be, and should not be considered, a substitute for medical, legal, or other professional advice. Treatment of the conditions described in this text is highly dependent on individual circumstances. While this text is designed to offer accurate information with respect to the subject matter covered and to be current as of the time it was written, research and knowledge about medical, legal, and health issues are constantly evolving and dose schedules for medications and vaccines are revised continually, with new side effects recognized and accounted for regularly. Therefore, readers of this text should always confirm the accuracy of any listed product information and clinical procedures with the most up-to-date published product information and data sheets provided by manufacturers and the most recent codes of conduct and safety regulations. Oxford University Press (the Publisher) and the authors and editors make no representations or warranties to readers, express or implied, as to the accuracy or completeness of this material, including without limitation that they make no representations or warranties as to the accuracy or efficacy of the drug dosages provided. The Publisher, the authors, and editors do not accept, and expressly disclaim, any responsibility for any liability, loss, or risk that may be claimed or incurred as a consequence of the use and/or application of any of the contents of this text.

The Publisher, the authors, and editors make all editorial decisions, including content decisions.

Neither the Publisher, the authors, nor the editors are responsible for any product information added to this publication by companies purchasing copies for distribution to clinicians.

The CDC YELLOW BOOK wordmark and the CDC YELLOW BOOK logo are trademarks of the U.S. Department of Health and Human Services (HHS). Use of these marks without prior written approval by HHS is strictly prohibited.