# Yellow Fever Vaccine and Malaria Prevention Information, by Country

World map.

## Search recommendations by country

Search yellow fever and malaria prevention recommendations by country (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/yellow-fever-vaccine-and-malaria-prevention-information-by-country.html)

## Yellow fever vaccine

### Decision to vaccinate

When deciding whether to vaccinate travelers, healthcare professionals should consider destination-specific risks for YF virus infection and individual risk factors (e.g., age, immune status) for serious YF vaccine-associated adverse events in the context of the country entry requirements (see Yellow Fever (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/yellow-fever.html) chapter for a full discussion of YF disease and vaccination guidance). Since 2016, the YF vaccine booster requirement was eliminated from the International Health Regulation (IHR), and a completed International Certificate of Vaccination or Prophylaxis (ICVP) is considered valid for the life of the person vaccinated.

### CDC recommendations

CDC’s YF vaccine recommendations are intended to protect travelers from acquiring YF virus infections during international travel and may differ from country entry requirements for proof of YF vaccination under the IHR. These recommendations are based on the risk for YF virus infection in a specific destination, which is classified according to its YF virus transmission activity: endemic, transitional, low potential for exposure, and no risk (Table 1.5.1). CDC recommends YF vaccination for travel to areas classified as having endemic or transitional risk (see Map 4.21.1 and Map 4.21.2 in Yellow Fever (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/yellow-fever.html) chapter) only.

Table 1.5.1 Yellow fever (YF) vaccine recommendation categories^1^

YF vaccine recommendation category | Rationale
Recommended | Vaccination recommended for all travelers ≥9 months old going to areas with endemic or transitional YF risk, as determined by persistent or periodic YF virus transmission
Generally not recommended | Vaccination generally not recommended for travel to areas where the potential for YF virus exposure is low, as determined by absence of reports of human YF and past evidence suggestive of only low levels of YF virus transmission; Vaccination might be considered for a small subset of travelers at increased risk for exposure to YF virus due to prolonged travel, heavy mosquito exposure, or inability to avoid mosquito bites
Not recommended | Vaccination not recommended for travel to areas where there is no risk for YF virus transmission, as determined by absence of past or present evidence of YF virus circulation in the area or environmental conditions not conducive to YF virus transmission

Notes

1 This table is an abbreviated version of Table 1 from: Jentes, E. S., Poumerol, G., Gershman, M. D., Hill, D. R., Lemarchand, J., Lewis, R. F., … Monath, T. P. (2011). The revised global yellow fever risk map and recommendations for vaccination, 2010: Consensus of the Informal WHO Working Group on Geographic Risk for Yellow Fever. The Lancet: Infectious Diseases, 11(8), 622–632 21798462 . The categories of risk of YF virus transmission and corresponding categories of YF vaccine recommendations that appear here are taken unchanged from the referenced article.

### Country entry requirements

Under the IHR, countries are permitted to establish YF vaccine entry requirements to prevent the importation and transmission of YF virus within their boundaries. Certain countries require proof of vaccination from travelers arriving from all countries (see Table 4.21.4 in Yellow Fever (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/yellow-fever.html) chapter). Some countries require proof of vaccination only for travelers above a certain age coming from countries with risk for YF virus transmission; sometimes travel through an airport of a country with risk of YF virus transmission is included. The World Health Organization (WHO) defines areas with risk for YF virus transmission as countries or areas where YF virus activity has been reported currently or in the past and where vectors and animal reservoirs exist. WHO publishes a list of YF vaccine country entry requirements and recommendations for international travelers approximately annually.

Travelers must comply with a country’s entry requirements for proof of vaccination against YF by showing an ICVP with either evidence of vaccination or indication of a medical waiver. Additionally, the full travel itinerary should be considered to assess for transfers through airports that may require the traveler to pass through immigration checkpoint for accommodations or otherwise during a long layover.

## Malaria prevention

Human malaria is caused by Plasmodium falciparum, Plasmodium malariae, Plasmodium ovale, Plasmodium vivax, and Plasmodium knowlesi. Plasmodium species are transmitted by the bite of an infective female Anopheles mosquito. In the World Malaria Report 2024, WHO reported a total of 83 malaria-endemic countries globally. The following recommendations to protect travelers from malaria were developed using the best available data from multiple sources. Countries are not required to submit malaria surveillance data to CDC. On an ongoing basis, CDC actively solicits data from multiple sources, including WHO (main and regional offices); national malaria control programs; international organizations; CDC overseas offices; US military; academic, research, and aid organizations; and the published scientific literature. The reliability and accuracy of those data are also assessed.

If the information is available, trends in malaria incidence and other data are considered in the context of malaria-control activities within a given country or other mitigating factors (e.g., natural disasters, wars, the COVID-19 pandemic) that can affect the ability to control malaria or accurately count and report it. Factors such as the volume of travel to that country and the number of acquired cases reported in the U.S. National Malaria Surveillance System are also examined. In developing its recommendations, CDC considers areas within countries where malaria transmission occurs, substantial occurrences of antimalarial drug resistance, the proportions of species present, and the available malaria prophylaxis options.

Healthcare professionals should use these recommendations in conjunction with an individual risk assessment and consider not only the destination but also the detailed itinerary, including specific cities, types of accommodations, season, and style of travel, as well as special health conditions (e.g., pregnancy). Several medications are available for malaria prophylaxis. When deciding which drug to use, consider the itinerary and length of trip, malaria drug resistance in the destination country, previous adverse reactions to antimalarials, drug allergies, medical history, and drug costs (for a thorough discussion of malaria and guidance for prophylaxis, see Malaria (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/malaria.html) chapter).

## Acknowledgements

The following authors contributed to the previous version of this chapter: Holly Biggs, Mark D. Gershman, Rhett J. Stoney, and Katherine R. Tan.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)