# China

Great Wall of China in Huairou District, China.

## Destination overview

China is the world’s second-most populous country (>1.4 billion people) and the fourth largest geographically, behind Russia, Canada, and the United States. Divided into 23 provinces, five autonomous regions, four municipalities, and two Special Administrative Regions, China is home to diverse customs, languages, and topographies (Map 11.3.1.1). The climate varies from tropical in the south to subarctic in the north, with wide variations between regions and seasons.

The long history and varied natural beauty of China can be traced through the country’s 59 UNESCO World Heritage sites, including the Forbidden City and Temple of Heaven, the Great Wall, the Terracotta Warriors of Xi’an, and the spectacular mountainous sanctuaries of the west. Recent additions include Quanzhou, the Emporium of the World in Song-Yuan, Mount Fanjing in southwest China, the archaeological ruins of Liangzhu City in the Yangtze River Delta, the migratory bird sanctuaries along the Bohai Gulf Coast, the Tusi tribal domains in western China, the Ancient Tea Plantations of JingMai Mountain in Pu’er, and the Grand Canal, the oldest (dating back to 468 BCE) and longest (1,794 km; 1,115 miles) man-made canal in the world.

Prior to the COVID-19 pandemic, China had the largest outbound travel market in the world, in terms of the number of trips and total expenditures. In 2019, there were 155 million outbound trips and an additional >145 million inbound visitors. These numbers represent an extraordinary pace of growth, more than tripling since 2010. The pandemic drastically reduced both inbound and outbound travel. After travel restrictions were lifted in January 2023, domestic travel rebounded sharply, reaching 90% of pre-pandemic levels during the first half of the year. Domestic travelers have been visiting the usual tourist destinations, including sightseeing in Beijing and at the Great Wall, touring Shanghai, cruising the Yangtze River, and exploring the Zhangjiajie National Forest Park in Zhejiang Province (see Box 11.3.1.1 for a list of other popular tourist destinations). International travel, both inbound and outbound, has not yet fully recovered but is expected to rebound as international air capacity improves and remaining restrictions on visa requirements and tour groups are lifted.

Aside from tourism, people travel to China for business opportunities, to visit friends and relatives, to study, and to adopt children. These non-tourist travelers might be at greater risk of becoming ill because they may underestimate health hazards, may be less likely to seek pre-travel advice, and may be more likely to stay in local or rural accommodations.

China has the second-largest economy and the second-largest number of billionaires in the world. In 2022, China’s gross national income (GNI) per capita using purchasing power parity method was USD 21,250, slightly above the global GNI per capita of USD 20,593 for the same year. Wide disparities in wealth and development exist between the urban and more rural areas. Health risks vary accordingly.

Box 11.3.1.1 Popular tourist destinations in China ★

- Guilin: uniquely shaped limestone karst mountains, featured in paintings
- Hainan Island: tropical beaches, luxury resorts
- Harbin: spectacular annual winter ice festival, European architecture
- Hong Kong: futuristic architecture, contrasts between Eastern and Western cultures
- Macau: modern casinos contrast with fascinating Portuguese heritage
- Xi’an: Terracotta warriors, ancient city wall, and Hui ethnic food street
- Dunhuang: Silk Road, camel treks, and Buddhist cave art in the Mogao Grottoes
- Sichuan Province: home to China’s iconic symbol, the giant panda (for more details, see Box 11.3.1.2), and spicy Sichuan cuisine
- Tibet: accessible by the world’s highest railroad (maximum elevation 5,072 m; approximately 16,600 ft)
- Yunnan Province: cultural diversity, famous Pu’er tea gardens, Tiger Leaping Gorge, and the historic cobblestone city of Lijiang
- Zhangjiajie National Forest Park (Hunan Province): tallest and longest glass bridge in the world and inspiration for the movie Avatar

Map 11.3.1.1 China

A map of China, showing its provinces, major cities, and geographical landmarks. The map highlights China’s borders with neighboring countries, including Mongolia, Russia, India, and Vietnam. Major cities such as Beijing, Shanghai, Guangzhou, and Chengdu are labeled. Geographical landmarks include the Himalaya Mountains, Tibetan Plateau, Takla Makan Desert, and the Yangtze River. Notable sites like the Great Wall, Terracotta Warriors, and Giant Panda Reserve are marked. The South China Sea, Yellow Sea, and East China Sea are labeled, along with Taiwan, Hong Kong SAR, and Macau SAR. A small map on the bottom left shows China’s location within Asia.

SOURCE: Centers for Disease Control and Prevention

## Infectious disease risks

Travelers should be up to date on routine childhood vaccinations (diphtheria-tetanus-pertussis, measles-mumps-rubella, and varicella), as well as vaccines that protect children and adults against respiratory illnesses like seasonal influenza and COVID-19. Because of high immunization coverage, China has maintained low rates of measles and rubella transmission since 2020. Due to health risks to unborn fetuses, women of reproductive potential should ensure that they have received rubella vaccine prior to travel. Cases of pertussis and varicella are reported regularly, particularly among young and school-aged children and adolescents.

### Vaccine quality and availability in China

China is making considerable advances in vaccine production, working with established pharmaceutical companies in joint ventures or by developing and manufacturing vaccines locally. Although counterfeit and improperly stored vaccines were concerns in the past, China has waged a robust response and these issues are now rare. Availability of some vaccines may be limited. Travelers should not assume they can complete an unfinished vaccination series once in China; thus, all travelers going to China should be up to date with all routine and recommended vaccinations before travel. Circumstances in Hong Kong are different; international vaccines, including routine childhood, COVID-19, and influenza vaccines, are generally available.

### Blood-borne pathogens

#### Hepatitis B virus

Hepatitis B virus (HBV) infection is endemic to China. Nearly one-third of the 350 million people worldwide infected with HBV reside in China. Although mother-to-child transmission has been virtually eliminated due to successful routine hepatitis B vaccination, a large proportion of infected adults in China remain unaware that they have HBV infection, resulting in potential HBV transmission to the unvaccinated population. The Advisory Committee on Immunization Practices recommends hepatitis B vaccine as part of the routine childhood schedule and for unvaccinated U.S. adults aged 19–59 years; hepatitis B vaccine should be considered for all nonimmune travelers to China.

### Enteric infections and diseases

#### Brucellosis

Brucellosis occurs in pastoral areas of China, primarily among persons involved in livestock production. High-risk provinces include Inner Mongolia, Jilin, Heilongjiang, Shandong, Gansu, Hebei, and Xinjiang. Regardless of destination, travelers should strictly avoid raw or unpasteurized milk and undercooked meat products.

#### Hepatitis E virus

Hepatitis E virus (HEV) genotype 4 is endemic in China and is usually acquired by drinking contaminated water (e.g., from wells) or eating uncooked/undercooked meats or seafood. Pregnant women in their third trimester are at particular risk for severe disease. Immunosuppressed persons, in particular solid organ transplant recipients receiving immunosuppressive medication, are at risk for chronic infection. Advise travelers to practice good hand hygiene and to adhere to safe food and water precautions (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/food-and-water-precautions-for-travelers.html).

#### Travelers’ diarrhea

The risk for travelers’ diarrhea appears to be low in “luxury” accommodations in China but moderate elsewhere (see Travelers’ Diarrhea (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travelers-diarrhea.html) and Post-Travel Diarrhea (https://www.cdc.gov/yellow-book/hcp/post-travel-evaluation/post-travel-diarrhea.html)). Travelers should adhere to safe food and water precautions (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/food-and-water-precautions-for-travelers.html); they should also strictly avoid undercooked fish and shellfish and unpasteurized milk products. Other than in Hong Kong, tap water is not safe to drink, even in major cities. Most hotels provide boiled or bottled water. Bottled water is readily available at local convenience stores and restaurants.

#### Typhoid fever

Typhoid fever (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/typhoid-and-paratyphoid-fever.html) and paratyphoid fever can be life-threatening diseases. Although typhoid fever is not a significant risk in China’s major urban areas, travelers visiting rural areas, adventure travelers (https://www.cdc.gov/yellow-book/hcp/travel-for-work-other/adventure-travel.html), and travelers visiting friends and relatives (https://www.cdc.gov/yellow-book/hcp/refugees-immigrants-migrants/visiting-friends-and-relatives-vfr-travel.html) should strongly consider receiving the typhoid vaccine. Paratyphoid fever can cause similar symptoms and is more common in China. Currently, there is not a vaccine against paratyphoid fever. Multidrug-resistant Salmonella typhi and Salmonella paratyphi have been detected in China. Travelers are advised to adhere to safe food and water precautions (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/food-and-water-precautions-for-travelers.html).

### Respiratory infections and diseases

#### Coronavirus disease 2019

All travelers going to China should be up to date with their COVID-19 vaccines (https://www.cdc.gov/covid/vaccines/stay-up-to-date.html).

#### Influenza

China’s national influenza vaccination technical guidelines recommend the Northern Hemisphere influenza vaccines. Travelers to China are recommended to be up to date using the influenza vaccination offered in their home country before travel. Even when vaccinated, travelers should continue to observe all necessary behavioral precautions to protect themselves from influenza, including frequent hand washing and respiratory etiquette.

#### Tuberculosis

The World Health Organization (WHO) classifies China as one of the high-burden countries for tuberculosis (TB) transmission. Travelers can become infected through exposure to a person with active Mycobacterium tuberculosis infection. Consuming unpasteurized milk products poses a risk for infection with Mycobacterium bovis, another mycobacterium that can cause disease in people. For long-term travelers or travelers whose itineraries place them at increased risk for exposure, consider pre-departure TB testing (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/tuberculosis.html) with retesting upon their return home.

### Sexually transmitted infections and HIV

Sexually transmitted infections (https://www.cdc.gov/yellow-book/hcp/travel-for-work-other/sex-and-travel.html) (STIs), including chlamydia, gonorrhea, HIV, and syphilis, are a growing problem in China, particularly along the booming eastern seaboard. Drug-resistant gonorrhea is increasingly prevalent. Travelers should be aware of STI risks and the importance of using condoms when having sex with anyone whose HIV or STI status is unknown. As previously noted, travelers should receive hepatitis B vaccination before travel.

Most cases of monkeypox occur among adult males, with more than 90% reporting same-sex sexual contact as a risk factor. China has not yet implemented an monkeypox vaccination prevention strategy. Suspected and confirmed cases are required to be isolated (see Sex and Travel (https://www.cdc.gov/yellow-book/hcp/travel-for-work-other/sex-and-travel.html), for more information about monkeypox).

### Soil- and waterborne infections

#### Schistosomiasis and leptospirosis

Elimination programs for schistosomiasis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/schistosomiasis.html) have been quite successful. Infections are primarily caused by Schistosoma japonicum and are most likely to occur along the Yangtze and Mekong River basins. Current prevalence of S. japonicum in humans and livestock is very low. Nevertheless, travelers should avoid freshwater swimming, which also decreases their risk of contracting bacterial infections, including leptospirosis.

### Vector-borne diseases

#### Chikungunya, dengue, and Zika

Most outbreaks of chikungunya, dengue (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/dengue.html), and Zika in China have been linked to imported cases from elsewhere in Asia, Africa, or South America and spread locally through 2 key vectors: Aedes aegypti and Aedes albopictus. Chikungunya has been reported in China, with recent outbreaks reported in Yunnan, Guangdong, and Zhejiang Provinces. In 2016, 22 cases of Zika were imported to China, including 15 to Guangdong Province. Due to rapid case detection and isolation, along with vector control, no local transmission was reported. Dengue, however, is a significant health risk for travelers. In 2014, China experienced the country’s worst dengue outbreak in decades; Guangdong Province reported >40,000 cases in just 2 months. Dengue epidemics occur in China every 4–6 years, mostly in the southern provinces. Travelers should practice insect-bite precautions (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html) during the summer months. Due to the moderate climate in southern Yunnan and Hainan Province, insect-bite precautions should be considered year-round.

#### Japanese encephalitis

China included the Japanese encephalitis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/japanese-encephalitis.html) (JE) vaccine in the national immunization schedule in 2008 and has successfully reduced the incidence of JE in most of the country. However, the 2018 JE outbreak in Gansu Province, with record high rates of transmission, is a reminder that the vector is still present, and that disease transmission and outbreaks are possible. JE vaccine should be considered for travelers with frequent travel to JE-endemic countries and those who will stay longer than 1 month in China. JE vaccination should also be considered for persons who will stay for a shorter period but plan to spend time in rural areas, participate in outdoor activities, or stay in accommodations without air conditioning, window screens, or bed nets.

#### Malaria

In 2021, WHO declared China malaria-free. In the 1940s, China reported >30 million cases of malaria per year. A 70-year eradication campaign progressively reduced numbers. Imported malaria cases still occur, particularly from elsewhere in Southeast Asia. Stopping onward transmission from these imported cases remains a top priority. The risk of malaria transmission in China is very low. Travelers should continue to follow insect-bite precautions (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/mosquitoes-ticks-and-other-arthropods.html) to minimize the risk of infection with other vector-borne diseases.

#### Plague

China has a large and complex natural reservoir of Yersinia pestis, the causative pathogen of plague. By the end of 2021, several natural plague foci were identified in 19 provinces in China. Most epizoic and enzootic transmission occurs in parts of Inner Mongolia, Gansu, and Qinghai in the north and in Yunnan, Sichuan, and Tibet in the south. In 2021, a plague death was reported from Inner Mongolia. Plague is rarely seen in tourists but is a risk to campers, hikers, hunters, spelunkers, and others exposed to wild rodents, flea-infested cats, or flea-infested dogs.

#### Tick-borne encephalitis

Tick-borne encephalitis (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/tick-borne-encephalitis.html) is endemic in northern and western China, including the mountain areas in Heilongjiang, Jilin, Inner Mongolia, and Xinjiang. Transmission also occurs in southwestern areas in Tibet and Yunnan. Persons who are planning hiking or camping trips from mid-April to July in forested areas are at highest risk. Consider offering vaccination to travelers who have itineraries that will include outdoor activities in forested areas (see Box 11.3.1.2). Even among vaccinated travelers, reinforce the importance of taking preventive measures (e.g., wearing long pants tucked into socks, using insect repellent, and regularly checking for ticks).

Box 11.3.1.2 Visiting a giant panda reserve in Sichuan Province: Health considerations for travelers ★

The giant panda (Ailuropoda melanoleuca) is China’s national emblem and one of the country’s most iconic images. Native to south-central China, the giant panda’s natural habitat has been greatly encroached upon, and only a small number of these animals now exist in the wild, in remote areas where seeing them is almost impossible. In response, the Chinese government established over 60 giant panda reserves across southwestern China. Travel to Sichuan Province to visit one or more of these habitats and to see the stunning scenery has become increasingly popular. In some locations, especially during the hot summer months, giant pandas spend much time inside, viewable only through glass. The Sichuan giant panda reserves were designated a UNESCO World Heritage site in 2006.

###### Chengdu research base of giant panda breeding

Located just 10 km (approximately 6 miles) north of the city of Chengdu, the Chengdu Research Base of Giant Panda Breeding is a well-developed park. In some reserves (including the Chengdu Research Base), visitors can get closer to the animals by joining a Panda Volunteer program. Participation in these programs is generally available only to adults and must be arranged and paid for in advance. Programs can vary from 1 day to 1 month in length, and some might require participants to provide certification of good health. Opportunities to photograph the giant pandas can be limited.

###### Animal bites

Despite their cute and cuddly appearance, giant pandas are wild animals with a very powerful bite (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/zoonotic-exposures.html). They can also be infected with rabies (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/rabies.html). Travelers should avoid any temptation to get close to giant pandas for a selfie or a hug. Sichuan Province also has a large population of free-roaming dogs, posing a risk for rabies transmission. Travelers to Sichuan should consider rabies pre-exposure prophylaxis.

###### Elevation and terrain of giant panda reserves

The region has many smaller reserves, some of which are peri-urban, others of which can be quite remote and require considerable travel or trekking, making them inaccessible to physically challenged or less physically fit travelers. The giant panda reserves are located at elevations ranging from 1,100 m (approximately 3,600 ft) to 4,400 m (approximately 14,400 ft), often in rugged terrain. Advise tourists visiting reserves at high elevations (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/high-altitude-travel-and-altitude-illness.html) to acclimatize slowly and to consider carrying acetazolamide.

###### Road travel risks apply to these more remote reserves

Travelers to less-urban reserves should be prepared for remoteness and should travel with a well-stocked travel health kit (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travel-health-kits.html).

###### Food and water precautions and sanitation

Travelers to Sichuan Province should follow safe food and water precautions (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/food-and-water-precautions-for-travelers.html). Travelers should only drink bottled water. Bottled water can easily be purchased at convenience stores and restaurants. Flush toilets may not be available.

## Environmental hazards and risks

### Air pollution

Rapid economic expansion and industrialization since 1978 has resulted in serious air pollution issues, along with water and soil contamination. To tackle air pollution, China introduced several policies and measures targeted at reducing emissions and promoting alternative energy production. Other measures included closing highly polluting factories, moving factories farther away from population centers, reforestation projects, and promoting the use of electric vehicles. These measures have resulted in a dramatic reduction in air pollution, particularly in fine particulate matter (PM2.5). Although air quality in Beijing has greatly improved overall, air pollution remains a problem in many parts of the country. In 2022, many of the world’s 200 cities with the worst air quality were in China. Hazardous air quality can occasionally occur following large sandstorms originating from southern Mongolia. These sandstorms—which are unpredictable—can blanket Beijing and neighboring provinces with a layer of dust and other air pollutants. Travelers can check the 5-day air quality forecasts (https://www.aqicn.org/map/china).

Short-term exposure to the levels of air pollution in China’s megacities can irritate the eyes and throat. Travelers with cardiovascular or chronic respiratory conditions, children, and older adults are the most likely to be affected by particle pollution exposure. In addition, exposure to high levels of air pollution significantly increases the risk for upper and lower respiratory tract infections, including otitis, sinusitis, bronchitis, and pneumonia.

Even before the COVID-19 pandemic, surgical-style facemasks were commonplace in China’s large cities, especially in Beijing, Hong Kong, and Shanghai. However, facemasks do not provide protection from fine particulate matter in air pollution. Properly fitted N95 masks can filter out these particulates and might be advisable for people determined to engage in outdoor activities at times when air quality (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/air-quality-and-ionizing-radiation-during-travel.html) is very poor. To reduce daily exposure, many facilities, particularly schools, have installed sophisticated central air-filtering devices and have constructed enclosed sports venues.

### Altitude illness

Western China is home to some of the tallest mountains in the world. Some popular destinations are Xining (2,295 m; 7,500 ft), Lijiang (2,418 m; 7,900 ft), Shangri-La (Zhongdian) (3,280 m; 11,000 ft), and Lhasa (3,658 m; 12,000 ft). Advise travelers on the importance of a gradual ascent and taking time to acclimatize to prevent the onset of altitude illness (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/high-altitude-travel-and-altitude-illness.html).

Visitors planning high-altitude travel whose itineraries do not permit gradual acclimatization— or people otherwise known to be at risk for developing acute mountain sickness—should carry their own supply (https://www.cdc.gov/yellow-book/hcp/preparing-international-travelers/travel-health-kits.html) of acetazolamide because availability in China is currently unreliable.

### Animal bites and rabies

An analysis of data collected by the GeoSentinel Surveillance Network indicates that dog bites (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/zoonotic-exposures.html) are common among tourists to China. Animal rabies (https://www.cdc.gov/yellow-book/hcp/travel-associated-infections-diseases/rabies.html) is endemic in China, especially among the free-roaming dog population. Human rabies deaths in China have decreased substantially since peaking in 2007. This decline is mainly attributable to increased public awareness and use of post-exposure prophylaxis. Rabies viruses have also been detected in several wildlife species, including the Chinese ferret badger, raccoon dog, and various bats species. The risk of human rabies exposure remains highest in Hubei, Hunan, Guangxi, and Guizhou Provinces.

Travelers should consider any dog or other mammal bite received anywhere in China, including urban areas, a high risk for rabies infection. Because international-standard rabies immune globulin is often unavailable, animal bites can force travelers to end their trips prematurely, requiring evacuation to Bangkok, Hong Kong, or home, to receive appropriate post-exposure prophylaxis. Younger children are more likely to experience a rabies exposure due to their inherent curiosity about animals. However, everyone is at risk; an American adult citizen died from rabies following a dog bite while traveling in Guangdong Province in 2019. A discussion about the risk of rabies and strategies for dealing with possible exposures should be held during pre-travel consultations. With the recent shortening of the pre-exposure regimen (2 doses, 1 week apart), barriers to pre-exposure rabies vaccination have been considerably reduced. Strongly consider providing travelers to rural communities, long-term travelers, and expatriates going to live in China with the rabies pre-exposure vaccination series. All travelers should also consider purchasing medical evacuation insurance coverage (https://www.cdc.gov/yellow-book/hcp/health-care-abroad/travel-insurance.html).

### Natural disasters

In the last few decades, China has experienced earthquakes, heat waves, droughts, forest and grassland fires, hailstorms, red tides, sandstorms, and torrential rains resulting in damaging landslides. Typhoons and storm surges occur regularly along the southern and eastern seaboard.

The heat wave in the summer of 2023 in Eastern China was close to the longest and hottest on record, creating an influx of emergency room visits for heat stroke. Air conditioning may not be reliable in all locations. Travelers, particularly those with existing chronic cardiovascular conditions, are strongly encouraged to reduce outdoor activities and increase fluid intake during prolonged periods of excessive heat (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/heat-and-cold-illness-in-travelers.html). An earthquake struck the western province of Sichuan in 2009, killing more than 90,000 persons and causing devastating damage to schools, homes, and businesses. Less severe and minor earthquakes are common in China; in 2023, a 5.5 magnitude earthquake occurred near the city of Dezhou, about 300 km south of Beijing. Advise U.S. citizen travelers to enroll with the Department of State’s Smart Traveler Enrollment Program (https://step.state.gov/step) (STEP); STEP will provide travelers with information and alerts from local U.S. embassies or consulates about disasters, safety, and security issues at their destination.

### Wet markets

“Wet markets” are common throughout China and many other parts of Asia. The term “wet market” is a generic one, encompassing many types of marketplaces selling perishable goods; some sell only fruits and vegetables, while others sell live animals that are slaughtered on-site after purchase.

Because the exotic animal trade has been banned in China, most wet markets do not sell wild or exotic animals. However, smuggling of animals (e.g., pangolins) is highly profitable and can be difficult to control. Travelers should avoid visiting markets selling live animals due to the risk of zoonotic disease spill-over (i.e., spread of animal diseases to humans), such as coronaviruses and avian influenza.

## Safety and security

### Crime

In major cities, expansive video security systems have been established, resulting in low rates of violent crime, thefts, and pickpocketing. However, various forms of scams and fraud, targeting foreign businesses and tourists, can and do occur. Travelers should remain vigilant and avoid responding to emails from unknown contacts as well as giving out sensitive information to unfamiliar sources.

### Political unrest

Travelers should be aware of and avoid involvement in protests and flare-ups of unrest in places as diverse as Hong Kong, Tibet, and Xinjiang. Travelers also should avoid public criticism of the Communist Party or the government. More information about political and religious activity can be found on the U.S. Department of State travel website (https://www.travel.state.gov/content/travel/en/international-travel/International-Travel-Country-Information-Pages/China.html).

### Traffic-related injuries

Traffic in China can be chaotic. The rate of traffic crashes (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/injury-and-death-during-travel.html#cdc_report_pub_study_section_1-road-traffic-injuries), including fatal ones, is among the highest in the world. Traffic accidents are one of the leading causes of death in China for children 6–18 years of age. Traffic crashes, even minor ones, can create major traffic jams and sometimes turn into violent altercations, particularly when foreign travelers are involved (see Safety and Security Overseas (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/safety-and-security-overseas.html)).

China has not signed the convention that created the International Driving Permit and requires travelers to have a Chinese license to drive. Recent regulations have allowed foreign travelers to obtain a temporary (≤3 months) driver’s license if they possess a valid overseas driver’s license, have a notarized copy translated into Chinese, and attend lessons on Chinese road safety regulations. Persons must be at least 18 years of age to legally drive in China.

Driving is on the right side of the road in mainland China and Taiwan but on the left side in Hong Kong and Macau. Advise travelers to avoid driving at night or when weather conditions are bad. Also, ensure that they do not assume that traffic rules are the same everywhere or that right-of-way will be respected. Despite national seat belt legislation being in effect since 2004, seat belt use is inconsistent, and rear seat belts are often unavailable. The use of child safety seats has recently become mandatory. For all these reasons, travelers should strongly consider hiring a local driver or using public transportation rather than driving themselves. Travelers should take care when opening the door of a taxi or private vehicle, to avoid hitting cyclists or pedestrians.

Despite the best efforts of municipal governments and green-developers, most of the urban centers in China are not yet pedestrian-friendly. As a pedestrian, travelers should defer right-of-way to vehicles and double-check at intersections for oncoming traffic before crossing, regardless of the traffic signals.

### Electronic bicycles and bike-sharing

Electronic bicycles (E-bikes) provide a low-cost mode of transportation and are popular in China. A driver’s license is not required. However, since 2019, all E-bikes must be registered. Registration requirements vary by municipality. Because E-bikes have no engine noise, pedestrians might not readily identify an oncoming E-bike, and crashes and injuries have increased. A 2020 law requiring helmet use for riders of motorcycles and E-bikes resulted in a shortage of available helmets. Helmet use on E-bikes remains inconsistent.

Bike-sharing has increased substantially during the last several years in major municipalities, including Beijing, Chengdu, Guangzhou, Shanghai, and Tianjin. Several bike-sharing companies exist in the same market, each requiring a smartphone app linked to a local phone number. If able to access the apps, travelers should check the brakes, steering column, and seat stability when selecting a shared bicycle. Bicycle helmets are not required but are advisable. Travelers should consider bringing their own motorcycle or bicycle helmets.

## Availability and quality of medical care

Strongly encourage travelers to invest in travel health insurance (https://www.cdc.gov/yellow-book/hcp/health-care-abroad/travel-insurance.html), including medical evacuation insurance coverage. Many hospitals do not accept foreign medical insurance, and patients are expected to pay a deposit to cover the anticipated cost of treatment before care is delivered. Many major cities, including Beijing, Guangzhou, Hong Kong, Shanghai, and Shenzhen, have medical facilities that meet international standards. Hospitals in other cities might have “VIP wards” (gaogan bingfang) with English-speaking staff. The standard of care in such facilities is somewhat unpredictable, however, and cultural and regulatory differences can cause difficulties for travelers. In rural areas, rudimentary medical care might be all that is available.

### Blood and blood product safety

The blood supply is heavily regulated and generally deemed safe. Since implementation of the 1998 Blood Donation Law, all blood and blood products must be tested before transfusion in medical institutes to ensure safety. Due to low blood donation rates, however, supply can be limited, especially for rare types, including Rhesus negative blood. Large regional variations exist in the blood supply, with acute shortages more likely in Western China. RhoGAM is available in Hong Kong, and recently in Shenzhen under a new program permitting drugs and medical equipment already marketed in Hong Kong to be used in the Guangdong-Hong Kong-Macau “Greater Bay Area” after approval. Hepatitis B and hepatitis C virus transmission from poorly sterilized medical equipment remains a risk in remote areas.

### Emergency medical services

Emergency medical services are scarce in many parts of China, most acutely in rural areas (see Injury and Death During Travel (https://www.cdc.gov/yellow-book/hcp/environmental-hazards-risks/injury-and-death-during-travel.html)). In major cities, 2 types of ambulances are available: general ambulances and ambulances that carry more advanced medical equipment. No recognized paramedic profession exists in China, and ambulances might be staffed instead with doctors or nurses with variable levels of training. In many rural areas, rather than waiting for an ambulance to arrive, injured travelers should strongly consider taking a taxi or other immediately available vehicle to the nearest major hospital.

### Medical tourism

Most people who choose to try traditional Chinese remedies do so uneventfully, albeit while accepting some risk. Remind travelers that acupuncture needles can be a source of blood-borne and skin infections; acupressure might be preferable. Herbal medicine products can be contaminated with heavy metals or pharmaceutical agents. Advise travelers about the dangers of possible interactions with their regular prescription medications.

Prior to the COVID-19 pandemic, China was experiencing an influx of patients from high-income countries seeking treatment (https://www.cdc.gov/yellow-book/hcp/health-care-abroad/medical-tourism.html) not available or licensed in their home countries. International medical tourism to China has not yet recovered post-pandemic.

### Pharmacies

Pharmacies often sell prescription medications over the counter, but these can be counterfeit, substandard, or contaminated. Advise travelers to bring all their regular medications in sufficient quantity. If travelers need more or other medications, recommend that they visit a reputable clinic or hospital. The U.S. Embassy or expatriates may be able to offer city-specific advice. China allows travelers to bring controlled medications (https://www.cdc.gov/yellow-book/hcp/travelers-with-additional-considerations/traveling-with-prohibited-or-restricted-medications.html) into the country in quantities “reasonable for personal use”. Especially for controlled medications, travelers are expected to carry a copy of the written prescription with them and, whenever possible, a signed note from the prescribing physician written on letterhead stationery. A copy of the prescription may be kept by customs or at tourist inspection site officials. Custom officials may hold and request high customs duties for medications sent to China from overseas, even if the medications are for personal use.

## Acknowledgements

The following authors contributed to the previous version of this chapter: Roohallah Changizi and Kate Gaynor.

## SOURCES

CONTENT SOURCE:

National Center for Emerging and Zoonotic Infectious Diseases (NCEZID) (https://www.cdc.gov/ncezid/index.html)

### SOURCES

• Comparison of China’s gross national income per capita. (2023). Ourworldindata.org. https://www.ourworldindata.org/human-development-index.
• Huang, B., Zhao, H., Song, J., Zhao, L., Deng, Y., Wang, W., …Tan, W. (2022). Isolation and characterization of monkeypox virus from the first case of monkeypox: Chongqing Municipality, China, 2022. China CDC Weekly, 4(46), 1019–1024. 10.46234/ccdcw2022.206.36483191
• Li, H., Yao, X., Xu, C., Cong, X., Ju, C., & Shao, K. (2022). Plague risk assessment: China, 2022[J]. China CDC Weekly, 4(20): 417–420. https://weekly.chinacdc.cn/en/article/doi/10.46234/ccdcw2022.096
• World Health Organization/ (2015). WHO position paper on hepatitis E vaccines. Weekly Epidemiologic Record, 18, 185–200.
• Xiang, B., Gao, P., Kang, Y., & Ren, T. (2017). Importation of Zika virus in China: A significant risk in southern China. The Journal of Infection, 74(3), 328–330. 10.1016/j.jinf.2017.01.004.28109676
• Xing, Y., Schmitt, H. J., Arguedas, A., & Yang, J. (2017). Tick-borne encephalitis in China: A review of epidemiology and vaccines. Vaccine, 35(9), 1227–1237. 10.1016/j.vaccine.2017.01.015.28153343