# CDC Contributors

Abbott, Andrew

Abe, Karon

Adams, Laura E.

Albalak, Rachel

Almayahi, Zayid K.

Alvarado-Ramy, Francisco

Angelo, Kristina M.

Anstey, Erica

Arshanapally, Suraj

Atherstone, Christine J.

Ballesteros, Michael F.

Barton Behravesh, Casey

Bonacci, Robert A.

Bonilla, Luis

Brown, Clive M.

Bustamante, Nirma D.

Cahill, Eric S.

Chancey, Rebecca J.

Chang, Arthur

Chard, Anna N.

Charp, Paul A.

Connelly, C. Roxanne

Coronado, Fátima

Cossaboom, Caitlin M.

Cote, Pierre-Olivier

Decenteceo, Francis M.

DePadilla, Lara

Desai, Meghna

Dorough, Layne

Estívariz, Concepción F.

Filardo, Thomas D.

Galang, Romeo R.

Gearhart, Shannon L.

Geissler, Aimee

Gimnig, John E.

Gittinger, Rachel

Goodson, James L.

Gould, Carolyn V.

Gregory, Cria O.

Hall, Aron J.

Halsey, Eric S.

Heitzinger, Kristen

Hill, Vincent

Hills, Susan L.

Hofmeister, Megan G.

Hughes, Michael J.

Jereb, John A.

Kamb, Mary L.

Kasule, Juliet N.

Kidd, Sarah

Knust, Barbara

Kone, Ahoua

Kovacs, Stephanie D.

Kroger, Andrew T.

Leidel, Laura

Lindsey, Nicole P.

Mace, Kimberly E.

Martin, Stacey W.

Mase, Sundari R.

Meaney-Delman, Dana

McCormick, David W.

McNamara, Lucy A.

Mirza, Sara A.

Mitchell, Tarissa

Mitruka, Kiren

Montgomery, Martha P.

Montgomery, Susan P.

Montiel, Sonia

Murthy, Neil

Nicholson, William L.

O'Connor, Lauren

O'Laughlin, Kevin

Ojwang, Joseph

Ortiz, Nancy

Park, Ina U.

Paulin, Heather N.

Paz-Bailey, Gabriela

Pecego da Silva, Ana Carla

Pieracci, Emily G.

Powers, Ann M.

Premjee, Sharmeen

Rainey, Jeanette J.

Reyes, Nimia L.

Ridpath, Alison D.

Roy, Sharon L.

Roy, Sheila C.

Rubis, Amy B.

Sánchez-González, Liliana

Schluter, W. William

Secor, W. Evan

Sircar, Kanta

Shih, David C.

Staples, J. Erin

Stoddard, Robyn A.

Stoney, Rhett J.

Straily, Anne

Szablewski, Christine M.

Tardivel, Kara

Taylor, Melanie M.

Valleau, Molly

VanderEnde, Kristin

Vinjé, Jan

Vivolo-Kantor, Alana

Wallace, Ryan M.

Wallender, Erika

Watkins, Louise K. Francois

Weinberg, Michelle

Wendt, Elizabeth M.

Weng, Mark K.

White, Stefanie

Williams, Cara

Yeh, Michael