# References

1 Demakis JG, McQueen L, Kizer KW, Feussner JR. Quality Enhancement Research Initiative (QUERI): A collaboration between research and clinical practice. Med Care. 2000;38(6 Suppl 1):I17–25.10843267
2 Atkins D, Kilbourne AM, Shulkin D. Moving From discovery to system-wide change: the role of research in a learning health care system: experience from three decades of health systems research in the Veterans Health Administration. Annu Rev Public Health. 2017;38:467–487.28125386
3 Kilbourne AM, Goodrich DE, Miake-Lye I, Braganza MZ, Bowersox NW. Quality Enhancement Research Initiative Implementation Roadmap: Toward Sustainability of Evidence-based Practices in a Learning Health System. Med Care. 2019;57 Suppl 10 Suppl 3:S286–S293.31517801
4 Bindman AB, Pronovost PJ, Asch DA. Funding Innovation in a Learning Health Care System. JAMA. 2018;319(2):119–120.29270611
5 Edmondson AC. Teaming: How Organizations Learn, Innovate, and Compete In the Knowledge Economy. San Francisco, CA: Jossey-Bass; 2012.
6 Hirschhorn LR, Ramaswamy R, Devnani M, Wandersman A, Simpson LA, Garcia-Elorrio E. Research versus practice in quality improvement? Understanding how we can bridge the gap. Int J Qual Health Care. 2018;30(suppl_1):24–28.29447351
7 Nilsen P. Making sense of implementation theories, models and frameworks. Implement Sci. 2015;10:53.25895742
8 National Cancer Institute. Implementation Science at a Glance: A Guide for Cancer Control Practitioners. Washington, D.C.: U.S. Department of Health & Human Services, National Institutes of Health;2019.
9 Rubenstein LV, Mittman BS, Yano EM, Mulrow CD. From understanding health care behavior to improving health care: the QUERI framework for quality improvement. Quality Enhancement Research Initiative. Med Care. 2000;38(6 Suppl 1):I129–141.10843277
10 Stetler CB, McQueen L, Demakis J, Mittman BS. An organizational framework and strategic implementation for system-level change to enhance research-based practice: QUERI Series. Implement Sci. 2008;3:30.18510750
11 Kilbourne AM, Atkins D. Partner or perish: VA health services and the emerging bi-directional paradigm. J Gen Intern Med. 2014;29: Suppl 4:817–819.25355094
12 Kilbourne AM, Elwy AR, Sales AE, Atkins D. Accelerating research impact in a learning health care system: VA’s quality enhancement research initiative in the choice act era. Med Care. 2017;55 Suppl 7 Suppl 1:S4–S12.
13 Shulkin DJ. Beyond the VA crisis--becoming a high-performance network. N Engl J Med. 2016;374(11):1003–1005.26981931
14 Braganza MZ, Kilbourne AM. The Quality Enhancement Research Initiative (QUERI) Impact Framework: measuring the real world impact of implementation science. J Gen Intern Med. (2020). https://doi.org/10.1007/s11606-020-06143-z
15 Graham ID, Logan J, Harrison MB, . Lost in knowledge translation: time for a map? J Contin Educ Health Prof. 2006;26(1):13–24.16557505
16 Greene SM, Reid RJ, Larson EB. Implementing the learning health system: from concept to action. Ann Intern Med. 2012;157(3):207–210.22868839
17 Guise JM, Savitz LA, Friedman CP. Mind the gap: putting evidence into practice in the era of learning health systems. J Gen Intern Med. 2018;33(12):2237–2239.30155611
18 Institute of Medicine. Best Care at Lower Cost: The Path to Continuously Learning Health Care in America. Washington, D.C. The National Academies Press;2012.
19 Field B, Booth A, Ilott I, Gerrish K. Using the Knowledge to Action Framework in practice: a citation analysis and systematic review. Implement Sci. 2014;9:172.25417046
20 Horwitz LI, Kuznetsova M, Jones SA. Creating a learning health system through rapid-cycle, randomized testing. N Engl J Med. 2019;381(12):1175–1179.31532967
21 Langley GJ, Moen RD, Nolan KM, Nolan TW, Norman CL, Provost LP. The Improvement Guide: A Practical Approach to Enhancing Organizational Performance. 2nd ed. San Francisco, CA: Jossey-Bass; 2009.
22 Kraft JM, Mezoff JS, Sogolow ED, Neumann MS, Thomas PA. A technology transfer model for effective HIV/AIDS interventions: science and practice. AIDS Educ Prev. 2000;12:(5 Suppl):7–20.11063066
23 Kochevar LK, Yano EM. Understanding health care organization needs and context. Beyond performance gaps. J Gen Intern Med. 2006;21: Suppl 2:S25–29.16637957
24 Neta G, Glasgow RE, Carpenter CR, . A framework for enhancing the value of research for dissemination and implementation. Am J Public Health. 2015;105(1):49–57.25393182
25 Fernandez ME, Ruiter RAC, Markham CM, Kok G. Intervention mapping: theory- and evidence-based health promotion program planning: perspective and examples. Front Public Health. 2019;7:8.30778382
26 Associates in Process Improvement, Institute for Healthcare Improvement (IHI). Science of Improvement: How to Improve. 2017; http://www.ihi.org/resources/Pages/HowtoImprove/ScienceofImprovementHowtoImprove.aspx. Accessed February 8, 2019.
27 Leeman J, Calancie L, Kegler MC, . Developing theory to guide building practitioners’ capacity to implement evidence-based interventions. Health Educ Behav. 2017;44(1):59–69.26500080
28 Green LW, Ottoson JM, Garcia C, Hiatt RA. Diffusion theory and knowledge dissemination, utilization, and integration in public health. Annu Rev Public Health. 2009;30:151–174.19705558
29 Aarons GA, Sklar M, Mustanski B, Benbow N, Brown CH. “Scaling-out” evidence-based interventions to new populations or new health care delivery systems. Implement Sci. 2017;12(1):111.28877746
30 Curran GM, Bauer M, Mittman B, Pyne JM, Stetler C. Effectiveness-implementation hybrid designs: combining elements of clinical effectiveness and implementation research to enhance public health impact. Med Care. 2012;50(3):217–226.22310560
31 Bodenheimer TS. Find the “bright spots”. Jt Comm J Qual Patient Saf. 2014;40(4):147.24864521
32 Dilling JA, Swensen SJ, Hoover MR, . Accelerating the use of best practices: the Mayo Clinic Model of Diffusion. Jt Comm J Qual Patient Saf. 2013;39(4):167–176.23641536
33 Wilson B, Tseng CL, Soroka O, Pogach LM, Aron DC. Identification of outliers and positive deviants for healthcare improvement: looking for high performers in hypoglycemia safety in patients with diabetes. BMC Health Serv Res. 2017;17(1):738.29145834
34 Washington State Department of Health. Best practices. 2019; https://www.doh.wa.gov/ForPublicHealthandHealthcares/HealthcareProfessionsandFacilities/BestPractices. Accessed August 15, 2019.
35 Clancy C. Creating world-class care and service for our nation’s finest: how Veterans Health Administration Diffusion of Excellence Initiative is innovating and transforming Veterans Affairs health care. Perm J. 2019;23:18.309
36 Vega R, Jackson GL, Henderson B, . Diffusion of Excellence: accelerating the spread of clinical innovation and best practices across the nation’s largest health system. Perm J. 2019;23:18.309.
37 Jackson GL, Cutrona SL, Kilbourne A, White BS, Everett C, Damschroder LJ. Implementation science: helping healthcare systems improve. JAAPA. 2020;33(1):51–53.
38 Elnahal SM, Clancy CM, Shulkin DJ. A framework for disseminating clinical best practices in the VA health system. JAMA. 2017;317(3):255–256.28114562
39 Hayes CW, Goldmann D. Highly Adoptable Improvement: A practical model and toolkit to address adoptability and sustainability of quality improvement initiatives. Jt Comm J Qual Patient Saf. 2018;44(3):155–163.29499812
40 Maratt JK, Kerr EA, Klamerus ML, . Measures used to assess the impact of interventions to reduce low-value care: a systematic review. J Gen Intern Med. 2019.
41 de Vries EF, Struijs JN, Heijink R, Hendrikx RJ, Baan CA. Are low-value care measures up to the task? A systematic review of the literature. BMC Health Serv Res. 2016;16(1):405.27539054
42 Shrank WH, Rogstad TL, Parekh N. Waste in the US health care system: estimated costs and potential for savings. JAMA. 2019;322(15):1501–1509 31589283
43 Berwick DM, Hackbarth AD. Eliminating waste in US health care. JAMA. 2019;322(15):1501–1509.31589283
44 Wang V, Maciejewski ML, Helfrich CD, Weiner BJ. Working smarter not harder: Coupling implementation to de-implementation. Healthc (Amst). 2018;6(2):104–107.29279297
45 Norton WE, Chambers DA, Kramer BS. Conceptualizing de-implementation in cancer care delivery. J Clin Oncol. 2019;37(2):93–96.30407894
46 Grimshaw JM, Patey AM, Kirkham KR, . De-implementing wisely: developing the evidence base to reduce low-value care. BMJ Qual Saf. 2020;29(5):409–417
47 Norton7 WE, Chambers DA. Unpacking the complexities of de-implementing inappropriate health interventions. Implement Sci. 2020;15(1):2.31915032
48 Kilbourne AM, Neumann MS, Pincus HA, Bauer MS, Stall R. Implementing evidence-based interventions in health care: application of the Replicating Effective Programs framework. Implement Sci. 2007;2:42.18067681
49 Allen JD, Shelton RC, Emmons KM, Linnan LA. Fidelity and its relationship to implementation effectiveness, adaptation, and dissemination. In: Brownson RC, Colditz GA, Proctor EK, eds. Dissemination and Implementation Research in Health: Translating Science to Practice. 2nd ed. New York, NY: Oxford University Press; 2018;267–284.
50 Rabin BA, Brownson RC, Haire-Joshu D, Kreuter MW, Weaver NL. A glossary for dissemination and implementation research in health. J Public Health Manag Pract. 2008;14(2):117–123.18287916
51 Dusenbury L, Brannigan R, Falco M, Hansen WB. A review of research on fidelity of implementation: implications for drug abuse prevention in school settings. Health Educ Res. 2003;18(2):237–256.12729182
52 Kelly JA, Heckman TG, Stevenson LY, . Transfer of research-based HIV prevention interventions to community services: fidelity and adaptation. AIDS Educ Prev. 2000;12:(5 Suppl):87–98.11063072
53 Wiltsey Stirman S, Baumann AA, Miller CJ. The FRAME: an expanded framework for reporting adaptations and modifications to evidence-based interventions. Implement Sci. 2019;14(1):58.31171014
54 Chambers DA, Norton WE. The Adaptome: advancing the science of intervention adaptation. Am J Prev Med. 2016;51(4 Suppl 2):S124–131.27371105
55 Washington State Department of Health. Logic models in public health program management. May 2012.
56 Center for Community Health - University of Kansas. Community tool box chapter 2, section 1. Developing a logic model or theory of change. 2018; https://ctb.ku.edu/en/table-of-contents/overview/models-for-community-health-and-development/logic-model-development/main. Accessed 2019, August 15.
57 Petersen D, Taylor PD, Peikes D. Logic models: the foundation to implement, study, and refine patient-centered medical home models. Rockville, MD: Agency for Healthcare Research and Quality;February 2013.
58 Aarons GA, Green AE, Palinkas LA, . Dynamic Adaptation Process to implement an evidence-based child maltreatment intervention. Implement Sci. 2012;7:32.22512914
59 Chambers DA, Glasgow RE, Stange KC. The Dynamic Sustainability Framework: addressing the paradox of sustainment amid ongoing change. Implement Sci. 2013;8:117.24088228
60 Rohrbach LA, Grana R, Sussman S, Valente TW. Type II translation: transporting prevention interventions from research to real-world settings. Eval Health Prof. 2006;29(3):302–333.16868340
61 Bauman AA, Cabassa LJ, Wiltsey-Stirman S. Adaptation in dissemination and implementation science. In: Brownson RC, Colditz GA, Proctor EK, eds. Dissemination and Implementation Research in Health: Translating Science to Practice. 2nd ed. New York: Oxford University Press; 2018:285–300.
62 Stirman SW, Gamarra J, Bartlett B, Calloway A, Gutner C. Empirical examinations of modifications and adaptations to evidence-based psychotherapies: methodologies, impact, and future directions. Clin Psychol. 2017;24(4):396–420.
63 Wiltsey Stirman S, Gutner CA, Crits-Christoph P, Edmunds J, Evans AC, Beidas RS. Relationships between clinician-level attributes and fidelity-consistent and fidelity-inconsistent modifications to an evidence-based psychotherapy. Implement Sci. 2015;10:115.26268633
64 Powell BJ, Beidas RS, Lewis CC, . Methods to improve the selection and tailoring of implementation strategies. J Behav Health Serv Res. 2017;44(2):177–194.26289563
65 Cancer Prevention and Control Research Network (CPCRN). Session 5: adapting an evidence-based intervention to fit your community. Putting public health evidence in action training workshop. November 2017; http://cpcrn.org/pub/evidence-in-action/.
66 Miller CJ, Wiltsey-Stirman S, Baumann AA. Iterative Decision-making for Evaluation of Adaptations (IDEA): A decision tree for balancing adaptation, fidelity, and intervention impact. J Community Psychol. 2020; https://doi.org/10.1002/jcop.222279.
67 Escoffery C, Lebow-Skelley E, Udelson H, . A scoping study of frameworks for adapting public health evidence-based interventions. Transl Behav Med. 2019;9(1):1–10.29346635
68 Stirman SW, Miller CJ, Toder K, Calloway A. Development of a framework and coding system for modifications and adaptations of evidence-based interventions. Implement Sci. 2013;8:65.23758995
69 Escoffery C, Lebow-Skelley E, Haardoerfer R, . A systematic review of adaptations of evidence-based public health interventions globally. Implement Sci. 2018;13(1):125.30257683
70 Rabin BA, McCreight M, Battaglia C, . Systematic, multi-method assessment of adaptations across four diverse health systems interventions. Front Public Health. 2018;6:102.29686983
71 Proctor EK, Powell BJ, McMillen JC. Implementation strategies: recommendations for specifying and reporting. Implement Sci. 2013;8:139.24289295
72 Glasgow RE, Klesges LM, Dzewaltowski DA, Estabrooks PA, Vogt TM. Evaluating the impact of health promotion programs: using the RE-AIM framework to form summary measures for decision making involving complex issues. Health Educ Res. 2006;21(5):688–694.16945984
73 Chinman M, Woodward EN, Curran GM, Hausmann LRM. Harnessing implementation science to increase the impact of health equity research. Med Care. 2017;55 Suppl 9 Suppl 2:S16–S23.28806362
74 U.S. Department of Veterans Affairs, Veterans Health Administration, VHA Office of Health Equity. Facts about the Office of Health Equity. 2019; https://www.va.gov/HEALTHEQUITY/Facts_About_OHE.asp. Accessed July 20, 2019.
75 McNulty M, Smith JD, Villamar J, . Implementation research methodologies for achieving scientific equity and health equity. Ethn Dis. 2019;29:(Suppl 1):83–92.30906154
76 Woodward EN, Matthieu MM, Uchendu US, Rogal S, Kirchner JE. The health equity implementation framework: proposal and preliminary study of hepatitis C virus treatment. Implement Sci. 2019;14(1):26.30866982
77 Bernal G, Bonilla J, Bellido C. Ecological validity and cultural sensitivity for outcome research: issues for the cultural adaptation and development of psychosocial treatments with Hispanics. J Abnorm Child Psychol. 1995;23(1):67–82.7759675
78 Hawkins RP, Kreuter M, Resnicow K, Fishbein M, Dijkstra A. Understanding tailoring in communicating about health. Health Educ Res. 2008;23(3):454–466.18349033
79 Damschroder LJ, Aron DC, Keith RE, Kirsh SR, Alexander JA, Lowery JC. Fostering implementation of health services research findings into practice: a consolidated framework for advancing implementation science. Implement Sci. 2009;4:50.19664226
80 Benzer JK, Charns MP, Hamdan S, Afable M. The role of organizational structure in readiness for change: A conceptual integration. Health Serv Manage Res. 2017;30(1):34–46.28166670
81 Edmondson AC. The competitive imperative of learning. Harv Bus Rev. 2008;86(7-8):60–67, 160.
82 Herzer KR, Pronovost PJ. Physician motivation: listening to what pay-for-performance programs and quality improvement collaboratives are telling us. Jt Comm J Qual Patient Saf. 2015;41(11):522–528.26484685
83 Leeman J, Calancie L, Hartman MA, . What strategies are used to build practitioners’ capacity to implement community-based interventions and are they effective?: a systematic review. Implement Sci. 2015;10:80.26018220
84 Bartholomew-Eldredge LK, Markham CM, Ruiter RAC, Femandez ME, Kok g, Parcel GS. Planning Health Promotion Programs: An Intervention Mapping Approach. 4th ed. San Francisco, CA: Jossey-Bass;2016.
85 Sullivan JL, Adjognon OL, Engle RL, . Identifying and overcoming implementation challenges: Experience of 59 noninstitutional long-term services and support pilot programs in the Veterans Health Administration. Health Care Manage Rev. 2018;43(3):193–205.28125459
86 Chuang E, Jason K, Morgan JC. Implementing complex innovations: factors influencing middle manager support. Health Care Manage Rev. 2011;36(4):369–379.21691212
87 Edmondson AC, Reynolds SS. Building the Future: Big Teaming for Audacious Innovation. Oakland, CA: Berrett-Koehler Publishers, Inc; 2016.
88 Willis CD, Saul J, Bevan H, . Sustaining organizational culture change in health systems. J Health Organ Manag. 2016;30(1):2–30.26964847
89 Birken SA, Lee SY, Weiner BJ, Chin MH, Chiu M, Schaefer CT. From strategy to action: how top managers’ support increases middle managers’ commitment to innovation implementation in health care organizations. Health Care Manage Rev. 2015;40(2):159–168.24566252
90 Hagedorn H, Hogan M, Smith JL, . Lessons learned about implementing research evidence into clinical practice. Experiences from VA QUERI. J Gen Intern Med. 2006;21: Suppl 2:S21–24.
91 Giannitrapani KF, Rodriguez H, Huynh AK, . How middle managers facilitate interdisciplinary primary care team functioning. Healthc (Amst). 2019;7(2):10–15.30765317
92 Engle RL, Lopez ER, Gormley KE, Chan JA, Charns MP, Lukas CV. What roles do middle managers play in implementation of innovative practices? Health Care Manage Rev. 2017;42(1):14–27.26488239
93 Miake-Lye I, Mak SS, Lambert-Kerzner AC, . Scaling Beyond Early Adopters: A Systematic Review and Key Informant Perspectives. Washington (DC): Department of Veterans Affairs (US); 2019.
94 Gardner KL, Dowden M, Togni S, Bailie R. Understanding uptake of continuous quality improvement in Indigenous primary health care: lessons from a multi-site case study of the Audit and Best Practice for Chronic Disease project. Implement Sci. 2010;5:21.20226066
95 Lorig KR, Hurwicz ML, Sobel D, Hobbs M, Ritter PL. A national dissemination of an evidence-based self-management program: a process evaluation study. Patient Educ Couns. 2005;59(1):69–79.16198220
96 Ramanadhan S, Davis MM, Armstrong R, . Participatory implementation science to increase the impact of evidence-based cancer prevention and control. Cancer Causes Control. 2018;29(3):363–369.29417296
97 Goodman MS, Sanders Thompson VL. The science of stakeholder engagement in research: classification, implementation, and evaluation. Transl Behav Med. 2017;7(3):486–491.28397159
98 Midboe AM, Elwy AR, Durfee JM, . Building strong research partnerships between public health and researchers: a VA case study. J Gen Intern Med. 2014;29: Suppl 4:831–834.25355082
99 Bergman AA, Delevan DM, Miake-Lye IM, Rubenstein LV, Ganz DA. Partnering to improve care: the case of the Veterans’ Health Administration’s Quality Enhancement Research Initiative. J Health Serv Res Policy. 2017:1355819617693871.
100 Stein BD, Adams AS, Chambers DA. A learning behavioral health care system: opportunities to enhance research. Psychiatr Serv. 2016;67(9):1019–1022.27133723
101 Kirchner JE, Kearney LK, Ritchie MJ, Dollar KM, Swensen AB, Schohn M. Research & services partnerships: lessons learned through a national partnership between clinical leaders and researchers. Psychiatr Serv. 2014;65(5):577–579.24585229
102 Sales A, Smith J, Curran G, Kochevar L. Models, strategies, and tools. Theory in implementing evidence-based findings into health care practice. J Gen Intern Med. 2006;21: Suppl 2:S43–49.16637960
103 Leeman J, Birken SA, Powell BJ, Rohweder C, Shea CM. Beyond “implementation strategies”: classifying the full range of strategies used in implementation science and practice. Implement Sci. 2017;12(1):125.29100551
104 Colquhoun H, Leeman J, Michie S, . Towards a common terminology: a simplified framework of interventions to promote and integrate evidence into health practices, systems, and policies. Implement Sci. 2014;9:51.24885553
105 Fernandez ME, Ten Hoor GA, van Lieshout S, . Implementation mapping: using intervention mapping to develop implementation strategies. Front Public Health. 2019;7:158.31275915
106 Scaccia JP, Cook BS, Lamont A, . A practical implementation science heuristic for organizational readiness: your = MC(2). J Community Psychol. 2015;43(4):484–501.26668443
107 Flaspohler P, Duffy J, Wandersman A, Stillman L, Maras MA. Unpacking prevention capacity: an intersection of research-to-practice models and community-centered models. Am J Community Psychol. 2008;41(3-4):182–196.18307028
108 Rogers EM. Diffusion of Innovations. 5th ed. New York: Free Press; 2003.
109 Wilson MG, Lavis JN, Travers R, Rourke SB. Community-based knowledge transfer and exchange: helping community-based organizations link research to action. Implement Sci. 2010;5:33.20423486
110 Wandersman A, Chien VH, Katz J. Toward an evidence-based system for innovation support for implementing innovations with quality: tools, training, technical assistance, and quality assurance/quality improvement. Am J Community Psychol. 2012;50(3-4):445–459.22538406
111 Sales A. Implementation Science: The Basics. Workshop presentation delivered in Kuala Lumpur: University of Malaya; August 2019.
112 Moullin JC, Dickson KS, Stadnick NA, Rabin B, Aarons GA. Systematic review of the Exploration, Preparation, Implementation, Sustainment (EPIS) framework. Implement Sci. 2019;14(1):1.30611302
113 Stetler CB, Damschroder LJ, Helfrich CD, Hagedorn HJ. A Guide for applying a revised version of the PARIHS framework for implementation. Implement Sci. 2011;6:99.21878092
114 Sales A. Theories and models: pragmatic frameworks and systematic approaches to intervention design. Presentation delivered at the Training Institute for Dissemination and Implementation in Health, Bethesda, MD. 2015
115 McCreight MS, Gilmartin HM, Leonard CA, . Practical use of process mapping to guide implementation of a care coordination program for rural veterans. J Gen Intern Med. 2019;34:(Suppl 1):67–74.31098974
116 Antonacci G, Reed JE, Lennox L, Barlow J. The use of process mapping in healthcare quality improvement projects. Health Serv Manage Res. 2018;31(2):74–84.29707978
117 Knox K, Brach C. Module 5. Mapping and Resdesigning Work-flow. In. Practice Facilitation Handbook. Rockville, MD: Agency for Healthcare Research and Quality; May 2018.
118 Hagley G, Mills PD, Watts BV, Wu AW. Review of alternatives to root cause analysis: developing a robust system for incident report analysis. BMJ Open Qual. 2019;8(3):e000646.
119 Tabak RG, Khoong EC, Chambers DA, Brownson RC. Bridging research and practice: models for dissemination and implementation research. Am J Prev Med. 2012;43(3):337–350.22898128
120 Bennett B, Provost L. What’s your theory? Qual Progrss. 2015;48:36.
121 Michie S, Richardson M, Johnston M, . The behavior change technique taxonomy (v1) of 93 hierarchically clustered techniques: building an international consensus for the reporting of behavior change interventions. Ann Behav Med. 2013;46(1):81–95.23512568
122 Kok G, Gottlieb NH, Peters GJ, . A taxonomy of behaviour change methods: an Intervention Mapping approach. Health Psychol Rev. 2016;10(3):297–312.26262912
123 Carey RN, Connell LE, Johnston M, . Behavior change techniques and their mechanisms of action: a synthesis of links described in published intervention literature. Ann Behav Med. 2019;53(8):693–707.30304386
124 Connell LE, Carey RN, de Bruin M, . Links between behavior change techniques and mechanisms of action: an expert consensus study. Ann Behav Med. 2019;53(8):708–720.30452535
125 Michie S, van Stralen MM, West R. The behaviour change wheel: a new method for characterising and designing behaviour change interventions. Implement Sci. 2011;6:42.21513547
126 Powell BJ, Waltz TJ, Chinman MJ, . A refined compilation of implementation strategies: results from the Expert Recommendations for Implementing Change (ERIC) project. Implement Sci. 2015;10:21.25889199
127 Waltz TJ, Powell BJ, Matthieu MM, . Use of concept mapping to characterize relationships among implementation strategies and assess their feasibility and importance: results from the Expert Recommendations for Implementing Change (ERIC) study. Implement Sci. 2015;10:109.26249843
128 Perry CK, Damschroder LJ, Hemler JR, Woodson TT, Ono SS, Cohen DJ. Specifying and comparing implementation strategies across seven large implementation interventions: a practical application of theory. Implement Sci. 2019;14(1):32.30898133
129 Oliva EM, Christopher MLD, Wells D, . Opioid overdose education and naloxone distribution: Development of the Veterans Health Administration’s national program. J Am Pharm Assoc (2003). 2017;57(2S):S168–S179 e164.28292502
130 U.S. Centers for Disease Control and Prevention Division for Heart Disease and Stroke Prevention, State Heart Disease and Stroke Prevention Program. Evaluation guide: developing and using a logic model. 2020; https://www.cdc.gov/dhdsp/docs/logic_model.pdf. Accessed January 10, 2020.
131 Petersen D, Taylor EF, Peikes D. Logic Models: The Foundation to Implementation, Study, and Refine Patient-Centered Medical Home Models. Rockville, MD: Agency for Healthcare Research and Quality;Feburary 2013.
132 McCawley PF. The logic model for program planning and evaluation. 2001. https://www.extension.uidaho.edu/publishing/pdf/CIS/CIS1097.pdf.
133 Lyon AR, Bruns EJ. User-centered redesign of evidence-based psychosocial interventions to enhance implementation-hospitable soil or better seeds? JAMA Psychiatry. 2018.
134 Lyon AR, Munson SA, Renn BN, . Use of human-centered design to improve implementation of evidence-based psychotherapies in low-resource communities: protocol for studies applying a framework to assess usability. JMIR Res Protoc. 2019;8(10):e14990.31599736
135 Dopp AR, Parisi KE, Munson SA, Lyon AR. A glossary of user-centered design strategies for implementation experts. Transl Behav Med. 2019;9(6):1057–1064.30535343
136 Lyon AR, Koerner K. User-centered design for psychosocial Intervention development and implementation. Clin Psychol (New York). 2016;23(2):180–200.29456295
137 Hempel S, O’Hanlon C, Lim YW, Danz M, Larkin J, Rubenstein L. Spread tools: a systematic review of components, uptake, and effectiveness of quality improvement toolkits. Implement Sci. 2019;14(1):83.31426825
138 Baumann AA, Morshed AB, Tabak RG, Proctor EK. Toolkits for dissemination and implementation research: Preliminary development. J Clin Transl Sci. 2018;2(4):239–244.30820360
139 U. S. Department of Health and Human Services, Centers for Disease Control and Prevention, Office of the Director, Office of Strategy and Innovation. Introduction to program evaluation for public health programs: a self-study guide. Atlanta, GA: Centers for Disease Control and Prevention; October 2011: https://www.cdc.gov/eval/guide/cover/index.htm.
140 Parry G, Coly A, Goldmann D, . Practical recommendations for the evaluation of improvement initiatives. Int J Qual Health Care. 2018;30(suppl_1):29–36.29447410
141 Leviton LC, Khan LK, Rog D, Dawkins N, Cotton D. Evaluability assessment to improve public health policies, programs, and practices. Annu Rev Public Health. 2010;31:213–233.20235852
142 Wholey JS. Assessing the feasibility and likely usefulness of evaluation. In: Wholey JS, Hatry HP, Newcomber KE, eds. Handbook of Practical Program Evaluation. 2nd ed. San Francisco: Jossey-Bass; 2004:33–62.
143 U.S. House of Representatives, 113th Congress. H. R. 1287 - Sound Science Act of 2013. 2013; https://www.congress.gov/bill/113th-congress/house-bill/1287. Accessed August 17, 2015.
144 U.S. House of Representatives, 114th Congress. H. R. 185 - Regulatory Accountability Act of 2015. 2015; https://www.congress.gov/bill/114th-congress/house-bill/185/text. Accessed August 17, 2015.
145 United States 115th Congress. Public Law No. 115-435: Foundations for Evidence-based Policymaking Act of 2018. In. Washington D.C. 2019.
146 Kilbourne A, Atkins D. Evidence-based policy making: balancing rigor with real-world health care for veterans and military personnel. N C Med J. 2015;76(5):339–342.26946871
147 Parker LE, Kirchner JE, Bonner LM, . Creating a quality-improvement dialogue: utilizing knowledge from frontline staff, managers, and experts to foster health care quality improvement. Qual Health Res. 2009;19(2):229–242.19092141
148 Gray CP, Yakir M, Hung DY. Physician engagement with metrics in lean primary care transformation. Qual Manag Health Care. 2018;27(3):117–122.29944622
149 Miller CJ, Smith SN, Pugatch M. Experimental and quasi-experimental designs in implementation research. Psychiatry Res. 2019.
150 Mazzucca S, Tabak RG, Pilar M, . Variation in research designs used to test the effectiveness of dissemination and implementation strategies: a review. Front Public Health. 2018;6:32.29515989
151 Brown CH, Curran G, Palinkas LA, . An overview of research and evaluation designs for dissemination and implementation. Annu Rev Public Health. 2017;38:1–22.28384085
152 Lewis E, Baumann A, Gerke D, . D&I research designs, eight toolkits related to dissemination and implementation research in cancer (DIRC). July 2017; https://sites.wustl.edu/wudandi. Accessed May 1, 2019.
153 Coly A, Parry G. Evaluating Complex Health Interventions: A guide to rigorous research designs. June 2017; https://www.academy-health.org/evaluationguide. Accessed August 2, 2017.
154 Portela MC, Pronovost PJ, Woodcock T, Carter P, Dixon-Woods M. How to study improvement interventions: a brief overview of possible study types. BMJ Qual Saf. 2015;24(5):325–336.
155 Handley MA, Lyles CR, McCulloch C, Cattamanchi A. Selecting and improving quasi-experimental designs in effectiveness and implementation research. Annu Rev Public Health. 2018;39:5–25.29328873
156 Frakt AB, Prentice JC, Pizer SD, . Overcoming challenges to evidence-based policy development in a large, integrated delivery system. Health Serv Res. 2018;53(6):4789–4807 29862494
157 Belin TR, Jones A, Tang L, . Maintaining internal validity in community partnered participatory research: experience from the community partners in care study. Ethn Dis. 2018;28:(Suppl 2):357–364.30202188
158 Allen H, Baicker K, Taubman S, Wright B, Finkelstein A. The Oregon health insurance experiment: when limited policy resources provide research opportunities. J Health Polit Policy and Law. 2013;38(6):1183–1192.23974473
159 Proctor E, Silmere H, Raghavan R, . Outcomes for implementation research: conceptual distinctions, measurement challenges, and research agenda. Adm Policy Ment Health. 2011;38(2):65–76.20957426
160 Proctor EK, Landsverk J, Aarons G, Chambers D, Glisson C, Mittman B. Implementation research in mental health services: an emerging science with conceptual, methodological, and training challenges. Adm Policy Ment Health. 2009;36(1):24–34.19104929
161 Martin L, Nelson E, Rakover J, Chase A. Whole System Measures 2.0: A Compass for Health System Leaders. Cambridge, MA: Institute for Healthcare Improvement;2016.
162 Institute of Medicine (IOM). Crossing the Quality Chasm: A New Health System for the 21st Century. Washington D.C.: National Academy Press;2001.
163 Gerke D, Lewis E, Prusaczyk B, Baumann A, Proctor E. Implementation outcomes toolkit. Eight toolkits related to dissemination and implementation research in cancer (DIRC). July 2017; https://sites.wustl.edu/wudandi. Accessed January 17, 2019.
164 Glasgow RE, Vogt TM, Boles SM. Evaluating the public health impact of health promotion interventions: the RE-AIM framework. Am J Public Health. 1999;89(9):1322–1327.10474547
165 McCreight MS, Rabin BA, Glasgow RE, . Using the Practical, Robust Implementation and Sustainability Model (PRISM) to qualitatively assess multilevel contextual factors to help plan, implement, evaluate, and disseminate health services programs. Transl Behav Med. 2019.
166 Feldstein AC, Glasgow RE. A practical, robust implementation and sustainability model (PRISM) for integrating research findings into practice. Jt Comm J Qual Patient Saf. 2008;34(4):228–243.18468362
167 Holtrop JS, Rabin BA, Glasgow RE. Qualitative approaches to use of the RE-AIM framework: rationale and methods. BMC Health Serv Res. 2018;18(1):177.29534729
168 Glasgow RE, Estabrooks PE. Pragmatic applications of RE-AIM for health care initiatives in community and clinical settings. Prev Chronic Dis. 2018;15:E02.29300695
169 Glasgow RE, Askew S, Purcell P, . Use of RE-AIM to Address Health Inequities: Application in a low-income community health center based weight loss and hypertension self-management program. Transl Behav Med. 2013;3(2):200–210.23750180
170 Aron DC, Tseng CL, Soroka O, Pogach LM. Balancing measures: identifying unintended consequences of diabetes quality performance measures in patients at high risk for hypoglycemia. Int J Qual Health Care. 2018.
171 Powell BJ, Fernandez ME, Williams NJ, . Enhancing the Impact of Implementation Strategies in Healthcare: A Research Agenda. Front Public Health. 2019;7:3.30723713
172 Eisman AB, Kilbourne AM, Dopp AR, Saldana L, Eisenberg D. Economic evaluation in implementation science: Making the business case for implementation strategies. Psychiatry Res. 2020;283.
173 Smith MW, Barnett PG. The role of economics in the QUERI program: QUERI Series. Implement Sci. 2008;3:20.18430199
174 Neumann PJ, Sanders GD, Russell LB, Siegel JE, T.G. G, eds. Cost-effectiveness in health and medicine. 2nd ed. New York: Oxford University Press. 2016.
175 Sanders GD, Neumann PJ, Basu A, . Recommendations for conduct, methodological practices, and reporting of cost-effectiveness analyses: second panel on cost-effectiveness in health and medicine. JAMA. 2016;316(10):1093–1103.27623463
176 Sullivan SD, Mauskopf JA, Augustovski F, . Budget impact analysis-principles of good practice: report of the ISPOR 2012 Budget Impact Analysis Good Practice II Task Force. Value Health. 2014;17(1):5–14.24438712
177 Ritzwoller DP, Sukhanova A, Gaglio B, Glasgow RE. Costing behavioral interventions: a practical guide to enhance translation. Ann Behav Med. 2009;37(2):218–227.19291342
178 Saldana L, Chamberlain P, Bradford WD, Campbell M, Landsverk J. The cost of implementing new strategies (COINS): a method for mapping implementation resources using the stages of implementation completion. Child th Serv Rev. 2014;39:177–182.
179 Hamilton AB, Finley EP. Qualitative methods in implementation research: An introduction. Psychiatry Res. 2019;280:112516.31437661
180 Cohen D, Crabtree BF, Damschroder L, . Qualitative methods in implementation science. Bethesda, MD: National Cancer Institute, Division of Cancer Control and Population Sciences, U.S. Department of Health and Human Services, National Institutes of Health. 2018.
181 Corbin JM, Strauss AL. Basics of Qualitative Research. 4th ed. Thousand Oaks, CA: Sage Publications, Inc. 2015.
182 Palinkas LA, Horwitz SM, Green CA, Wisdom JP, Duan N, Hoagwood K. Purposeful sampling for qualitative data collection and analysis in mixed method implementation research. Adm Policy Ment Health. 2015;42(5):533–544.24193818
183 Palinkas LA, Mendon SJ, Hamilton AB. Innovations in mixed methods evaluations. Annu Rev Public Health. 2019;40:423–442.30633710
184 Bauer MS, Damschroder L, Hagedorn H, Smith J, Kilbourne AM. An introduction to implementation science for the non-specialist. BMC Psychol. 2015;3:32.26376626
185 Elwy AR, Wasan AD, Gilman AG, . Using formative evaluation methods to improve clinical implementation efforts: Description and an example. Psychiatry Res. 2019:112532.31477261
186 Stetler CB, Legro MW, Wallace CM, . The role of formative evaluation in implementation research and the QUERI experience. J Gen Intern Med. 2006;21: Suppl 2:S1–8.
187 Finley EP, Huynh AK, Farmer MM, . Periodic reflections: a method of guided discussions for documenting implementation phenomena. BMC Med Res Methodol. 2018;18(1):153.30482159
188 Moore GF, Audrey S, Barker M, . Process evaluation of complex interventions: Medical Research Council guidance. BMJ. 2015;350:h1258.25791983
189 Dorr DA, Cohen DJ, Adler-Milstein J. Data-driven diffusion of innovations: successes and challenges in 3 large-scale innovative delivery models. Health Aff (Millwood). 2018;37(2):257–265.29401031
190 Kilbourne AM, Abraham KM, Goodrich DE, . Cluster randomized adaptive implementation trial comparing a standard versus enhanced implementation intervention to improve uptake of an effective re-engagement program for patients with serious mental illness. Implement Sci. 2013;8:136.24252648
191 Kilbourne AM, Almirall D, Goodrich DE, . Enhancing outreach for persons with serious mental illness: 12-month results from a cluster randomized trial of an adaptive implementation strategy. Implement Sci. 2014;9:163.25544027
192 Abraham KM, Mach J, Visnic S, McCarthy JF. Enhancing treatment reengagement for veterans with serious mental illness: evaluating the effectiveness of SMI Re-Engage. Psychiatr Serv. 2018;69(8):887–895.29793395
193 National State Auditors Association. Best practices in performance measurement Part 1: Developing performance measures. Lexington, KY: National State Auditors Association. 2004.
194 MacLean CH, Kerr EA, Qaseem A. Time out - charting a path for improving performance measurement. N Engl J Med. 2018;378(19):1757–1761.29668361
195 Compton-Phillips A, Mohta NS. Care redesign survey: how data and analytics improve clinical care. NEJM Catalyst. 2019(February):18. https://catalyst.nejm.org/data-and-analytics-improve-clinical-care/. Accessed May 2, 2019.
196 Academy Health, Office of the National Coordinator for Health Information Technology, Health EA. Collecting quality data for performance management: A learning guide In. March 2017: https://www.academyhealth.org/publications/2017-03/collecting-quality-data-performance-management-learning-guide.
197 Powell BJ, Stanick CF, Halko HM, . Toward criteria for pragmatic measurement in implementation research and practice: a stakeholder-driven approach using concept mapping. Implement Sci. 2017;12(1):118.28974248
198 Glasgow RE. What does it mean to be pragmatic? Pragmatic methods, measures, and models to facilitate research translation. Health Educ Behav. 2013;40(3):257–265.23709579
199 McGinnis JM, Malphrus E, Blumenthal D. Vital Signs: Core Metrics for Health and Health Care Progress. Washington, D.C.: National Academies Press. 2015.
200 McNamara P, De La Mare D, Ivers N. Confidential Physician Feedback Reports: Designing for Optimal Impact on Performance. Rockville, MD: Agency for Healthcare Research and Quality. 2016.
201 Cohen DJ, Dorr DA, Knierim K, . Primary care practices’ abilities and challenges in using electronic health record data for quality improvement. Health Aff (Millwood). 2018;37(4):635–643.29608365
202 Kirchner JE, Smith JL, Powell BJ, Waltz TJ, Proctor EK. Getting a clinical innovation into practice: an introduction to implementation strategies. Psychiatr Res. 2019.
203 Bunger AC, Powell BJ, Robertson HA, MacDowell H, Birken SA, Shea C. Tracking implementation strategies: a description of a practical approach and early findings. Health Res Policy Syst. 2017;15(1):15.28231801
204 Craig P, Dieppe P, Macintyre S, . Developing and evaluating complex interventions: new guidance. London: Medical Research Council;2019; https://mrc.ukri.org/documents/pdf/developing-and-evaluating-complex-interventions/
205 Rogal SS, Yakovchenko V, Waltz TJ, . Longitudinal assessment of the association between implementation strategy use and the uptake of hepatitis C treatment: Year 2. Implement Sci. 2019;14(1):36.30961615
206 Waltz TJ, Powell BJ, Fernandez ME, Abadie B, Damschroder LJ. Choosing implementation strategies to address contextual barriers: diversity in recommendations and future directions. Implement Sci. 2019;14(1):42.31036028
207 Beidas RS, Kendall PC. Training therapists in evidence-based practice: a critical review of studies from a systems-contextual perspective. Clin Psychol. 2010;17(1):1–30.
208 Grimshaw JM, Thomas RE, MacLennan G, . Effectiveness and efficiency of guideline dissemination and implementation strategies. Health Technol Assess. 2004;8(6):iii–iv, 1–72.
209 Wensing M, Grol R. Methods to identify implementation problems. In: Grol R, Wensing M, Eccles M, Davis D, eds. Improving Patient Care: The Implementation of Change in Health Care. Chichester: John Wiley & Sons, Inc. 2005:165–184.
210 Birken SA, Powell BJ, Shea CM, . Criteria for selecting implementation science theories and frameworks: results from an international survey. Implement Sci. 2017;12(1):124.29084566
211 Baker R, Camosso-Stefinovic J, Gillies C, . Tailored interventions to address determinants of practice. Cochrane Database Syst Rev. 2015;(4):CD005470. Published 2015 Apr 29. doi:10.1002/14651858.CD005470.pub3 25923419
212 Scheirer MA. Linking sustainability research to intervention types. Am J Public Health. 2013;103(4):e73–80.
213 Flottorp SA, Oxman AD, Krause J, . A checklist for identifying determinants of practice: a systematic review and synthesis of frameworks and taxonomies of factors that prevent or enable improvements in healthcare professional practice. Implement Sci. 2013;8:35.23522377
214 Dearing JW, Cox JG. Diffusion of innovations theory, principles, and practice. Health Aff (Millwood). 2018;37(2):183–190.29401011
215 Lewis CC, Klasnja P, Powell BJ, . From classification to causality: advancing understanding of mechanisms of change in implementation science. Front Public Health. 2018;6:136.29868544
216 Glanz K, Rimer BK. Theory at a glance: a guide for health promotion practice. In. 2nd ed. Washington, D.C.: National Cancer Institute, National Institutes of Health, U. S. Department of Health and Human Services. 2005.
217 Kilbourne AM, Almirall D, Eisenberg D, . Protocol: Adaptive Implementation of Effective Programs Trial (ADEPT): cluster randomized SMART trial comparing a standard versus enhanced implementation strategy to improve outcomes of a mood disorders program. Implement Sci. 2014;9:132.25267385
218 Rogal SS, Yakovchenko V, Waltz TJ, . The association between implementation strategy use and the uptake of hepatitis C treatment in a national sample. Implement Sci. 2017;12(1):60.28494811
219 Stewart RE, Beidas RS, Mandell DS. Stop calling them laggards: strategies for encouraging nonadopters to incorporate evidence-based practices. Psychiatr Serv. 2019;70(10):958–960.31242831
220 Ritchie MJ, Dollar KM, Miller CJ, . Implementation Facilitation Training Manual: Using Implementation Facilitation to Improve Care in the Veterans Health Administration (Version 2). 2017; https://www.queri.research.va.gov/tools/implementation.cfm. Accessed January 1, 2019.
221 Kilbourne AM, Goodrich DE, Lai Z, . Reengaging veterans with serious mental illness into care: preliminary results from a national randomized trial. Psychiatr Serv. 2015;66(1):90–93.25554233
222 Institute of Medicine (IOM). Spread, scale, and sustainability in population health: workshop summary. Washington, D.C.: The National Academies Press. 2015.
223 Barker PM, Reid A, Schall MW. A framework for scaling up health interventions: lessons from large-scale improvement initiatives in Africa. Implement Sci. 2016;11:12.26821910
224 Nolan K, Schall MW, Erb F, Nolan T. Using a framework for spread: The case of patient access in the Veterans Health Administration. Jt Comm J Qual Patient Saf. 2005;31(6):339–347.15999964
225 Aarons GA, Green AE, Trott E, . The roles of system and organizational leadership in system-wide evidence-based intervention sustainment: a mixed-method study. Adm Policy Ment Health. 2016;43(6):991–1008.27439504
226 Greenhalgh T, Papoutsi C. Spreading and scaling up innovation and improvement. BMJ. 2019;365:l2068.31076440
227 Milat AJ, Bauman A, Redman S. Narrative review of models and success factors for scaling up public health interventions. Implement Sci. 2015;10:113.26264351
228 Kizer KW, Demakis JG, Feussner JR. Reinventing VA health care: systematizing quality improvement and quality innovation. Med Care. 2000;38(6 Suppl 1):I7–16.10843266
229 Institute of Medicine (IOM). Spread, scale, and sustainability in population health: Workshop summary. Washington, D.C.: The National Academies Press. 2015.
230 McCannon J. Accelerating spread and scale in population health. From contemplation to action: keys to getting started and scaling efficiently. The Institute of Medicine Roundtable on Population Health Outcomes: A Workshop on Spread and Scale. Hunter College. New York City, NY. 2014.
231 House RJ. A path-goal theory of leadership effectiveness. Admin Sci Q. 1971;16:321–328.
232 Waldman DA, Bass BM, Yammarino FJ. Adding to contingent-reward behavior: augmenting effect of charismatic leadership. Group and Organizational Studies. 1990;15:381–394.
233 Aarons GA. Transformational and transactional leadership: association with attitudes toward evidence-based practice. Psychiatr Serv. 2006;57(8):1162–1169.16870968
234 Bass BM. Good, better, best. Leadership and performance beyond expectations. New York: Free Press. 1985.
235 Aarons GA, Sommerfeld DH. Leadership, innovation climate, and attitudes toward evidence-based practice during a statewide implementation. J Am Acad Child Adolesc Psychiatry. 2012;51(4):423–431.22449648
236 Solimeo SL, Ono SS, Lampman MA, Paez MB, Stewart GL. The empowerment paradox as a central challenge to patient centered medical home implementation in the veteran’s health administration. J Interprof Care. 2015;29(1):26–33.25052920
237 Keroack MA, ngberg BJ, Cerese JL, Krsek C, Prellwitz LW, Trevelyan EW. Organizational factors associated with high performance in quality and safety in academic medical centers. Acad Med. 2007;82(12):1178–1186.18046123
238 Institute for Healthcare Improvement (IHI). The Breakthrough Series: IHI’s Collaborative Model for Achieving Breakthrough Improvement. Cambridge, MA: Institute for Healthcare Improvement. 2003.
239 Edmondson AC. Psychological safety and learning behavior in work teams. Adm Sci Q. 1999;44(2):350–383.
240 Duhigg C. What Google learned from its quest to build the perfect team. The New York Times Magazine. February 25, 2016. https://www.nytimes.com/2016/02/28/magazine/what-google-learned-from-its-quest-to-build-the-perfect-team.html. Accessed October 25, 2018.
241 Edmondson AC, Zhike L. Psychological safety: the history, renaissance, and future of an interpersonal construct. Annu Rev Organ Psychol Organ Behav. 2014;1:23–43.
242 Yanchus NJ, Derickson R, Moore SC, Bologna D, Osatuke K. Communication and psychological safety in veterans health administration work environments. J Health Organ Manag. 2014;28(6):754–776.25420355
243 Derickson R, Fishman J, Osatuke K, Teclaw R, Ramsel D. Psychological safety and error reporting within Veterans Health Administration hospitals. J Patient Saf. 2015;11(1):60–66.24583957
244 Persaud DD. Designing a performance measurement system for accountability, quality improvement, and innovation. Health Care Manag (Frederick). 2019;38(1):82–88.30640235
245 Shewhart WA. Statistical method from the viewpoint of quality control. Lancaster, PA: Lancaster Press. 1939.
246 Deming WE. The New Economics for Industry, Government, Education. 2nd ed. Cambridge, MA: Massachusetts Institute of Technology, Center for Advanced Engineering Study. 1993.
247 Scheirer MA, Dearing JW. An agenda for research on the sustainability of public health programs. Am J Public Health. 2011;101(11):2059–2067.21940916
248 Shelton RC, Cooper BR, Stirman SW. The sustainability of evidence-based interventions and practices in public health and health care. Annu Rev Public Health. 2018;39:55–76.29328872
249 Wiltsey Stirman S, Kimberly J, Cook N, Calloway A, Castro F, Charns M. The sustainability of new programs and innovations: a review of the empirical literature and recommendations for future research. Implement Sci. 2012;7:17.22417162
250 Holweg M, Staats BR, Upton DM. Making process improvements stick. 2018:18. https://dx.doi.org/10.2139/ssrn.3240097. Accessed June 1, 2019.
251 Kearsley-Ho EL, Yang HY, Karunananthan S, Laur C, Grimshaw JM, Ivers NM. When do trials of diabetes quality improvement strategies lead to sustained change in patient care? BMJ Qual Saf. 2019.
252 Bowman CC, Sobo EJ, Asch SM, Gifford AL, HIV/Hepatitis Quality Enhancement Research Initiative. Measuring persistence of implementation: QUERI Series. Implement Sci. 2008;3:21.18430200
253 Hailemariam M, Bustos T, Montgomery B, Barajas R, Evans LB, Drahota A. Evidence-based intervention sustainability strategies: a systematic review. Implement Sci. 2019;14(1):57.31171004
254 Orton S, Menkens AJ. Business planning for public health from the North Carolina Institute for Public Health. J Public Health Manag Pract. 2006;12(5):489–492.16912616
255 Justice Research and Statistics Association. Sustaining Evidence-based Practices. Washington, D.C.: Bureau of Justice Assistance, Office of Justice Programs, U.S. Department of Justice;December 2015.
256 Dopp AR, Mundey P, Beasley LO, Silovsky JF, Eisenberg D. Mixed-method approaches to strengthen economic evaluations in implementation research. Implement Sci. 2019;14(1):2.30635001
257 Wolfson D, Santa J, Slass L. Engaging physicians and consumers in conversations about treatment overuse and waste: a short history of the Choosing Wisely campaign. Acad Med. 2014;89(7):990–995.24979166
258 Kerr EA, Hofer TP. Deintensification of routine medical services: the next frontier for improving care quality. JAMA Intern Med. 2016;176(7):978–980.27272959
259 Colla CH, Mainor AJ, Hargreaves C, Sequist T, Morden N. Interventions aimed at reducing use of low-value health services: a systematic review. Med Care Res Rev. 2017;74(5):507–550.27402662
260 Whittington MD, Ho PM, Helfrich CD. Recommendations for the use of audit and feedback to ed-implement low-value care. Am J Med Qual. 2019:1062860618824153.
261 McKay VR, Morshed AB, Brownson RC, Proctor EK, Prusaczyk B. Letting go: conceptualizing intervention de-implementation in public health and social service settings. Am J Community Psychol. 2018;62(1-2):189–202.29971792
262 Sacarny A, Barnett ML, Agrawal S. New evidence on stemming low value prescribing. NEJM Catalyst. 2019;April 10. https://catalyst.nejm.org/new-evidence-stemming-overprescribing/.
263 Baker DW, Qaseem A, Reynolds PP, Gardner LA, Schneider EC, American College of Physicians Performance Measurement C. Design and use of performance measures to decrease low-value services and achieve cost-conscious care. Ann Intern Med. 2013;158(1):55–59.23108285
264 Kerr EA, Klamerus ML, Markovitz AA, . Identifying recommendations for stopping or scaling back unnecessary routine services in primary care. JAMA Intern Med. Published online September 14, 2020. doi:10.1001/jamainternmed.2020.4001
265 Johnson K, Hayes C, Center H, Daley C. Building capacity and sustainable prevention innovations: a sustainability planning model. Evaluation and Program Planning. 2004;27:135–149.
266 Swensen SJ, Dilling JA, Mc Carty PM, Bolton JW, Harper CM, Jr. The business case for health-care quality improvement. J Patient Saf. 2013;9(1):44–52.23429226
267 Roberts SLE, Healey A, Sevdalis N. Use of health economic evaluation in the implementation and improvement science fields-a systematic literature review. Implement Sci. 2019;14(1):72.31307489
268 Raghavan R. The role of economic evaluation in dissemination and implementation research. In: Brownson R, Colditz G, Proctor E, eds. Dissemination and Implementation Research in Health: Translating Science to Practice. New York: Oxford University Press; 2018:89–106.
269 Bodenheimer T, Sinsky C. From triple to quadruple aim: care of the patient requires care of the provider. Ann Fam Med. 2014;12(6):573–576.25384822
270 Stiefel M, Nolan K. A Guide to Measuring the Triple Aim: Population Health, Experience of Care, and Per Capita Cost. IHI Innovation Series white paper. 2012. http://www.ihi.org/resources/Pages/IHIWhite-Papers/AGuidetoMeasuringTripleAim.aspx.
271 Belperio PS, Chartier M, Ross DB, Alaigh P, Shulkin D. Curing hepatitis C virus infection: best practices from the U.S. Department of Veterans Affairs. Ann Intern Med. 2017;167(7):499–504.28973196
272 Koczwara B, Stover AM, Davies L, . Harnessing the synergy between improvement science and implementation science in cancer: a call to action. J Oncol Pract. 2018;14(6):335–340.29750579
273 Nilsen P, Bernhardsson S. Context matters in implementation science: a scoping review of determinant frameworks that describe contextual determinants for implementation outcomes. BMC Health Serv Res. 2019;19(1):189.30909897
274 Atkins L, Francis J, Islam R, . A guide to using the Theoretical Domains Framework of behaviour change to investigate implementation problems. Implement Sci. 2017;12(1):77.28637486
275 Saint S, Kowalski CP, Banaszak-Holl J, Forman J, Damschroder L, Krein SL. How active resisters and organizational constipators affect health care-acquired infection prevention efforts. Jt Comm J Qual Patient Saf. 2009;35(5):239–246.19480375
276 Bearman G, Stevens MP. Pushing beyond resistors and constipators: implementation considerations for infection prevention best practices. Curr Infect Dis Rep. 2014;16(1):388.24407546
277 Community Health Scholars. Program goals and competencies. http://www.kellogghealthscholars.org/about/community/.php#competencies.
278 National Cancer Institute, Division of Cancer Control & Population Sciences. What are constructs? April 28, 2008; https://cancercontrol.cancer.gov/brp/research/constructs/what-are-constructs.html.
279 Norton WE, Kennedy AE, Chambers DA. Studying de-implementation in health: an analysis of funded research grants. Implement Sci. 2017;12(1):144.29202782
280 National Institutes for Health. Dissemination and implementation research in health. 2017; https://grants.nih.gov/grants/guide/pafiles/PAR-18-007.html.
281 Chambers DA, Vinson CA, Norton WE. Advancing the Science of Implementation Across the Cancer Continuum. New York, NY: Oxford University Press; 2019.
282 U.S. Centers for Disease Control and Prevention (CDC). Understanding the interactive systems framework for dissemination and implementation. Applying science. Advancing practice (ASAP). https://www.cdc.gov/violenceprevention/pdf/ASAP_Issue-a.pdf.
283 Wandersman A, Duffy J, Flaspohler P, . Bridging the gap between prevention research and practice: the interactive systems framework for dissemination and implementation. Am J Community Psychol. 2008;41(3-4):171–181.18302018
284 Agency for Healthcare Research and Quality. Lean. https://heal-thit.ahrq.gov/health-it-tools-and-resources/evaluation-resources/workflow-assessment-health-it-toolkit/all-workflow-tools/lean. Accessed July 17, 2019.
285 Olsen LA, Aisner D, McGinnis JM, Institute of Medicine (IOM). The Learning Healthcare System: Workshop Summary. Washington, D.C.: The National Academies Press;2007.
286 Institute of Medicine (IOM). Best Care at lower cost: The path to continuously learning health care in America. Washington D.C.: The National Academies Press;2013.
287 U.S. Centers for Disease Control and Prevention (CDC), Program Performance and Evaluation Office. Logic Models. 2020; https://www.cdc.gov/eval/logicmodels/index.htm. Accessed January 15, 2020.
288 Nembhard IM, Edmondson AC. Psychological safety: a foundation for speaking up, collaboration, and experimentation in organizations. In: Spreitzer GM, Cameron KS, eds. The Oxford Handbook of Positive Organizational Scholarship. New York: Oxford University Press; 2012:490–506.
289 Batalden PB, Davidoff F. What is “quality improvement” and how can it transform healthcare? Qual Saf Health Care. 2007;16(1):2–3.17301192
290 Health Resources and Services Administration (HRSA). Quality Improvement. April 2011. https://www.hrsa.gov/sites/default/files/quality/toolbox/508pdfs/qualityimprovement.pdf.
291 Simmons R, Fajans P, Ghiron L. Scaling up health service delivery: from pilot interventions to policies and programmes. Geneva, Switzerland: World Health Organzation;2007.
292 Agency for Healthcare Research and Quality. Six Sigma. https://healthit.ahrq.gov/health-it-tools-and-resources/evaluation-resources/workflow-assessment-health-it-toolkit/all-workflow-tools/six-sigma#h=Six%20Sigma. Accessed July 17, 2019.