# Glossary of Terms

ACTIVE RESISTERS: Health care personnel who vigorously and openly oppose implementing changes in clinical practice and whose resistance typically takes one of two forms: 1) difficulty implementing a change that is incompatible with practices that are engrained as the result of prior clinical training or habitual work flows or 2) resistance from competing authorities on whether to implement the new effective practice.^275,276^
ADAPTATION: A process of thoughtful and deliberative alteration of the design or delivery of an effective practice with the aim of improving its fit or effectiveness in a given context.^62,63^
*ADOPTION: A decision to make full use of an effective practice or program as the best course of action available. Also defined as the decision of an organization or community to commit to and initiate an effective practice.^108^
*COMMUNITY-BASED PARTICIPATORY RESEARCH: A collaborative approach to research that equally involves all partners in the research process and recognizes the unique strengths that each brings. Community-based participatory research begins with a research topic of importance to the community and aims to combine knowledge with action to drive social change to improve health outcomes and eliminate health disparities.^277^
*CONSTRUCTS: Concepts developed or adopted for use in a theory. The key concepts of a given theory are its constructs.^278^
*DE-IMPLEMENTATION: Reducing or stopping the use of a guideline, practice, or policy in health care or public health settings.^279^
DESIGN THINKING: A solution-focused, action-oriented approach to solving problems through the application of user/human-centered design strategies.^135^
*DISSEMINATION SCIENCE: The study of targeted distribution of information and intervention materials to a specific public health or effective practice audience. The intent is to understand how best to spread and sustain knowledge and the associated evidence-based interventions.^280^
EFFECTIVE PRACTICE: A health-focused innovation, intervention, program, policy, or technology with evidence from well-conducted scientific research supporting its ability to have a meaningful impact on consumer health behaviors or outcomes while minimizing harms.^281^
*FIDELITY: Degree to which an effective practice is implemented without compromising the core components essential for the practice’s effectiveness.^50,51^
FORMATIVE EVALUATION: A rigorous and active assessment process designed to identify potential and actual influences on the progress, quality and potential sustainment of implementation effort and then use this data to refine, improve, and evolve the implementation process and, in some cases, adapt an implementation and/or effective practice itself; formative evaluation involves assessment prior to, during, and/or after implementation activities to provide data for immediate use to optimize a related implementation effort and for post hoc interpretation of findings.^30,186^
HEALTH DISPARITY: A particular type of health difference that is closely linked with social or economic disadvantage. Health disparities adversely affect groups of people who have systematically experienced greater social and/or economic obstacles to health and/or a clean environment based on: race or ethnicity, gender, age, geographic location, religion, socioeconomic status, sexual orientation, mental health, military service era, cognitive/sensory/physical disability, or other characteristics historically linked to discrimination or exclusion.^74^
*IMPLEMENTATION OUTCOMES: The effects of deliberate and purposive actions to implement new treatments, practices, and services. Implementation outcomes may include acceptability, feasibility, adoption, penetration, appropriateness, cost, fidelity, and sustainability.^159^
*IMPLEMENTATION SCIENCE: The study of methods to promote the adoption and integration of effective practices, interventions, and policies into routine health care and public health settings to improve the impact on population health.^8^
*IMPLEMENTATION STRATEGIES: Methods or techniques to enhance the adoption, implementation, and Sustainment of a program or practice.^71,126^
*KNOWLEDGE SYNTHESIS: A process for obtaining and summarizing scientifically derived information, including evidence of effectiveness (risk and protective factors, core components, and key features, etc.).^282,283^
*KNOWLEDGE TRANSLATION: The process of converting scientific and technically complex research into everyday language and applicable actionable concepts in the practice setting.^282,283^
LOW-VALUE CARE: Health care services or treatments that provide little or no benefit to consumers, have the potential to cause harm, incur unnecessary costs to consumers, or waste limited health care resources.^40,41^
LEAN (also known as the Toyota Production System [TPS]): A systematic method for streamlining a process by identifying and eliminating unnecessary elements of a process that do not contribute value to the desired outcome or the product being created (also known as waste). The seven types of waste are: motion, defects, waiting, over-processing, overproduction, transport and handling, and inventory.^284^
LEARNING HEALTH SYSTEM: Health care systems in which knowledge generation processes are embedded in daily practice to produce continuous improvement in quality care outcomes.^285,286^
LOGIC MODEL: A graphic depiction or roadmap that presents the shared relationships among the resources, activities, outputs, outcomes, and impact for an effective practice; it depicts the relationships among a practice’s activities and its intended effects.^287^
ORGANIZATIONAL CONSTIPATOR: Individuals characterized as mid- to high-level executive leaders who prevent or delay certain implementation actions without active resistance, thereby acting as insidious barriers to change.^275^,^276^
PSYCHOLOGICALLY SAFETY: Individuals’ perceptions related to the degree of interpersonal threat in their work environment^288^ or the belief that a work setting is safe for interpersonal risk taking and that one will not be punished or humiliated for speaking up with ideas, questions, concerns, or mistakes.^239^
PROCESS EVALUATION: A rigorous assessment approach designed to identify potential and actual influences on the conduct and quality of a clinical intervention and/or implementation of an effective practice but in which data are not used during the conduct to influence the process; such data can be collected prior to, during, or after the implementation project.^30^
QUALITY IMPROVEMENT: The systematic and continuous actions by health care professional, consumers and their families, investigators, payers, planners and educators that lead to measurable improvement in health care services and health status of target consumer groups with respect to consumer outcomes (health), better system performances (care), and professional development of the workforce.^289,290^
*REACH: The absolute number, proportion, and representativeness of individuals who participate in a given initiative or receive a specific intervention.^168,169^
*SCALE-UP: Deliberate efforts to increase the spread and use of practices successfully tested in pilot or experimental projects to benefit more people and to foster policy and program development.^291^
*SERVICE EFFECTIVENESS OUTCOMES: Intervention results examined at the system level, including efficiency, safety, effectiveness, equity, consumer centeredness, and timeliness.^160,162^
SIX SIGMA: An organization wide error-reduction technique that relies on statistical analysis and extensively trained project leaders called black belts and green belts. Six sigma explains exactly how managers can best organize the effort to improve the quality and reduce variation and defects in a process.^292^
STAKEHOLDERS: Anyone who has a direct or indirect role in supporting the adoption and use of an effective practice, including senior organizational leaders, managers, clinicians, support staff, and patients as well as their families (consumers).
SUMMATIVE EVALUATION: A rigorous assessment approach that uses data on the impacts, outputs, products, or outcomes to make judgements about the extent to which the effective practice was implemented as planned and resulted in the desired degree of success, effectiveness, or goal achievement of an implemented effective practice.^30,186^
*SUSTAINMENT: The continued use of program components and activities to achieve desirable outcomes.^247^
USABILITY: The extent to which a product can be used by specified users to achieve specified goals with effectiveness, efficiency, and satisfaction in a specified context of use.^135^
USER-CENTERED DESIGN: A design approach that grounds the characteristics of an innovation in information about the individuals who use that innovation, with a goal of maximizing “usability in context.”^135^
USER RESEARCH: Data collection and analyses that are meant to understand the needs, desires, preferences, values, experiences, and recommendations of people who use a particular effective practice.^135^

* From the Glossary of Terms from Implementation Science at a Glance: A Guide for Cancer Control Practitioners by the National Cancer Institute, 2019. https://cancercontrol.cancer.gov/sites/default/files/2020-04/NCI-ISaaG-Workbook.pdf