# Foreword

Welcome to the Quality Enhancement Research Initiative (QUERI) Roadmap for Implementation and Quality Improvement! The QUERI Roadmap combines real-world experience with “state-of-the art” implementation and quality improvement science practices to make this knowledge usable for investigators and practitioners alike. This resource is a practical guide to plan and deploy methods and tools to support health system leaders, managers, and frontline clinicians in promoting the use of effective practices in routine health care settings. Moreover, the QUERI Roadmap aims to help frontline clinicians and staff integrate these practices into routine care using implementation strategies and rigorous evaluation of these efforts to inform policy and improve population health.

The QUERI Implementation Roadmap demystifies implementation science for stakeholders in a learning health system to ensure that effective practices are more rapidly implemented into practice to improve overall health

Health systems in the United States are rapidly changing, and investigators and clinical leaders must meet the needs of consumers and the clinicians who care for them. Since 1998, QUERI has responded to these demands by promoting the use of implementation science to accelerate the adoption of effective practices in routine care settings using a learning health system framework. Learning health systems use health system data to find opportunities to apply effective practices to improve consumer and service outcomes. QUERI has also led the development and application of implementation strategies, which are highly specified, theory-based tools or methods that are designed to help frontline practitioners overcome barriers to using effective practices in routine care settings, or in some cases, de-implement ineffective or low-value practices. Several success stories where QUERI implementation strategies were used to implement effective practices nationally include integrated mental health treatment in primary care, telemedicine for chronic illnesses ranging from PTSD to stroke, and physical activity and caregiver interventions.

We designed the QUERI Roadmap to serve as a practical guide for anyone interested in improving health care. The QUERI Roadmap’s three phases of Pre-implementation, Implementation, and Sustainment involve multidisciplinary stakeholders and rigorous evaluation methods.

- Pre-implementation: Identifies a high-priority need, selects effective practices to address the need, engages stakeholders to build implementation capacity, specifies needed practice adaptations and evaluation goals, and activates leadership support.
- Implementation: Calls for clinical and research leaders to use strategies that support frontline clinician learning and motivate and inspire clinicians to adopt effective practices.
- Sustainment: Includes the analyses that make the business case for sustaining an effective practice and the handoff to local operational leaders to own practice sustainment over time.

We see this QUERI Roadmap as a living document that will ultimately inform and be informed by the implementation and quality improvement initiatives within your health systems and communities. We hope the QUERI Roadmap becomes an essential tool to your work improving care, and we wish you best of luck in your journey!

- Amy M. Kilbourne, PhD, MPH
  Director, Quality Enhancement Research Initiative (QUERI)
  Health Services Research and Development
  Office of Research & Development
  Veterans Health Administration
  United States Department of Veterans Affairs

## Acknowledgements

This Department of Veterans Affairs QUERI Implementation and Quality Improvement Roadmap was developed by the Department of Veterans Affairs Quality Enhancement Research Initiative (QUERI) in collaboration with the Department of Veterans Affairs Health Services Research & Development Evidence Synthesis Program to support partnered initiatives to implement quality improvement innovations and effective practices in health care settings. The views expressed in this document do not necessarily reflect those of the Department of Veterans Affairs.

### Contributors

We would like to thank the many implementation experts, clinicians, and Department of Veterans Affairs operational program partners who contributed content, thoughtful suggestions, and critical feedback as part of the development of this resource.

The following individuals contributed subject matter expertise, tools and resources, case study examples, and/or reviewed the QUERI Road-map: Veronica Williams, MPH, Nicholas W. Bowersox, PhD, (ABBP) VA QUERI Center for Evaluation and Implementation Resources; Catherine Battaglia, PhD, RN; Borsika Rabin PhD, MPH, PharmD; Russ Glasgow, PhD; Marina McCreight, MPH (VA Eastern Colorado Healthcare System); Mark S. Bauer, MD (Boston VA Healthcare System); Diane Hanks, MA (VA Center for Information Dissemination and Education Resources); Austin B. Frakt, PhD, Melissa M. Garrido, PhD; Steven D. Pizer, PhD (VA QUERI Partnered Evidence-based Policy Resource Center); Leslie R. Hausmann, PhD, Shari Rogal, MD, MPH (VA Pittsburgh Healthcare System); JoAnn E. Kirchner, MD (Central Arkansas Veterans Healthcare System); Maureen L. Marks, PhD (VA National Center for Organizational Development); Cynthia K. Perry, PhD, FNP-BC, FAHA (School of Nursing, Oregon Health & Sciences University); Byron J. Powell PhD, LCSW (Brown School at University of Washington in St.Louis); Maria Souden, MSI, PhD; Jenifer Stelmack, MSW; Chandrea Culbreath, MPH: Amanda Taylor, PHD: (VA Information Resource Center); Anne Sales, PhD, RN (VA Ann Arbor Healthcare System); Angela So, MPH; Todd Wagner, PhD (VA HSR&D Health Economics Resource Center); Shannon Wiltsey Stir-man, PhD (National Center for PTSD, Palo Alto VA Health Care System); Thomas J. Waltz, PhD (Eastern Michigan University); and Shawna N. Smith, PHD (Department of Health Management and Policy, University of Michigan School of Public Health).

### Case Study Contributors

We would especially like to express our gratitude to the following individuals who contributed clinical case studies: Shari Rogal MD, MPH (VA Pittsburgh Healthcare System); Vera Yakovchenko PhD, MPH; Pamela Bellino OT (Boston VA Healthcare System); Elizabeth M. Yano PhD, MSPH; Alison Hamilton, PhD, MPH (VA Greater Los Angeles Healthcare System); and Elizabeth Oliva, PhD (Palo Alto VA Health Care System).

### Reviewers

We want to thank the following individuals for sharing critical feedback: Borsika Rabin, PhD, MPH, PharmD (UC San Diego School of Medicine); Rinad Beidas, PhD (University of Pennsylvania Perelman School of Medicine and Penn Implementation Science Center, Leonard Davis Institute of Health Economics); Ashley L. Choate, MPH (Durham VA); Deborah M. Delevan, MA (VA Greater Los Angeles Healthcare System); Alex Dopp, PhD; Lisa V. Rubenstein, MD, MSPH, FACP (RAND Corporation); Margaret Farrell, MPH, RD (National Cancer Institute Division of Cancer Control & Population Sciences); Erin P. Finley, PhD, MPH (South Texas Veterans Health Care System); Kyler M. Godwin, PhD, MPH (National VA Quality Scholars Program); Samantha M. Harden PhD (Virginia Tech); Blake Henderson, BS, Ryan Vega, MD (VA Center for Innovation); Lauren Korshak, MA (VA Office of Health Equity); Nicole Floyd, MPH; Kim Peterson, MS (VA HSR&D Evidence Synthesis Program); Karin Nelson, MD, MSHS (VA Puget Sound Healthcare System); Gretchen A. Piatt, MPH, PhD (University of Michigan Department of Learning Health Sciences); and Lucy A. Savitz, PhD, MBA (Kaiser Permamente Northwest Region).

### Graphic Design and Editorial Assistance

Graphic design support and editorial assistance was provided by: Natalya Wawrin, MSW (VA Center for Clinical Management Research); Sarah Wonders; Amy Miller; Sarah Papke; Shawn Bauguess; and Kyle Morse (Atlas Research/Prometheus Federal Services).

### For More Information

Center for Evaluation and Implementation Resources

Quality Enhancement Research Initiative

U.S. Department of Veterans Affairs

ceir@va.gov

## SUGGESTED READING

Kilbourne AM, Glasgow RE, Chambers DA. What Can Implementation Science Do for You? Key Success Stories from the Field. JGIM (2020)

## Suggested Citation

Goodrich DE, Miake-Lye I, Braganza MZ, Wawrin N, Kilbourne AM. Quality Enhancement Research Initiative. QUERI Roadmap for Implementation and Quality Improvement. United States Department of Veterans Affairs Veterans Health Administration Office of Research and Development Health Services Research and Development, 2020. Available at https://www.queri.research.va.gov/tools/roadmap/