# The QUERI Roadmap

A pragmatic guide on how to adopt, adapt, implement, spread and sustain new clinical practices and innovations across diverse real-world settings

Beating The Odds

Getting Where You Need To Go