# General Resources for Implementation and Quality Improvement

Resources:

- Implementation versus Improvement Science (Quality Improvement)
- Adaptation Guidance Tool
- The Iterative Decision-making for Evaluation of Adaptations (IDEA) Decision Tree
- Abridged Checklist for Conducting Adaptation Interviews
- Detailed FRAME Adaptations and Modifications Checklist
- What’s a Barrier and Facilitator Framework
- List of Expert Recommendations for Implementing Change (ERIC)
- Evaluation and Study Designs for Implementation and Quality Improvement
- Other Resources

## Implementation Science Versus Quality Improvement?

We often hear that implementation science and quality improvement have distinct origins, but they share common concepts. Both fields share overlapping goals and methods, which can make the distinction between the two confusing at times (see Table 24).

The way to distinguish implementation science from quality improvement is to clarify the goal of the project. Many implementation science projects involve the deployment and scale-up of an effective practice or innovation. Quality improvement initiatives involve systematic efforts to improve care processes to reach a clinical priority goal (e.g., decrease infection rates).

Implementation science is the study of methods to promote the adoption and integration of effective practices, interventions, and policies into routine health care and public health settings to improve the impact on population health.^8^

Implementation science addresses the problem of effective practices that are underutilized or adopted too slowly. Implementation scientists work to find and address the quality gaps from these delays at the clinician-, team-, clinic-, or organizational-level and use scientific theories to develop implementation strategies to solve these care deficits.^184^

Implementation strategies are methods or techniques that enhance the adoption, implementation, and sustainment of a program or practice.^71,126^

Quality improvement refers to a range of local facility- to systems-level work to improve the quality, safety, and value of health care services.^272^ Many quality improvement strategies are similar to implementation strategies, such as rapid-cycle testing or consultation by experts.

Quality improvement efforts usually begin with a specific problem (i.e., poor performance) at a local hospital that is recognized at the level of the clinician, clinic, or health system. In turn, improvement teams design and conduct rapid-cycle tests of “interventions” to fix the problem. This improvement may then spread to improve outcomes across the health system.

Quality improvement often relies on tacit knowledge (“real-world wisdom”) of stakeholders and a range of tools and analytical measures to make thoughtful and continual improvements to a problem over time.

Both Implementation strategy studies and quality improvement projects can be considered non-research. See the previous section on determining whether implementation science projects are considered non-research.

Table 24 Concepts, Approaches and Terms Used in Improvement Science and Implementation Science

adapted from^272^

## Adaptation Guidance Tool

When choosing an evidence-based intervention, changes may need to be made to increase fit or compatibility with a specific audience and/or setting. Here is general guidance in terms of things that can and cannot be changed from the original intervention.

Adaptation Guidance

Green | Things that CAN be changed:; Usually minor and made to increase reach, receptivity, and consumer participation
Green | - Names of health care centers or systems; - Pictures of people and places and quotes; - Hard-to-read words that affect reading level; - Wording to be appropriate to audience | - Cultural indicators based on population (e.g., language, pictures, art, scenarios); - Ways to reach and recruit the target audience; - Incentives for participation; - Timeline
Yellow | Things that can be changed with caution:; Typically add or modify practice components and contents versus deleting them
Yellow | - Substituting activities and/or adding new activities; - Changing the order of the curriculum or steps (i.e., sequence); - Altering the length of program activities; - Shifting or expanding the primary audience | - Varying delivery format/process steps; - Modifying who delivers the program; - Adding activities to address other risk factors or behaviors
Red | Things that CANNOT be changed:; Changes to the core components
Red | - The health model, theory, or core logic; - The health topic, behavior; - Core components or whole sections of the program | - Reduction of program; - Timeline; - Dosage (e.g., activities, time/session); - Adding more strategies that detract from the core components

1. *Tool adapted from: Lesesne, C. A., Lewis, K. M., Moore, C., Fisher, D., Green, D., & Wandersman, A. (2007). Promoting Science-based Approaches to Teen Pregnancy Prevention using Getting To Outcomes: Draft June 2007 . Unpublished manual.

2. * Tool adapted from Session 5: Adapting an Evidence-based Intervention to Fit Your Community. Putting Public Health Evidence in Action Training Workshop. Cancer Prevention and Control Research Network: https://cpcrn.org/training. February 2020 .

## Iterative Decision-making for Evaluation of Adaptations (IDEA) Decision Tree

The Iterative Decision-making for Evaluation of Adaptations (IDEA) decision tree is a tool to guide effective practice adaptation that incorporates important decision points and the dynamic nature of ongoing adaptation. Its use is intended to help implementation scientists, clinicians, and administrators maximize effective practice impact.

### References

1 Miller CJ, Wiltsey Stirman S, Baumann A. Iterative Decision-making for Evaluation of Adaptations (IDEA): a decision tree for balancing adaptation, fidelity, and intervention impact. J Community Psychol. 2020;In press. doi: 10.1002/jcop.22279.
2 The F.A.S.T. Lab – The Fidelity, Adaptation, Sustainability, and Training Lab at the VA National Center for PTSD and Stanford University: http://med.stanford.edu/fastlab.html

## Conducting Adaptation Interviews

### Abridged Check List

[image] Who you should interview

- Key staff implementing the clinical practice/program

[image] How to identify key informants

- Identify with help of research staff familiar with local stakeholders
- Include at least 3 staff who have different implementation roles

[image] When to conduct the interview

- A third of the way through the program
- Shortly after conclusion of the program

### Questions to ask about each adaptation

◻ WHAT component, part of the practice or implementation strategy was changed?
◻ HOW would you describe the type of change involved in this adaptation?
◻ WHO was responsible for first suggesting or initiating this change?
◻ WHEN during the XYZ program was this adaptation first made?
◻ HOW or on what BASIS was this change made?
◻ WHY (1): WHY was this adaptation made?
◻ WHY (2): Was this adaptation a result of EXTERNAL factors or INTERNAL issues
◻ WHAT was the short term IMPACT of this adaptation on WHAT outcomes?
◻ OTHER? Probe any other aspects of adaptations that emerge from Interviewee comments

## Framework for Reporting Adaptations and Modifications-Enhanced (FRAME)

### Adaptation Process

#### WHEN did the modification occur?

□ Pre-implementation/planning/pilot
□ Implementation
□ Scale up
□ Maintenance/sustainment

#### Were adaptations PLANNED?

□ Planned/proactive adaptation
□ Planned/reactive adaptation
□ Unplanned/reactive modification

#### WHO participated in the decision to modify?

□ Ex: Political leaders, funder, administrator, community members…
□ Optional: Indicate who made the ultimate decision

#### WHAT is modified/adapted?

□ Content
  Modifications to content or that impact aspects of treatment delivery
□ Contextual
  Modifications to overall way intervention is delivered
□ Training and Evaluations
  Modifications to staff training or how the intervention is evaluated
□ Implementation and scale-up activities Modifications to the strategies used to implement or spread the intervention

#### Contextual adaptations/modifications are made to which of the following?

□ Format
□ Setting
□ Personnel
□ Population

#### At what LEVEL OF DELIVERY (for whom/what is the modification made?)

□ Individual
□ Target intervention group
□ Cohort
□ Individual clinician
□ Clinic/unit level
□ Organization
□ Network System/community

#### What is the nature of the content modification/adaptation?

□ Tailoring/tweaking/refining
□ Changes in packaging or materials
□ Adding/removing/skipping elements
□ Shortening/condensing/lengthening/extending (pacing/timing)
□ Substituting/reordering/spreading of intervention modules or segments
□ Integrating parts of the intervention into another framework
  Relationship to fidelity/core elements?
  □ Fidelity consistent/core elements or functions preserved
  □ Fidelity inconsistent/core elements or functions changed
  □ Unknown
□ Integrating another treatment into EBD
□ Repeating elements or modules
□ Loosening structure
  What was the goal of the adaptation or modification?
  □ Increase reach or engagement
  □ Increase retention
  □ Improve feasibility
  □ Improve fit with recipients
  □ To address cultural factors
  □ Improve effectiveness/outcomes
  □ Reduce cost
  □ Increase satisfaction

### Reasons for Adaptations

#### Socio-political

□ Existing laws
□ Existing mandates
□ Existing policies
□ Existing regulations
□ Political climate
□ Funding policies
□ Historical content
□ Societal/cultural norms
□ Funding or resource allocation/availability

#### Clinician

□ Race/Ethnicity
□ Sexual/gender identity
□ First/spoken languages
□ Previous training and skills
□ Preferences
□ Clinical judgement
□ Cultural norms, competency
□ Perception of intervention

#### Organization/Setting

□ Available resources (funds, staffing, technology, space)
□ Competing demands or mandates
□ Time constraints
□ Service structure
□ Location accessibility
□ Time constraints
□ Regulatory compliance
□ Billing constraints
□ Social context (culture, climate, leadership support)
□ Mission
□ Cultural or religious norms

#### Recipient/Consumer

□ Race/ethnicity
□ Gender identity
□ Sexual orientation
□ Access to resources
□ Cognitive capacity
□ Physical capacity
□ Literacy and education level
□ First/spoken languages
□ Legal status
□ Cultural/multimorbidity
□ Immigration status
□ Crisis or emergent circumstances
□ Motivation and readiness

#### References

1 Stirman SW, Miller CJ, Toder K, Calloway A. Development of a framework and coding system for modifications and adaptations of evidence-based interventions. Implement Sci. 2013;8:65.23758995
2 Wiltsey Stirman S, Baumann AA, Miller CJ. The FRAME: an expanded framework for reporting adaptations and modifications to evidence-based interventions. Implement Sci. 2016;14(1):5
3 The F.A.S.T Lab - The Fidelity, Adaptation, Sustainability, and Training Lab at the VA National Center for PTSD and Stanford University: http://med.stanford.edu/fastlab.html

## What’s a Barrier and Facilitator Framework?

Determinants are contextual factors believed or shown to influence implementation processes or outcomes. They are also referred to as barriers/obstacles or facilitators/enablers to implementation processes.^273^

The purpose of a determinant framework is to:^273^

- Diagnose the reasons why a gap in quality exists
- Understand or explain what influences an implementation process
- Help support decisions about evaluation/measurement (what to assess)
- Build theory in implementation science

A determinant framework is a catalog or checklist of these factors that specifies types, domains, or classes at multiple levels of the health system.

There are dozens of implementation science determinant frameworks^119,273^ that describe relationships between some types of determinants with the aim of helping to understand and/or explain the influence on implementation outcomes.^7^ Examples of types or levels of determinants:

- Intervention characteristics
- Consumer/caregivers/family
- Clinician
- Team/unit/service
- Organization
- System or external environment
- Multi-level (time, financing, leadership, social relations/support)

Some types of determinant frameworks focus on summarizing barriers and facilitators to implementing an effective practice for a type of clinical care or consumer population (e.g., psychosocial interventions for mental health/substance use treatment, cancer care) or delivery of a practice using e-health or m-health technologies.

Other frameworks are informed by one or two underlying theories of individual or organizational behavior change. This helps make sense of the multi-level determinants related to implementing a practice to specific consumer populations or settings.

However, the more widely used frameworks bring together determinants and theoretical constructs from many theories and blend them into a single catalog of relevant factors, levels of assessment, and theory for assessing the implementation of most health care effective practices

Three widely used, “blended” determinant frameworks that are helpful in assessing, organizing, and prioritizing the influence of these factors in a local context include:

Theoretical Domains Framework (TDF)^274^ – An integrative framework that synthesizes 33 psychology theories into 14 domains and 84 constructs that can be used to develop theoretical approaches to interventions aimed at individual-level behavior change.

Consolidated Framework for Implementation Research (CFIR)^79^ – Conceptualizes 39 determinant constructs across five major domains that may affect an intervention’s implementation. They include intervention characteristics, inner setting (of organization), outer setting, characteristics of individuals involved in implementation, and the implementation process itself. For more, see Other Implementation Resources.

Tailored Implementation for Chronic Disease (TICD)^213^ – Uses a checklist with 57 potential individual- and organizational-level determinants of clinical practice improvement grouped into seven domains. These domains include guideline factors, individual health professional factors, professional interactions, incentives, resources, capacity for organizational change, and social-political-legal factors. The implementation includes additional checklists that guide the development of an implementation strategy to address identified determinants.

- Review epidemiological and health services research studies that report on how these multi-level contextual factors (determinants) affect service delivery in the targeted clinical area to understand their relative influence
- Identify and apply relevant theories on emerging and relevant determinants
- Use formative evaluation methods to interview or survey multilevel stakeholders to understand relevant influences using implementation science theories and determinant frameworks to structure questions and guide analyses

For guidance selecting a dissemination or implementation science theory and models to guide your planning process, visit: Dissemination & Implementation Models in Research & Practice (http://www.dissemination-implementation.org/)

## Expert Recommendations for Implementing Change (ERIC)

This collection of definitions for 73 discrete implementation strategies from the ERIC Study^126,127^ includes updated definitions and three new strategies from the evaluation^128^ of the EvidenceNOW Initiative funded by the Agency for Healthcare Research and Quality. Reprinted with permission.

Table 25 Implementation Strategies Organized by Functional Category

Category and Strategy | Definition | Ancillary Lessons Material from ERIC Study and from the Agency for Healthcare Research Quality EvidenceNOW Initiative
Strategies to Develop Stakeholder Relationships
Identify and prepare champions | Identify and prepare individuals who dedicate themselves to supporting, marketing, and driving through an implementation, overcoming indifference or resistance that the effective practice may provoke in an organization. | This strategy includes preparing individuals for their role as champions. Champions are primarily internal to the organization. Additional issues raised include the need for guidance regarding:; a) Methods and considerations related to the selection and identification of champions. Social network theory and methods may be useful in this regard.; b) Training and or providing champions support materials.; c) Addressing incentives or disincentives to the champion role.; d) Whether there are needs for champions at different levels of an organization (e.g., clinic, region, national).; Champions are often distinguished from opinion leaders. Opinion leaders may be considered more of an objective third party with relevant expertise
Organize implementation teams and team meetings | Develop and support teams of clinicians, staff, consumers, and other stakeholders who are implementing or may be users of the effective practice. Provide protected time for teams to reflect on the implementation progress, share lessons learned, make refinements to plans, and support one another’s learning. | None.
Recruit, designate, and train for leadership | Recruit, designate, and train leaders for the change effort. | Change efforts require certain types of leaders, and organizations may need to recruit accordingly, rather than assuming that their current personnel can implement the change. Designated change leaders can include an executive sponsor and a day-to-day manager of the effort. Change leaders should consider how to best establish supervisory lines for effective practices that are enacted by clinicians when the change leader does not have similar clinical responsibilities.
Inform local opinion leaders | Inform clinicians identified by colleagues as opinion leaders or “educationally influential” about the effective practice in the hopes that they will influence colleagues to adopt it. | The opinions of individuals who refer people to services, or who initiate the connection to services also function in a key opinion role. Keeping opinion leaders informed from Pre-implementation through maintenance of the effective practice is important. Ensuring that opinion leaders do not serve as implementation obstacles if they are not actively promoting the effective practice is also important.
Build a coalition | Recruit and cultivate relationships with partners in the implementation effort. | Partnerships can develop around cost-sharing, shared resources, shared training, and the division of responsibilities among partners. This work may proceed naturally from local consensus discussions. Coalition members commonly have defined roles in the implementation effort.
Engage community resources | Connect practices and their consumers to community resources outside the practice (e.g., state and county health departments; nonprofit organizations; resources related to addressing the social determinants of health; and organizations focused on self-management techniques and support). | None.
Obtain formal commitments | Obtain written commitments from key partners that state what they will do to implement the effective practice. | Formal commitments should clarify roles, responsibilities, and communicate tangible and non-tangible benefits (e.g., community partnerships). Ensure that key roles are supported within the organization (e.g., workload release credit for providing and receiving supervision in a new clinical practice). Formal commitments in no way diminish the importance of informal commitments to a change effort.
Identify early adopters | Identify early adopters at the local site to learn from their experiences with the effective practice. | Early adopters are a good pool for identifying implementation champions. Recruit early adopters to attend stakeholder meetings to present their experiences. Investigating the adoption chasm between early adopters and the early majority has been found to be useful. Different engagement techniques for these two groups are typically needed. For further discussion see Moore (2014).
Conduct local consensus discussions | Include local clinicians and other stakeholders in discussions that address whether the chosen problem is important and whether the effective practice to address it is appropriate. | Identify stakeholders relevant to each project. Further, with each project, there will be a need to identify whether the goal of the consensus discussion is to characterize consensus or build consensus. Utilizing community-based participatory research principles may be relevant to many effective practices. Notably, the chosen problem needs to be a high enough priority compared to other problems that attention and resources will be dedicated to addressing the problem.
Capture and share local knowledge | Capture local knowledge from implementation sites on how implementers and clinicians made something work in their setting and then share it with other sites. | This strategy is often coordinated with centralized technical assistance and learning collaboratives. There are multiple techniques for capturing local knowledge, which could be presented in multiple formats. For example, short Tube videos could be created that document testimonials from clinicians who have successfully used a given effective practice. Another example would be maintaining a running list of a team’s response to specific implementation barriers that could be shared readily through a platform like Google Docs or Microsoft SharePoint. Additional techniques can be found at www.liberatingstructures.com.
Use advisory boards and workgroups | Create and engage a formal group of multiple kinds of stakeholders to provide input and advice on implementation efforts and to elicit recommendations for improvements. | Consider how group composition (or heterogeneity) impacts stakeholder participation and take active steps to reduce response bias. For example, inclusion of supervisors and supervisees in these groups can be problematic and it may be a desirable strategy to ensure that these situations are avoided due to the power difference in the relationship. Supervisees, for example, may feel pressure to report positively to put a good face on for the supervisors, and supervisors may feel pressure to deny having any problems with implementation to save face. It can be useful to distinguish between internal stakeholders and representatives (in a participatory approach to maintain buy-in and relevance) versus external experts and advisors. Similarly, depending on the input or oversight need, the workgroup composition may include multiple-level or multidisciplinary stakeholders.
Use an implementation advisor | Seek guidance from experts in implementation, including providing support and training for the implementation work force. | This could include consultation with outside experts such as university-affiliated faculty members or hiring quality improvement experts and/or implementation professionals. Implementation Advisors may provide support and training for facilitators (see Implementation Facilitation) related to broad facilitation skills, how to use and interpret data, or effective use of an electronic health record.
Model and simulate change | Model or simulate the change that will be implemented prior to Implementation. | Computer simulations, walkthrough simulation exercises, or modeling the potential overall impact of stakeholder’s behavior change may be used. System dynamics modeling is one example of a specific method that may be used. This approach is often more relevant for complex multi-component effective practices.
Visit other sites | Visit sites where a similar implementation effort has been considered successful. | Clarifying the goals of the site visit prior to making the visit is particularly useful. Comparing and contrasting the features of one’s own site with the comparison site in preparation for the visit may better inform the visit objectives. Clarifying goals, in part includes developing a plan for using the information upon returning to your setting. Identify adaptations made in implementing the innovation and any perceived impact of the effective practice. It is important to document facilitators and lessons learned. Much can be learned from visiting sites that have a strong track record for successfully implementing a wide variety of other effective practices. Consulting with sites where implementation has stalled or failed can also provide useful information. Sites also benefit from sharing implementation planning and execution notes virtually (i.e., information exchange is not limited to physical visits).
Involve executive boards | Involve existing governing structures (e.g., boards of directors, medical staff boards of governance) in the implementation effort, including the review of data on implementation processes. | Other types of leadership with ‘top-down’ powers may be involved for settings that do not have a governing board. Examples include administrative leadership, clinical leadership, policy makers, and insurance clinicians or other payment systems.
Develop an implementation glossary | Develop and distribute a list of terms describing the effective practice, implementation, and stakeholders in the organizational change. | When compiling a glossary, reflect as to whether the terms being introduced are essential.
Develop academic partnerships | Partner with a university or academic unit for the purposes of shared training and bringing research skills to an implementation project. | The Health Insurance Portability and Accountability Act (HIPAA), and other legal limitations are common to encounter with academic partnerships. Formal relationships (e.g., contracts, memorandums of understanding) will be required in some instances. Not all academics have a full understanding of practice-level stakeholder needs and this should be considered while developing this partnership. In settings where ‘research’ is not a commonly supported practice, evaluation or developmental evaluation may be more useful ways of characterizing the activity.
Promote network weaving | Identify and build on existing high-quality working relationships and networks within and outside the organization, organizational units, teams, etc. to promote information sharing, collaborative problem-solving, and a shared vision/goal related to implementing the effective practice. | Individuals functioning as network weavers usually have external links outside of the community to bring in information and ideas. An example would be nurses and doctors who staff hospitals and skilled nursing facilities, and the consumers who rotate among these facilities. Networks are somewhat more organic than collaboratives and are often enduring and durable. See: http://www.networkweaver.com/
Strategies to Adapt and Tailor to Context
Tailor strategies | Tailor the implementation strategies to address barriers and leverage facilitators that were identified through earlier data collection. | The tailoring process tends to be idiosyncratic and driven by multiple factors. It is important to identify the core components of the effective practice and implementation strategies that are required to maintain fidelity and effectiveness, and to distinguish those components amenable to modification/adaptation. Flottorp et al (2013) and Langley et al. (2009) provide guidance regarding many of the multiple factors to consider. Wensing et al (2011, 2014) provide an example of a structured approach to tailoring strategies.
Promote adaptability | Identify the ways a clinical innovation can be tailored to meet local needs and clarify which elements of the innovation must be maintained to preserve fidelity. | Preserving fidelity to the effective practice can be an uncertain process if the core elements of the innovation are not empirically defined.
Use data experts | Involve, hire, and/or consult experts to acquire, structure, manage, report, and use data generated by implementation efforts. | It is sometimes necessary to engage data experts early in the implementation planning process. Data Experts may be particularly important to enable effective use of data-driven effective practices and to support other strategies such as: Develop Implementation Tools for Quality Monitoring; Develop and Organize Quality-Monitoring Systems; Audit and Provide Feedback; Change Record Systems; and Use Data Warehousing Techniques.
Use data warehousing techniques | Integrate clinical records across facilities and organizations to facilitate implementation across systems. | A key feature of this strategy is linking local data to data platforms outside the local setting. Often the connection is to a central data repository that provides benchmarking capability (see Audit and Provide Feedback) or other aggregation functions. Records that include variables that can serve as outcome measures are particularly useful. When outcomes of interest are not available, it may be useful to examine proxy measures.
Strategies to Use Evaluative and Iterative Strategies
Conduct a local needs assessment | Collect and analyze data related to the need for the effective practice. | This assessment could be focused on:; - Outcomes of usual care; - Process of care; - Description of usual care and its distance from the effective practice (e.g., gaps in care); - Opinions from stakeholders (including consumers) on (a) barriers and facilitators to the desired outcome (e.g., recovery from mental illness); (b) the need for any effective practice (i.e., tension for change); (c) the need for a specific innovation; or (d) the special considerations for delivering the effective practice in the local context.; Common needs assessment methods include surveys, focus groups, key informant interviews, direct observation, and data mining of administrative records utilized to identify priority populations, as well as to identify baseline care process and outcome clinical care data. If the change involves multiple sites or facilities, then it is necessary to examine practice variation across facilities and outline strategies for the needs assessment to support a standardized approach across sites. Collecting data from a random sample of stakeholders may be necessary to reduce response bias and decrease chances that the level of need is not over- or under-estimated.
Obtain and use consumers and family feedback | Develop strategies to increase consumer and family feedback on the implementation effort. | This can continue throughout the implementation effort. Strategies could include complaint forms that funnel feedback to change managers or advisory boards. Consider whether anonymous feedback formats are appropriate.
Assess for readiness and identify barriers and facilitators | Assess various aspects of an organization to determine its degree of readiness to implement an effective practice, identify barriers that may impede implementation, and determine strengths that can be leveraged to facilitate the implementation effort. | Readiness assessments may focus on agency finances, staffing levels, and other material or logistical resources needed, or available, to support the implementation effort. This assessment may also focus on leadership support, the organizational priority for change, and the presence of successful experience with quality improvement techniques and change management. Additional aspects for assessment may include other services provided, as well as community support, stakeholder attitudes, and beliefs and perceptions of evidence for the effective practice. Rationale for current practices, organizational climate and culture, structure, decision-making styles, and the perceived needs of frontline stakeholders to implement the effective practice (consider adaptation needs and limits) are also important aspects to consider in this assessment. Readiness assessments can be used to vet, eliminate, or prioritize implementation sites. More so, the assessment can help inform internal decisions about whether to go ahead with an implementation initiative. Some barriers can be difficult to observe prior to implementation. Specific measures have been created to assess readiness for change, which may be useful. This strategy does not include Assess and Redesign Workflow.
Develop an implementation blueprint | Develop a formal implementation blueprint that includes all goals and strategies. The blueprint should include the following: 1) aim/purpose of the implementation; 2) scope of the change (e.g., what organizational units are affected); 3) timeframe and milestones; and 4) appropriate performance/progress measures. Use and update this plan to guide the implementation effort over time. | The implementation blueprint or manual may be informed by one or more theories or conceptual frameworks and/or data from pre-implementation needs assessments. This blueprint can also provide a useful historical record of the implementation process, as well as provide a mechanism to track changes over time. The implementation blueprint is often useful to ensure that feedback is received from prospective frontline users of the blueprint prior to implementation.; Consider coordinating this strategy with the development of a fidelity monitoring tool.; Issues to consider separately, especially for research purposes:; - Number and type of implementation strategies; - Organizational levels involved—this can vary by type of intervention. It may be possible to do some interventions at the lowest level. Others may require top management.; - Pre-implementation assessments would be separate step; Other examples of how to create an implementation blueprint include the CDC and Prevention’s Replicating Effective Programs.
Develop and implement tools for quality monitoring | Develop, test, and introduce into quality-monitoring systems the right input – the appropriate language, protocols, algorithms, standards, and measures (of processes, consumer outcomes, and implementation outcomes) that are often specific to the innovation being implemented. | These tools should be flexible enough to reflect fidelity, even after adaptations to the setting or client. Performance sites can benefit when these tools are available locally, particularly to help clinicians develop a sense of ownership for the change process. Quality-monitoring tools can be coordinated with other strategies to encourage or reward performance that is in alignment with the effective practice. This strategy may include activities necessary to prepare data needed to support the Develop and Organize Quality-Monitoring Systems and the Audit and Provide Feedback strategies, including data cleaning, validation, and standardization.
Develop and organize quality-monitoring systems | Develop and organize systems and procedures that monitor clinical processes and/ or outcomes for the purpose of quality assurance and improvement. | This includes developing systems for monitoring through peer reviews, collecting data from consumers, clinicians, and supervisors, and using administrative and electronic record data. This category of strategies also includes the design of disease-specific clinical registries and dashboards, where clinical information and tools (graphical representations, real-time report cards, comparisons with benchmarks, fidelity monitoring, etc.) are easily available to key stakeholders and users, e.g., care team members. These systems may provide support to the Audit and Provide Feedback strategy. Some intensive fidelity monitoring activities (e.g., psychotherapy recordings) are more practical at random, but not infrequent, intervals.
Conduct cyclical small tests of change | Implement changes in a cyclical fashion using small tests of change before taking changes system-wide. Tests of change benefit from systematic measurement, and results of the tests of change are studied for insights on how to do better. This process continues serially over time, and refinement is added with each cycle. | Two common small tests of change cycling strategies are “Plan-Do-Study-Act” from Deming’s quality management work, and Six Sigma’s Define-Measure-Analyze-Improve-Control sequence.
Audit and provided feedback | Develop summaries of clinical performance over a specific time period, often including a comparator, and give it to clinicians and/ or administrators. Summary content (e.g., nature of the data, choice of comparator) and their delivery (e.g., mode, format) are designed to modify specifically targeted behavior(s) or actions of individual clinicians, teams, or health care organizations. | Brehaut and colleagues (2016) list 15 suggestions for optimal outcomes using this strategy in clinical settings. Feedback may be derived from a variety of sources, including Quality-Monitoring Systems, medical records, computerized databases, observation, or feedback from consumers. Performance evaluations may also be considered as audit and feedback data if the evaluation included specific information on clinical performance. Feedback summaries may include recommendations. Feedback may be displayed publicly, and often involves comparisons to peers or to local, state, national, or international norms or benchmarks. Feedback may be designed to guide a clinician in improving fidelity. It should also be noted that audit and feedback data can be helpful in promoting the continuation of intended behavior. Performance data may include process variables, outcomes, or fidelity measures. Feedback can include mandatory performance measures, which are related to benchmarks from the literature or normative data within an organization or industry. This strategy may rely on systems described by the Develop and Organize Quality-Monitoring Systems strategy. Audit and Provide Feedback includes pre-defined summaries of data that are specifically designed to trigger change in behavior to improve clinical performance. Feedback is structured and provided at regular pre-defined intervals. These features differentiate this strategy from Develop and Organize Quality-Monitoring Systems, which is focused on continuous monitoring via, e.g., dashboards or registries.
Purposefully reexamine the implementation | Monitor progress and adjust effective practices and implementation strategies to continuously improve the quality of care. | It is beneficial to use a concrete schedule for monitoring rather than ‘as needed.’ Time-sensitive benchmarks for determining when adjustments are needed have also been found to be useful.
Assess and redesign workflow | Observe and map current work processes and plan for desired work processes, identifying changes necessary to accommodate, encourage, or incentivize use of the clinical innovation as designed. | Workflow redesign may comprise consideration of the following:; - Perceived process (what we think is happening);; - Reality process (what the process actually is); and; - Ideal process (what the process could be).; Process mapping is a core technique for system change. Process maps are used to develop plans that may be a part of Develop an Implementation Blueprint.
Stage implementation scale-up | Phase implementation efforts by starting with small pilots or demonstration projects and gradually move to a system-wide rollout. | This involves an iterative process that often results in adaptations. Strategies for integrating pilot feedback into the scale-up or spread process should be established in advanced. Depending on the effective practice, piloting may also involve phasing in elements or components of the practice change. Many effective practices involve more than one service (e.g., inpatient and outpatient; primary care and specialty care), and the scaling-up or spread process may have different needs to address the interactions among services (e.g., needs related to ensure continuity of care while connecting services). For more details see the Institute for Healthcare Improvement’s white paper, which describes a framework for spread.
Strategies to Train and Educate Stakeholders
Conduct ongoing training | Plan for and conduct training in the effective practice in an ongoing way for all individuals involved with implementation and users of the effective practice (e.g., clinicians, implementation staff, practice facilitators). | This can include follow-up training, advanced training, booster training, purposefully spaced training, training to competence, integration of off-the-job and on-the-job training, structured supervision, the introduction of concepts in a specific sequence to ensure mastery, and trainings based on the level of clinician knowledge. Ongoing training efforts need to reach across shifts and accommodate staff turnover, as well as rotating staff (e.g., residents). Trainings can be in person, on the web, or technology-assisted (e.g., simulation lab training), and may focus on individuals or involve groups. When planning for ongoing training, it is important to describe the training components, including the timing and frequency of trainings. Issues related to the dynamics of training can be found in the strategy, making training dynamic.
Provide ongoing consultation | Provide ongoing consultation with one or more experts in the strategies used to support implementing the effective practice. | Ongoing consultations could include in-person or distance consultation and feedback on taped clinical encounters. Consultations are tailored to the clinician’s actual practice, thus, differentiating a consultation from ongoing trainings. Feedback may be from a consultant external to the organization, which distinguishes consultation from clinical supervision. Some practice changes can involve a recertification process, thus, involving consultation ensures adequate fidelity. Consultation may also be necessary for non-clinical staff such as administrators and those responsible for billing, constructing feedback systems, or other staff with duties that impact the implementation process.
Develop educational materials | Develop and format manuals, toolkits, and other supporting materials to make it easier for stakeholders to learn about the effective practice and for clinicians to learn how to deliver it. This can include technology-delivered (e.g., online/smart-phone-based static or dynamic) content and health messaging. | Create eye-catching, easy-to-use educational documents. Distill complex information into easier-to-learn components. Consider teaching skills modularly. Use different forms of media, and target messages for different audiences. Educational materials should reflect principles of adult learning theory. Assessment of current, available technology infrastructure to accommodate educational media (e.g., firewalls, old hardware, old software) is merited. Consider how the educational materials will be used over time. For example, will the educational materials’ primary use be to train new or rotating staff; to refresh staff knowledge; or to be incorporated into existing supervision, competency, and performance review structures? Educational materials may be refined through the use of formative evaluation feedback.; Relevant suggestions are provided via the Replicating Effective Programs (REP) framework, under its ‘packaging’ domain. Further support related to developing educational materials can be found on the Training Within Industry Service website: http://twi-institute.org/training-within-industry
Make training dynamic | Vary the information delivery methods to cater to different learning styles and work contexts and shape the training to be interactive. | Making training dynamic includes efforts to divide material into small time intervals, the use of small group breakouts, audience response systems, and other measures, such as having learners try new skills between training sessions. Interactive components of training can be very dynamic with participants actively contributing to the training content, engaging in problem-solving, and identifying solutions that can be tested.
Distribute educational materials | Distribute educational materials (including guidelines, manuals and toolkits) in person, by mail, and/or electronically. | None
Use trainthe-trainer strategies | Train designated clinicians or organizations to train others in the effective practice. | Restrictions regarding who can serve as a trainer are idiosyncratic to the change, for example, some effective practices may require that supervisors have specific levels of education, training, or experience, and such restrictions should be explored in the planning phase. Train-the-trainer strategies may also apply to those responsible for administrative procedures, and who are part of implementing the effective practice.
Conduct educational meetings | Hold meetings targeted toward educating multiple stakeholder groups (i.e., clinicians, administrators, other organizational stakeholders, community members, consumers, families) about the effective practice and/ or its implementation. | The content of the education may include information regarding what to expect as implementation moves forward. It may be useful to consider whether meeting attendees are relatively homogeneous or comprised of multiple roles and disciplines so that the education can be most effective in meeting stakeholder needs. For example, some educational meetings may inform the stakeholder group about the effective practice in a way intended to increase demand by including consumers and families, while others may preview technical facets of the effective practice for clinicians and administrators. It is often useful to have recordings or other materials from the educational meetings available to those who cannot attend the meetings and for individuals engaged or hired after the meeting(s).
Conduct educational outreach visits | Have a trained person meet with individuals or teams in their work settings to educate them about the effective practice with the intent of changing behavior to reliably use the effective practice as designed. | Visits to the site may be in person or virtual. Some initiatives may require regular educational outreach as part of maintaining behavioral changes required to ensure sustained, consistent use of the effective practice. Academic detailing is another commonly used term, although academic detailing typically involves many additional discrete implementation strategies (e.g., conduct ongoing training, modeling, developing and distributing educational materials).
Create a learning collaborative | Facilitate the formation of groups of clinicians or clinician organizations and foster a collaborative learning environment to improve implementation of the effective practice. | There are several approaches to this in the literature including peer consultation networks, online communities of practice, quality circles, and learning collaboratives. Groups may meet in person or interact using a wide variety of media. The inclusion of a quality manager within the collaborative may be useful. Positive deviance approaches use “discovery and action dialogue” among peers to promote collaborative learning.; Resources specific to learning collaboratives include:; - The Agency for Healthcare Research Quality; - The Institute for Healthcare Improvement; Key terms for searching literature specific to collaborative learning include: learning community, learning network, and community of practice.
Create online learning communities | Create an online portal for clinical staff members to share and access resources, webinars, and frequently asked questions related to the specific effective practice and provide interactive features to encourage learning across settings and teams (e.g., regular blogs, facilitated discussion boards, access to experts, and networking opportunities). | While shadowing traditionally has involved in-person observation, creative use of technology may provide additional opportunities for individuals to observe and learn from those experienced in the innovation.
Shadow other experts | Provide ways for key individuals to directly observe experienced people engage with or use the targeted effective practice. | While shadowing traditionally has involved in-person observation, creative use of technology may provide additional opportunities for individuals to observe and learn from those experienced in the effective practice.
Work with educational institutions | Encourage educational institutions to train clinicians in the effective practice. | This strategy fits well with effective practices requiring clinical training and other skills where training expertise is more likely to be housed in educational institutions.
Strategies to Provide Interactive Assistance
Implementation Facilitation | A multi-faceted process of enabling and supporting individuals, groups, and organizations in their efforts to adopt and incorporate effective practices into routine practices. | Effective practices that are the target of facilitation efforts can include a continuum of innovations ranging from evidence-based research evidence to incremental quality improvement efforts. Ideally, facilitation efforts are holistic and help to build capacity and skill within the setting to sustain ongoing effective practices. Facilitation can be provided by individuals who are internal or external to the setting within which Implementation Facilitation occurs. Implementation Facilitation is an interactive support process and draws on a combination of implementation strategies based on the needs of the setting. Implementation Facilitation is sometimes referred to as a “meta” strategy because, as an interactive support process, it often includes a combination of implementation strategies and bundles multiple strategies as needed.
Provide local technical assistance | Develop and use a system to deliver technical assistance within local settings that is focused on implementation issues. | Local technical assistants can be local staff members or affiliated with a broader or centralized network of technical assistants. The key is providing tailored technical assistance within settings where the effective practice is being implemented. Technical assistance for both the effective practice and the implementation processes may be important. For example, the VA aims to have mental health Evidence-Based Psychotherapy coordinators, Military Sexual Trauma coordinators, and OEF/OIF/OND coordinators in each facility who can provide technical assistance to other local clinicians for relevant initiatives. This strategy may be supported by Centralize Technical Assistance, which may provide necessary infrastructure and support for Provide Local Technical Assistance.
Provide clinical supervision | Provide clinicians with ongoing supervision focusing on the effective practice. Provide training for clinical supervisors who will supervise clinicians who provide the effective practice. | Clearly defining the role of supervision and providing ongoing resources to ensure that it occurs is important. Supervisor training often needs to include specific training in how to supervise the effective practice.; See Nadeem et al. (2013) for a discussion of the distinction between consultation and supervision.
Centralize technical assistance | Develop and use a centralized system to deliver technical assistance focused on implementation issues. This strategy may involve setting up a centralized technical assistance entity that may, in turn, support a network of technical assistants who work directly with local implementation sites. It may provide human-driven ad hoc support as with a helpdesk, from a centralized location (online or phone) or may be automated e.g., online frequently asked questions or via online community with discussion boards. | This could be the designation of a lead technical assistance organization (could also be responsible for training). The lead technical assistance entity can develop other mechanisms (e.g., call-in lines or websites) in order to share information on how to best implement the effective practice. This centralized function may support Provide Local Technical Assistance and enable local implementation sites to Use Data Experts.
Strategies to Support Clinicians
Facilitate relay of clinical data to clinicians | Provide as close to real-time data as possible about key measures of process/out comes using integrated modes/channels of communication in a way that promotes use of the targeted effective practice. | For recommendations regarding how to introduce effective practices or change of any kind into existing workflows, please see May (2013).
Remind clinicians | Develop reminder systems designed to help clinicians to recall information and/or prompt them to use the effective practice. | Reminders could be consumer- or encounter-specific, provided verbally, on paper, or electronically. Computer-aided decision support and drug dosages are included in this strategy. Reminders may be delivered at various time points (prior to service, during service, or following service delivery).
Develop resource sharing agreements | Develop partnerships with organizations that have resources needed to implement the effective practice. | For example, this could involve data sharing agreements, agreements to share necessary equipment (e.g., telemedicine equipment), or sharing the cost of bringing in experts who provide training and consultation. Resource sharing agreements could involve formal memorandums of understanding or be much more informal in nature.
Revise professional roles | Shift and revise roles among professionals who provide care, and redesign job characteristics. | Revising professional roles includes the expansion of roles to cover provision of the effective practice and the elimination of service barriers to care, including personnel policies.
Create new clinical teams | Change who serves on the clinical team, adding different disciplines and different skills to make it more likely that the effective practice is delivered (or is more successfully delivered). | None
Strategies to Engage Consumers
Involve consumers and family members | Engage or include consumers and families in the implementation effort. | Feedback from stakeholders can be obtained at any stage of the implementation process depending on the needs and goals of project. Involving stakeholders in the pre-implementation phase is advantageous for many effective practices. Training in the practice, and relevant advocacy, may also be included in stakeholder involvement. Informal caregivers such as neighbors, friends, and other key sources of support may also be prudent to include.
Intervene with consumers to enhance uptake and adherence | Develop strategies with consumers to encourage and problem solve around adherence. | This includes consumer reminders, outreach, and financial incentives to attend appointments. Feedback regarding consumers’ understanding and use of the treatment is also important to collect.
Prepare consumers to be active participants | Prepare consumers to be active in their care, to ask questions, and specifically to inquire about care guidelines, the evidence behind clinical decisions, or about available effective practices. | Preparing consumers to inquire about specific practices can involve asking questions and educating consumers about the existence of treatments supported by evidence, as well as explicitly inviting them into the process of treatment decision-making.
Increase demand | Attempt to influence the market for the effective practice to increase competition intensity and to increase the maturity of the market. | One way of increasing demand is to educate consumers about the effective practice so that they demand it from their clinicians (e.g., what pharmaceutical companies do).
Use mass media | Use media to reach large numbers of people to spread the word about the effective practice. | Mass media may include television, newspapers, magazines, radio, electronic social media, listservs, mass email campaigns, mass mailings, and robocalls as methods for spreading information. Targets of these media campaigns may be clinicians, potential consumers, or their associates. Other commonly used terms include marketing or social marketing.
Strategies to Change Infrastructure
Mandate change | Have leadership declare the priority of the effective practice and their determination to have it implemented. | It is important to ensure that the individuals mandating the change have the power to do so, as implementers often lack such authority. Working with health system leaders to develop buy-in and lobby for a change mandate is often needed. It can also be important to inform other stakeholders (e.g., auditors, groups that review services for billing) about the mandate to ensure they are on the same page.
Change record systems | Change clinical documentation (e.g., electronic medical records) systems to allow better assessment of implementation or clinical outcomes. | This strategy involves changing or upgrading the structure, content, function, or design of record system components. These systems most commonly involve the electronic health or medical records systems. These changes may include modifying the format of progress notes and treatment plans to reflect the effective practice being implemented. This strategy focuses on changes within the clinical setting. Please refer to Use Data Warehousing Techniques for activities that involve links to or integration with outside entities, repositories, or systems.
Change physical structure and equipment | Evaluate current configurations and adapt, as needed, the physical structure and/or equipment (e.g., changing the layout of a room, adding equipment) to best accommodate the targeted effective practice. | None
Create or change credentialing and/or licensure standards | Create an organization that certifies clinicians in the effective practice or encourage an existing organization to do so. Change governmental professional certification or licensure requirements to include delivering the effective practice. Work to alter continuing education requirements to shape professional practice toward the change. | None
Change service sites | Change the location of clinical service sites to increase access. | Changing service sites can include collocating different services to better implement complex effective practices that require multiple disciplines or services, telemedicine, or bringing the services to the client in their home, the community, or other clinically relevant settings, such as busy public spaces for a client with PTSD.
Change accreditation or membership requirements | Strive to alter accreditation standards so that they require or encourage use of the effective practice. Work to alter membership organization requirements so that those who want to affiliate with the organization are encouraged or required to use the effective practice. | None
Start a dissemination organization | Identify or start a separate organization that is responsible for disseminating the effective practice. It could be a for-profit or nonprofit organization. | This strategy can address concerns (e.g., conflict of interest) for situations in which it is desirable to have fidelity monitors that are independent from the care setting. The dissemination organization could be a for-profit or nonprofit organization. The organization could be ‘licensed’ by a university if the effective practice was born within an academic setting. It is important for dissemination organizations to be aware of organizations’ approaches to implementing other effective practices in order to build upon existing knowledge and practices.
Change liability laws | Participate in liability reform efforts that make clinicians more willing to deliver the effective practice. | Liability reform can also make clinicians less willing to deliver alternatives to the effective practice.
Strategies to Utilize Financial Strategies
Fund and contract (and/or Negotiate) with Vendors for the clinical innovation | Governments and other payers of services issue requests for proposals to deliver the effective practice, use contracting processes to motivate clinicians to deliver the effective practice, and develop new funding formulas that make it more likely that clinicians will deliver the effective practice. | None
Access new funding | Access new or existing money to facilitate the implementation. | Accessing new funding sources could involve new uses of existing money, accessing block grants, shifting funding from one program to another, cost-sharing, passing new taxes, raising private funds, or applying for grants. These monies may be used to fund the delivery of an effective practice, or to support other time limited actions needed for initial implementation, such as to purchase material or logistical support, training, and consultations.
Place innovation on fee-for-service lists/formularies | Work to place the effective practice on lists of actions for which clinicians can be reimbursed (e.g., a drug is placed on a formulary, a procedure is now reimbursable). | The VA made Naloxone kits available on all formularies free of charge to consumers and facilities as part of Opiate Education and Naloxone Distribution program to prevent opiate overdose mortality.
Alter incentive/ allowance structures | Work to incentivize the adoption and implementation of the effective practice. | Incentives may be based on the performance of individual clinicians or larger performance units at the organizational level. The incentive could be in the form of an increased rate of pay to cover the incremental costs associated with implementing the effective practice. The incentive could be through loan reduction or forgiveness to clinicians to learn the new practice. This category of financial strategies also includes the elimination of any perverse incentives that become a barrier to receiving appropriate care. An incentive suggests the payment is tied to performing a clinical action or improving outcomes. An allowance suggests that the clinician or organization is not required to perform the clinical action or meet the performance standard.
Make billing easier | Make it easier to bill for the effective practice. | Making billing easier might involve requiring less documentation, ‘block’ funding for delivering the effective practice, and creating new billing codes. Developing progress note templates to facilitate documentation of the effective practice can also decrease the burden for obtaining payment.
Alter consumer fees | Create fee structures where consumers pay less for preferred treatments (the effective practice) and more for less-preferred treatments. | None
Use other payment schemes | Introduce payment approaches (in a catchall category). | Payment scheme approaches may involve prepayment and prospective payment for service, clinician salaried service, the alignment of payment rates with the attainment of consumer outcomes, and the removal or alteration of billing limits, such as numbers of encounters that are reimbursable. Payment may also be based on measures of treatment fidelity. Payment schemes are implementation strategies to the degree that they free the clinician’s time to provide the effective practice. Others’ strategies motivate clinicians to provide better service.
Develop disincentives | Provide financial disincentives for failure to implement or use the effective practice. | In addition to direct financial disincentives, this strategy could include tying promotion decisions to the use of certain practices.
Use capitated payments | Pay clinicians or care systems a set amount per consumer for delivering clinical care. | This is an implementation strategy to the degree that it frees the clinician to provide services that they may have been disincentivized to provide under a fee-for-service structure. This may be helpful to motivate clinicians to use certain effective practices. These changes often come about as part of policy changes that alter fee structures, alter coverage, or add items to reimbursement formularies.

References:

1 Perry CK, Damschroder LJ, Hemler JR, Woodson TT, Ono SS, Cohen DJ. Specifying and comparing implementation strategies across seven large implementation interventions: a practical application of theory. Implement Sci. 2019;14(1):32.30898133

2 Powell BJ, Waltz TJ, Chinman MJ, . A refined compilation of implementation strategies: results from the Expert Recommendations for Implementing Change (ERIC) project. Implement Sci. 2015;10:21.25889199

3 Waltz TJ, Powell BJ, Matthieu MM, . Use of concept mapping to characterize relationships among implementation strategies and assess their feasibility and importance: results from the Expert Recommendations for Implementing Change (ERIC) study. Implement Sci. 2015;10:109.26249843