# VA Resources for Implementation & Quality Improvement

VA Resource Centers Fact Sheets:

- Center for Evaluation & Implementation Resources (CEIR)
- Evidence Synthesis Program (ESP)
- Partnered Evidence-based Policy Resource Center (PEPReC)
- HSR&D VA Information Resource Center (VIReC)
- HSR&D Health Economics Resource Center (HERC)

QUERI Implementation Strategy Learning Hubs

VA Quality Scholars

## VA RESOURCE CENTERS

- [image] CENTER FOR EVALUATION & IMPLEMENTATION RESOURCES
  Time sensitive consultation support to Operational Leaders on evaluation & implementation
- [image] EVIDENCE SYNTHESIS PROGRAM
  Identifies best practices & conducts rapid evidence reviews
- [image] PARTNERED EVIDENCE-BASED POLICY RESOURCE CENTER
  Supports development & evaluation of national policies/program for VA Leaders using rigorous designs
- [image] HSR&D VA INFORMATION RESOURCE CENTER
  Provides guidance on data, information systems & analysis
- [image] HSR&D HEALTH ECONOMICS RESOURCE CENTER
  Estimates return on investment & implementation strategy costs

### CEIR (Center for Evaluation and Implementation Resources)

### ESP (Evidence Synthesis Program)

### PEPReC (Partnered Evidence-Based Policy Resource Center)

### VIReC (VA Information Resource Center)

### HERC (Health Economics Resource Center)

## QUERI Implementation Strategy Learning Hubs

The goal of the QUERI Implementation Strategy Learning Hubs (https://www.queri.research.va.gov/training_hubs/default.cfm) is to demystify implementation science by offering opportunities for clinicians and researchers to learn how to deploy effective practices using specific implementation strategies (i.e., tools or methods that help existing providers adopt effective practices). QUERI Learning Hubs use evidence-based implementation strategies and are coordinated by the Center for Evaluation & Implementation Resources (https://www.queri.research.va.gov/ceir/).

Ann Arbor, MI – Virtual Quality Improvement Training for VHA Teams (https://www.queri.research.va.gov/training_hubs/virtual-qi.cfm)

Bedford, MA – Teamwork Training Hub: Frontline Huddling for Quality Improvement Implementation (https://www.queri.research.va.gov/training_hubs/teamwork.cfm)

Denver, CO – Designing for Dissemination and Implementation Training Hub (https://www.queri.research.va.gov/training_hubs/dissemination.cfm)

Houston, TX – Leading Healthcare Improvement: Leadership Training for Applying Improvement Strategies (https://www.queri.research.va.gov/training_hubs/healthcare_improvement.cfm)

Little Rock, AR – Behavioral Health QUERI Implementation Facilitation Training Hub (https://www.queri.research.va.gov/training_hubs/behavioral_health.cfm)

Los Angeles, CA – Evidence-Based Quality Improvement Learning Network (https://www.queri.research.va.gov/training_hubs/quality_improvement.cfm)

San Francisco, CA – QUERI Adaptation Training Hub (https://www.queri.research.va.gov/training_hubs/adaptation.cfm)

### VAQS (VA Quality Scholars)