# Sustainment Check List

Sustain an Intervention

◻ Develop business plan to continue EP
  Consider sources of funding, local fit, value to local organization, etc.
◻ Monitor for changes in EP, whether different EP is needed
  Keep abreast of needed changes, adaptations, or consider de-implementation/de-intensification
◻ Weigh costs of maintaining EP
  Analyze the costs, benefits, and return on investment of supporting EP

Transition Ownership to Stakeholders

◻ Provide management support
  Provide implementation playbook to clarify how to support the EP
◻ Plan and budget for resources
  Plan and budget for local and shared operating resources (budget impact analysis, break-even analysis)
◻ Support continuous learning and innovation in local stakeholder teams
  Plan for ongoing analysis, sharing between sites, and staff development

Ongoing Evaluation and Reflection

◻ Consumer outcomes
  Ensure EP has a population effect on a priority group(s) of patients
◻ Delivery of EP (fidelity vs. adaptation)
  Maintain ongoing monitoring of fidelity and testing of adaptations to improve fit
◻ Provider and system costs
  Local teams should iteratively refine implementation to optimize local fit and uptake