# Case Studies

## The National Hepatitis C Innovation Team Collaborative

### Pre-Implementation

#### Identify a Problem and Solution

The hepatitis C virus is a leading cause of liver cancer and liver failure among United States adults and Veterans. In 2014, new, direct-acting antiviral medications with fewer side effects, shorter courses of treatment, and higher cure rates became widely available.

Earlier treatments included injectable interferon and were less than optimal for consumers and clinicians. These treatments were delivered over many months and frequently had adverse side effects, contraindications, and low cure rates. As a result, few Veterans had received hepatitis C virus treatment prior to 2014.^218^

As the new medications became available in 2014, the Veterans Health Administration cared for over 160,000 Veterans who were eligible for the medications. Recognizing the benefit of these innovative treatments on consumer health and quality of life, VA clinical leadership decided to redesign the structure of hepatitis C virus care to make these treatments easily accessible for Veterans.

To support the expansion of treatment, the HIV, Hepatitis, and Related Conditions Program created a national quality improvement collaborative called the Hepatitis C Innovation Team Collaborative. The collaborative’s goal was to improve the hepatitis C virus system of care. Health system leaders saw this rapid, national effort as an opportunity to study implementation strategies and how they affect outcomes over time. This work informs future similar implementation efforts.^218^

To support the study, implementation scientists at VA partnered with the collaborative to answer these questions:

1. Which strategies helped make sites successful in providing hepatitis C virus treatment and testing?
2. Was the collaborative an important part of hepatitis C virus treatment success?

#### Engage Stakeholders

The new antiviral treatments gave clinicians the ability to provide curative hepatitis C virus treatments. Treating the hepatitis C virus had strong political leadership and budgetary support to rapidly make treatments available to qualified Veterans. Given the cost of treatment, between fiscal year 2015 and 2020, Congress appropriated over three billion dollars to VA to purchase hepatitis C virus medication.

The collaborative approached leaders from each of the health system’s 21 regional networks and from Viral Hepatitis Lead Clinicians to gain support. These stakeholders were asked to form a regional team that represented multiple facilities within a network (e.g., medical centers and outpatient clinics). Each team developed and proposed plans to clinical operations offices for review on how they would improve hepatitis C virus care in their network facilities.

Scaling up hepatitis C virus treatment required local care teams to rapidly change how they treated the virus. Teams also had to expand the reach of treatment to Veterans who were found previously ineligible as well as those previously undiagnosed and connect them with care.

To facilitate implementation, the HIV, Hepatitis, and Related Conditions Program supported regional teams. The program provided a learning collaborative and training using Lean quality improvement principles to make changes that resulted in clinical improvements and system redesign. This allowed local clinicians more time to select implementation strategies for their facility. It also provided the opportunity for evaluators to compare implementation strategies used by sites with varying implementation-effectiveness outcomes over time.

Originally developed for manufacturing settings, Lean seeks to introduce new ways of operating that empower frontline staff to make continuous improvements to their daily work that focus on improving value by reducing sources of waste and inefficiency causes by complicated daily processes and workarounds. Lean engages frontline employees in an interactive problem-solving to examine areas for improvement, propose solutions, and experiment using rapid PDSA cycles and monitoring of results. To achieve improvements in quality and performance, Lean emphasizes monitoring measures that represent a range of outcomes including clinical outcomes, financial, consumer and employee aspects of health care delivery.

#### Develop Measures and Data

The HIV, Hepatitis, and Related Conditions Program developed and supported Hepatitis C Innovation Team leadership to deploy national hepatitis C virus measures, including birth cohort testing, treatment, and cure. Team evaluators also developed an annual web-based survey to assess the use of the 73 implementation strategies identified by the Expert Recommendations for Implementing Change (ERIC) Project.^126,127^ They did so by sampling key facility hepatitis C virus clinical leads. Survey responses were used to examine associations between implementation activities and hepatitis C virus performance metrics that could be monitored over time. The team did this to compare differences across sites, especially with high versus low-performing facilities (i.e., performance based on numbers of new hepatitis C virus treatment starts).

### Implementation

#### Implement an Intervention

Nationally, Hepatitis C Innovation Team leadership provided a structure for communicating and networking to help overcome barriers and spread best practices through the collaborative. Hepatitis C Innovation Team leadership held annual in-person meetings and weekly calls. They also trained members in Lean and system redesign methods, conducted onsite support, and delivered real-time feedback.

#### Activate Implementation Teams

Regionally, teams received annual funding to support a regional coordinator position. They also received other staff support, clinical pharmacists, supplies, and travel to help implement the intervention.

After building team capacity to conduct hepatitis C virus quality improvement, teams determined the implementation strategies needed to improve hepatitis C virus care in their local health system.

#### Monitor Implementation Progress

The Hepatitis C Innovation Team Collaborative helped create a national dashboard that acted as a population health management tool. The dashboard helped identify consumers who were eligible for hepatitis C virus testing and treatment. Evaluators and Hepatitis C Innovation Team leaders tracked the progress across hepatitis C virus measures. They focused on ensuring that all Veterans received access to the treatment. While only 10% of Veterans with hepatitis C virus were cured by the end of fiscal year 2014, by the end of fiscal year 2016 (Year 2), 43% (84,192 Veterans) were cured.^271^

The evaluation team then used methods to identify strategies related to higher treatment across implementation years. Strategies related to treatment shifted between Years 1 (Pre-implementation and early Implementation) and 2 (Implementation). Pre-implementation strategies in the “training/educating,” “interactive assistance,” and “building stakeholder interrelationships” clusters were more likely to be significantly associated with treatment starts in Year 1. Strategies in the “evaluative and iterative” and “adapting and tailoring” clusters were more likely to be related to treatment in Year 2. Table 21 shows the shift and implementation strategies across nine thematic clusters.

Table 21 Strategies Related to Hepatitis C Virus Treatment Starts in Years 1 and 2 Mapped onto Strategy Clusters^205^

Strategy cluster | Discrete implementation strategy | Year 1 use | Year 2 use | Both years
Develop stakeholder interrelationships | Inform local opinion leaders of advances | ✕
Develop stakeholder interrelationships | Share knowledge gained from quality improvement efforts with other sites | ✕
Develop stakeholder interrelationships | Identify and prepare clinical champions | ✕
Develop stakeholder interrelationships | Build networks and relationships for information sharing and problem-solving | ✕
Develop stakeholder interrelationships | Partner with a university to share ideas | ✕
Develop stakeholder interrelationships | Visit other sites outside your facility to learn from their experience | ✕
Develop stakeholder interrelationships | Organize support teams of clinicians caring for hepatitis C virus to share lessons learned and support others’ learning | | ✕
Develop stakeholder interrelationships | Involve executive boards | | ✕
Develop stakeholder interrelationships | Build a local team to address challenges | | | ✕
Develop stakeholder interrelationships | Conduct local consensus discussions | | | ✕
Develop stakeholder interrelationships | Recruit, designate, and/or train leaders | | | ✕
Develop stakeholder interrelationships | Use modeling or simulated change | | | ✕
Develop stakeholder interrelationships | Make efforts to identify early adopters and learn from their experiences | | | ✕
Train and educate stakeholders | Conduct educational trainings | ✕
Train and educate stakeholders | Have expert in hepatitis C virus care meet with clinicians for educational trainings | ✕
Train and educate stakeholders | Provide ongoing hepatitis C virus training | ✕
Train and educate stakeholders | Vary information delivery methods to cater to different learning styles | ✕
Train and educate stakeholders | Distribute educational materials | | ✕
Train and educate stakeholders | Facilitate forming clinician groups and a collaborative learning environment | | | ✕
Train and educate stakeholders | Use educational institutions to train clinicians | | | ✕
Engage consumers | Promote demand for HCV care among patients through any other means | ✕
Engage consumers | Engage in efforts to prepare consumers to be active participants in hepatitis C virus care | ✕
Clinician interactive assistance | Offer external technical assistance to support clinics | ✕
Clinician interactive assistance | Use a centralized system to deliver facilitation | ✕
Clinician interactive assistance | Provide clinical supervision | | | ✕
Change infrastructure | Create or change credentialing and/or licensing standards | ✕
Change infrastructure | Participate in liability reform efforts to make clinicians more willing to support innovation | ✕
Change infrastructure | Change the records system | | ✕
Change infrastructure | Change the physical structure and equipment | | | ✕
Change infrastructure | Change the location of clinical service sites | | | ✕
Use financial strategies | Alter incentive/allowance structures | | ✕
Support clinicians | Develop resource sharing agreements | ✕
Support clinicians | Facilitate the relay of clinical data to clinicians | | | ✕
Support clinicians | Create new clinical teams | | | ✕
Support clinicians | Revise professional roles | | | ✕
Adapt and tailor to the context | Use data experts to manage hepatitis C virus data | | | ✕
Adapt and tailor to the context | Use data warehousing techniques | ✕
Adapt and tailor to the context | Tailor strategies to deliver HCV care | ✕
Adapt and tailor to the context | Promote adaptability | ✕
Use evaluative and iterative strategies | Assess for readiness and identify barriers/facilitators to change | | ✕
Use evaluative and iterative strategies | Develop a formal implementation blueprint | | ✕
Use evaluative and iterative strategies | Conduct small tests of change, measure outcomes, and then refine these tests | | ✕
Use evaluative and iterative strategies | Develop and organize systems to monitor clinical processes or outcomes for purpose of quality assurance/improvement | | ✕
Use evaluative and iterative strategies | Intentionally examine the efforts to promote hepatitis C virus care | | ✕
Use evaluative and iterative strategies | Develop strategies to obtain and use consumer and family feedback | | ✕
Use evaluative and iterative strategies | Collect and summarize clinical performance data to feedback to decision makers to iteratively pilot changes before making system-wide changes | | | ✕

### Sustainment

#### Sustain an Intervention

The Hepatitis C Innovation Team Collaborative structure had great success in treating over 85% of Veterans with the hepatitis C virus. As a result, the team decided to focus on Veterans with advanced liver diseases in 2019. The team changed its name to the “Hepatic Innovation Team Collaborative” in recognition of the expanded scope.

To improve the sustainability of the redesign efforts that led to the VA’s success in hepatitis C virus testing and treatment, the collaborative’s leadership team changed the team composition from system redesign experts to liver disease specialists from regional networks across the country.

#### Transition Ownership to Stakeholders

The collaborative provided infrastructure through regional funding, cross-regional networking, technical assistance, and data feedback. Regional coordinators and their teams developed new relationships with stakeholders. They also obtained approval for applying redesign and Lean management to advanced liver disease.

To make the transition successful, the leadership team provided infrastructure support during the transition to the regional networks. This allowed new leaders to receive train-the-trainer support and education in process improvement and data management. New leaders were also provided coaching and mentorship.

#### Ongoing Evaluation and Reflection

The VA has led the nation in hepatitis C virus elimination efforts. The evaluation of their national efforts led to the creation of a method to measure implementation strategies over time. These strategies link to the stages of Implementation.

The evaluation team continues to review the factors associated with equal access to these medications. As the collaborative changes their focus to clinical care, the evaluation team continues to learn more about how to help later-adopting sites improve their care of Veterans with liver disease.

#### Suggested Readings

1 Belperio PS, Backus LI, Ross D, Neuhauser MM, Mole LA. A population approach to disease management: hepatitis C direct-acting antiviral use in a large health care system. J Manag Care Spec Pharm. 2014;20(6):533–540.24856591
2 Belperio PS, Chartier M, Ross DB, Alaigh P, Shulkin D. Curing Hepatitis C Virus Infection: Best Practices From the U.S. Department of Veterans Affairs. Ann Intern Med. 2017;167(7):499–504.28973196
3 Rogal SS, Yakovchenko V, Waltz TJ, . The association between implementation strategy use and the uptake of hepatitis C treatment in a national sample. Implement Sci. 2017;12(1):60.28494811
4 Belperio PS, Chartier M, Gonzalez RI, . Hepatitis C Care in the Department of Veterans Affairs: Building a Foundation for Success. Infect Dis Clin North Am. 2018;32(2):281–292.29778256
5 Belperio PS, Chartier M, Ross DB. After Curing Hepatitis C Virus Infection. Ann Intern Med. 2018;168(9):682–683.
6 Rogal SS, Yakovchenko V, Waltz TJ, . Longitudinal assessment of the association between implementation strategy use and the uptake of hepatitis C treatment: Year 2. Implement Sci. 2019;14(1):36.30961615
7 Yakovchenko V, Miech EJ, Chinman MJ, . Strategy Configurations Directly Linked to Higher Hepatitis C Virus Treatment Starts: An Applied Use of Configurational Comparative Methods. Med Care. 2020;58(5):e31–e38 32187105

## Tailoring Implementation of a Medical Home Model to Meet Women Veterans’ Needs Using Evidence-based Quality Improvement

We applied the QUERI Roadmap to our work to modify the VA’s medical home model (i.e., Patient Aligned Care Team) to meet the needs of women Veterans. Women Veterans are an extreme minority in the VA (approximately 8%). However, they have complex physical and mental health needs that must be treated and are the fastest growing segment of new VA users.

### Pre-Implementation

#### Identify the Problem and Solution

Women Veterans face gender disparities in primary care access, continuity, and coordination. They also face disparities when it comes to preventive screenings that routinely occur in primary care settings (e.g., colorectal cancer screening, depression screening).

The Patient Aligned Care Team was not originally changed for women Veterans’ primary care needs. Therefore, multiple policies guide the implementation of Women’s Health Patient-Aligned Care Team models. These models must be capable of meeting primary care and gender-specific care needs by expert clinicians in gender-sensitive care environments.

In partnership with VA Women’s Health Services, our goal was to test an evidence-based quality improvement approach to tailoring the Patient Aligned Care Team (as the intervention) to meet women Veterans’ care needs. This intervention is team-based and focuses on access to and continuity with identifiable teamlets. These teamlets have assigned Veteran populations for whom they are accountable for preventive care, primary care coordination, and Veteran outcomes.

#### Engage Stakeholders

We engaged stakeholders in the beginning using several strategies. First, we reached out to medical centers that were part of the VA Women’s Health Practice Based Research Network. Each medical center has a trained site lead with knowledge about site characteristics (e.g., care arrangements). Leads helped provide insights on local organizational strengths and challenges. They also helped us identify stakeholders we should further engage.

We then engaged regional network-level leaders to orient them to our plans. We also had to understand their structures for oversight and decision-making and secure their agreement to participate.

Finally, we convened multilevel (i.e., network, medical center, clinic levels) meetings within each of four participating regional networks. In the meetings, we described the problem and evidence-based quality improvement solution. We described the problem in the context of Patient Aligned Care Team core elements and data on local barriers/gaps (e.g., network-specific gender disparities). Then, we used expert panel methods to agree on a quality improvement roadmap for each regional network adapted to local contexts. Communication strategies for ongoing regional network and medical center engagement were integral to the quality improvement roadmaps.

#### Develop Measures and Data

The evaluation was designed as a cluster-randomized trial with measures of access, clinician/staff gender sensitivity, and gender-specific care delivery. We also measured potential impacts on health care utilization when implementing the Patient Aligned Care Team model (e.g., primary care visits, hospitalizations, emergency room visits).

Finally, we determined baseline performance. We measured it using consumer and clinician/staff surveys, key stakeholder and teamlet interviews, and administrative data. These data sets were collected after the stakeholder panel meetings.

### Implementation

#### Implement the Intervention

Evidence-based quality improvement is a top-down/bottom-up research-clinical partnership approach to implementation. It includes:

- Leadership buy-in (achieved in pre-implementation)
- Quality improvement training for local teams (e.g., process flow maps)
- Formative data feedback
- Technical support (e.g., measures development for local Patient Aligned Care Team quality improvement projects)
- External practice facilitation

Local quality improvement teams selected the target related to the Patient Aligned Care Team among many options prioritized in the regional network quality improvement roadmaps. This enabled them to identify what mattered most locally. The research team helped the local quality improvement teams develop project proposals using a standardized template. The template required:

- Specific problem
- A solution
- Activities that needed to be accomplished
- Other stakeholders who needed to be involved
- Measures that needed to be collected
- Time/effort needed by local participants to do the project.

The evidence-based quality improvement needed to be adapted to meet local teams’ competing demands (i.e., fewer facilitation calls).

#### Activate Implementation Teams

All teams were activated for an in-person, evidence-based quality improvement training session spanning one-and-a half-days. During the session, they received group training on evidence-based quality improvement principles and heard testimony from previous users. The teams listened to leaders from the VA Central Office endorse the work ahead. Finally, they worked in small groups with investigators to develop and get feedback on their project proposals.

Top-down support from local leaders was not necessary at this stage because leaders provided support during stakeholder panel meetings. Their priorities were reflected in the network-specific quality improvement roadmaps. Feedback channels were also laid out during the pre-implementation stakeholder panel meetings, but specific strategies were added and evolved over the course of implementation. This included a range of briefings to leaders at the medical center and regional network levels that did not participate in the panel meetings.

#### Monitor Implementation Progress

In addition to pre-implementation communication plans, each VA regional network had a different structure or council for reporting progress (e.g., network quality council). One network created a steering committee specific to this implementation effort. We generated formative feedback reports for the local quality improvement teams and provided them with slide decks and templates for their own reporting at medical center and network levels, giving them both voice and visibility in their respective organizations. Most had never had these reporting opportunities.

We also provided reviews of their own progress reports, leading in a few cases to academic products of their own. Monitoring of implementation was chiefly accomplished through facilitation calls, where we generated brief summaries of progress and action items for the quality improvement and research teams, respectively, and helped teams navigate apparent roadblocks. We also used rapid summaries of key stakeholder interviews at the clinic, medical center, and regional network levels, which were fed back to the teams for applied analysis.

### Sustainment

#### Sustain an Intervention

As the VA’s medical home model, Patient Aligned Care Team was already mandated nationally. However, ongoing improvements were underway as part of the Demonstration Laboratory initiative, where evaluation feedback was provided to national VA primary care leaders for their consideration in ongoing adaptations.

To sustain attention to the value of gender-tailoring Patient Aligned Care Team moving forward, we convened another round of stakeholder panel meetings 24-months post-implementation in each regional network.

These meetings highlighted team accomplishments and ongoing challenges. They also provided the opportunity to decide on sustainability plans at the network and medical center levels. The meetings presented opportunities for regional network leaders to identify and select evidence-based improvements that could spread network-wide.

Aspects of both evidence-based quality improvement and Women’s Health Patient Aligned Care Team advances were integrated into the VA Women’s Health Service’s national Women’s Health Patient Aligned Care Team Roadmap. The roadmap was circulated nationally.

#### Transition Ownership to Stakeholders

One of the key beliefs underlying evidence-based quality improvement is the partnership model. This model infuses every stage of implementation. It empowered local quality improvement teams to solve problems that got in the way as they worked. We continue to hear about their ongoing improvements and new quality improvement projects four years after the study ended.

We focused on transitioning evidence-based quality improvement functions to key leaders. For example, we worked with network-level Women Veteran Program Managers to take on facilitation roles with women’s health leaders under their purview. We also developed and delivered national evidence-based quality improvement training for all women’s health leaders.

#### Ongoing Evaluation and Reflection

There were many impacts of evidence-based quality improvement on Women’s Health Patient Aligned Care Team implementation. Local quality improvement projects achieved better follow-up of abnormal cervical cancer screening, linking Veterans to designated women’s health clinicians. This led to the Women’s Health Services’ adoption of evidence-based quality improvement as an approach to further comprehend women’s health care delivery. However, this time it occurred in low-performing VA facilities.

We developed technical specifications for contract vendors to use when deploying evidence-based quality improvement. Currently, we are evaluating the fidelity and effectiveness of deployment in these new organizational contexts.

We have also launched an Evidence-Based Quality Improvement Collaborative in the VA Women’s Health Practice Based Research Network, which tests our ability to spread innovations in increasingly efficient and effective ways.

More work is necessary to determine the time needed between evidence-based quality improvement Patient Aligned Care Team changes in this context. Additional research is also needed to determine clinician gender sensitivity and burnout, changes in consumer experience (e.g., how much time does it take for women Veterans to see a difference in their care), as well as clinician, staff, and system costs.

#### Suggested Readings

Those interested in training on evidence-based quality improvement can visit the Evidence-Based Quality Improvement Implementation Strategy Learning Network Hub (https://www.queri.research.va.gov/training_hubs/quality_improvement.cfm) and contact vhawlaebqihub@va.gov.

1 Brunner, J., Cain, C.L., Yano, E.M., Hamilton, A.B. (2019). HYPERLINK “https://www.ncbi.nlm.nih.gov/pubmed/30455089” Local leaders’ perspectives on women Veterans’ health care: what would ideal look like? Women’s Health Issues. 2019;29:64–71.30455089
2 Chuang, E., Brunner, J., Mak, S., Hamilton, A.B., Canelo, I., Darling, J., Rubenstein, L.V. Yano, E.M. Challenges with implementing a patient-centered medical home model for women Veterans. Women’s Health Issues. 2017;27(2):214–220.28063848
3 Hamilton, A.B., Brunner, J., Cain, C., Chuang, E., Luger, T.M., Canelo, I., Rubenstein, L., Yano, E.M. Engaging multilevel stakeholders in an implementation trial of evidence-based quality improvement in VA women’s health primary care. Transl Behav Med. 2017;7(3):478–85.28585163
4 Hamilton, A., Olmos-Ochoa, T.T., Canelo, I., Rose, D., Hoggatt, K.J., Than, C., Yano, E.M. (In press). Dynamic waitlisted design for evaluating a randomized trial of evidence-based quality improvement of comprehensive women’s health care implementation in low performing VA facilities. Implement Sci Commun.
5 Klap, R., Darling, J., Hamilton, A., Rose, D., Dyer, K., Canelo, I., Haskell, S., Yano, E. (2019). Prevalence of stranger harassment of women Veterans at Veterans Affairs Medical Centers and impacts on delayed and missed care. Women’s Health Issues. 2019;29:107–115.30686577
6 Meredith, L. S., Wang, Y., Okunogbe, A., Bergman, A. A., Canelo, I. A., Darling, J. E., & Yano, E. M. (2017). Attitudes, practices, and experiences with implementing a patient-centered medical home for women veterans. Women’s Health Issues. 2017;27(2):221–227.28087130
7 Yano, E.M., Darling, J., Hamilton, A., Canelo, I., Chuang, E., Meredith, L., Rubenstein, L. Cluster randomized trial of a multilevel evidence-based quality improvement approach to tailoring VA Patient Aligned Care Teams to the needs of women veterans. Implement Sci. 2016;11(1):101.27435723

## The Department of Veterans Affairs Rapid Naloxone Initiative: National Diffusion of a Promising Practice

The Veterans Health Administration has worked quickly to prevent opioid overdose deaths among Veterans at VA facilities. The Rapid Naloxone Initiative is one part of a multi-faceted national strategy to address the opiate epidemic. Notably, this case study illustrates how a promising care innovation developed by a single health care facility can be spread through the system to improve outcomes using the QUERI Roadmap.^129^

### Pre-Implementation

#### Identify a problem and solution

The United States is in the midst of an opioid epidemic. In 2017, opioid overdoses took the lives of nearly 47,600 people—an average of 130 fatalities per day. Military Veterans are a vulnerable population and are twice as likely to die from an accidental overdose compared to non-Veterans.

Naloxone is a safe and effective medication that can reverse an opioid overdose when delivered as an intranasal spray or as an intramuscular shot. In 2014, the VA became the first large United States health system to rapidly implement a nationwide Opioid Overdoes Education and Naloxone Distribution (OEND) program.

The goals of Opioid OEND are to educate at-risk Veterans, their friends, their family, and their clinicians to improve access to naloxone and reduce and prevent Veteran deaths. In the context of this urgent national initiative, there is ample opportunity for local innovation and practice-based knowledge sharing across the health system.

Although the administration of intranasal naloxone effectively reverses opioid overdoses, clinicians and safety experts at the Boston VA Healthcare System realized that it was often unavailable at the time of an overdose, even when on facility grounds. The accessibility of naloxone is critical because the onset of brain damage can begin after just five minutes without oxygen.

The Boston VA Healthcare System iteratively worked to solve this problem by developing the Opioid Overdose Reversal Program, now named the Rapid Naloxone Initiative. The initiative consists of three core elements:

1. Training at-risk consumers and their families to administer intranasal naloxone
2. Equipping Department of Veterans Affairs Police or other first responders at a facility with intranasal naloxone and training them to use it
3. Stocking automated external defibrillator cabinets with intranasal naloxone to provide quick access

#### Engage stakeholders

The Rapid Naloxone Initiative benefitted from the national Opioid OEND initiative, which started in 2014. The Opioid OEND initiative gained support at every level of the organization. At the Boston VA Healthcare System, clinical champions garnered support for and over-saw OEND implementation with pharmacy staff and clinicians from mental health, pain management, primary care, and substance-use disorder treatment at each local health facility.

A national workgroup of operational program offices also worked collaboratively toward initiative goals. They developed common tools and resources to educate stakeholders and develop implementation plans, policies, and a data collection and evaluation plan.

The Rapid Naloxone Initiative began when a Veteran experienced an opiate overdose at a Boston VA Healthcare System’s facility in 2015.

A local consumer safety manager realized the need to expand OEND programming. She started an improvement project to assess the feasibility of equipping VA Police officers with naloxone. However, pilot testing suggested this strategy alone would be insufficient—they would also need to enable first responders to respond quickly.

In early 2016, the team began placing naloxone in unlocked cabinets containing automated external defibrillators on the walls of VA cafeterias, gyms, warehouses, clinic waiting rooms, and rehabilitation housing. This allowed trained first responders to rapidly access intranasal naloxone in critical situations. The following implementation barriers were identified during early rapid-cycle testing.

Barriers to Increasing Rapid Access to Naloxone
Gaining support of local unions to support initiative
Making a prescribed medication (albeit safe) readily available on VA campuses
Obtaining permission to develop guidelines for storing naloxone in automated external defibrillator cabinets
Developing standard methods to track and report implementation/ clinical outcomes

After successfully piloting the practice at the Boston VA Healthcare System, the initiative was spread across the regional network of medical centers, outpatient clinics, and community outpatient clinics located in six New England states (Maine, New Hampshire, Vermont, Massachusetts, Rhode Island and Connecticut).

Later in 2016, the initiative was entered into the Shark Tank competition hosted by the VA Diffusion of Excellence. It competed against hundreds of other promising employee-initiated practices to receive operational funding support from medical center leaders.

The initiative was ultimately selected as a “Gold Status” practice and received funding. The funding allowed the team to implement the practice in the regional network representing VA facilities in Florida and Puerto Rico between December 2016 and May 2017.

#### Develop measures and data

The VA Boston Healthcare System partnered with the National Opioid Overdose Education Distribution Coordinator to obtain baseline data. The partners then developed measures for success that would be relevant and meaningful once the practice spread, as displayed in Table 22.

Table 22 Measures for Assessing Impact of the Rapid Naloxone Initiative

| Outcome | Source
Opioid overdose and naloxone education | Number of Veterans prescribed naloxone | Standardized medical template in electronic health record
Opioid overdose and naloxone education | Reported opioid overdose reversals (per year) | Self-reported by facility
Department of Veterans Affairs Police naloxone | Number of facilities with Department of Veterans Affairs Police carrying naloxone | Self-reported by facility
Department of Veterans Affairs Police naloxone | Department of Veterans Affairs Police opioid overdose reversals per year | Self-reported by facility
Automated external defibrillator naloxone | Number of automated external defibrillator cabinets equipped with naloxone per facility | Self-reported by facility
Automated external defibrillator naloxone | Number of facilities with automated external defibrillator cabinets equipped with naloxone | Self-reported by facility
Automated external defibrillator naloxone | An automated external defibrillator opioid overdose reversals per year | Self-reported by facility

### Implementation

#### Implement an Intervention

In April of 2018, the VA Under Secretary for Health selected the Rapid Naloxone Initiative for national diffusion. In July of 2018, an interdisciplinary workgroup with stakeholders from the following programs and agencies met face to face to develop a formal national diffusion strategy:

- Veterans Health Administration Diffusion of Excellence
- Pharmacy Benefits Management (including the pharmacy Academic Detailing Service)
- Department of Veterans Affairs:
  - Police
  - National Center for Patient Safety
  - National Center on Homelessness Among Veterans
  - Office of Nursing Services
  - Office of Mental Health and Suicide Prevention

To implement the plan, the Rapid Naloxone Initiative team partnered with the Diffusion of Excellence initiative and the Opioid OEND national coordinator to manage the spread throughout the VA. The team developed two implementation toolkits. One was created for the automated external defibrillator cabinet naloxone program, and another was created for equipping VA Police with intranasal naloxone. The team selected a number of implementation strategies to address barriers identified through pilot and regional spread efforts (Table 23).

Table 23 Implementation Strategies to Facilitate Rapid Naloxone Initiative Uptake

Implementation barrier | Implementation strategy
Opioid OEND clinician training and education | Standardized educational resources, academic detailing
Naloxone training for at-risk Veterans, caregivers | Consumer brochures, materials, education delivered by interdisciplinary VA clinicians
Identification of high-risk consumers eligible for naloxone | Clinician decision-support tools
Implementation guidance | Standardized Opioid OEND implementation plan, clinical guidance, resources via centralized web-based portal, technical assistance by Diffusion of Excellence and Opioid OEND national program staff
Co-pay cost for naloxone | Waiver of co-pay fee via policy change to consumers and costs to local facilities
Leadership support | National workgroup of operational office, policy mandates, policy changes in formulary
Local union support | Memorandum of understanding signed with union groups to allow VA Police to carry naloxone
Automated external defibrillator cabinet regulatory approval | Guidance from the Joint Commission on standards for labeling, securing, monitoring, and maintaining naloxone in automated external defibrillator cabinets
Marketing to Department of Veterans Affairs and non-Department of Veterans Affairs stakeholders | Multi-channel marketing campaign using print media, social media (e.g., Facebook, Ted Talks), presentation on national VA clinical and leadership calls, academic detailers, community of practice, centralized websites
Local site barriers | External facilitation by Opioid OEND national coordinator and initiative implementation team; sharing problems and successes on a monthly community of practice call
Data collection and outcome monitoring | Creation of standardized clinician templates for electronic medical record, national dashboard on program metrics

#### Activate Implementation Teams

The Rapid Naloxone Initiative was initiated by a top-down memorandum sent by VA leadership. The memorandum defined a goal for all facilities to implement the program by December 2018. When this directive was released in September 2018, each VA health system was required to identify a clinical champion and back-up champion for the program.

The role of champions was to coordinate and monitor the implementation of the practice at the local level to improve fit. In addition, each facility was required to submit a registration form, which included the implementation status at their facility and contact information of the champions. Then, a member of the Diffusion of Excellence team was assigned to contact each champion to provide technical assistance and address implementation barriers.

#### Monitor Implementation Progress

Virtual teleconference calls with regional network stakeholders helped identify common implementation barriers. Tools and resources to overcome barriers were often provided the same day. While barriers related to VA Police naloxone tended to be easily addressed (e.g., gaining police union support), barriers related to automated external defibrillator cabinet naloxone were more difficult. This was because many concerns related to the Joint Commission and department guidance were created specifically for the Rapid Naloxone Initiative.

The national implementation team met with the Joint Commission to address common questions/concerns and provide feedback to the field, including updated guidance that made it easier implement the practice. For example, the Canandaigua VA Medical Center presented their model of automated external defibrillator cabinet naloxone that garnered a best practice designation from the Joint Commission. This model was shared widely with facilities struggling to implement the practice.

Another major barrier to implementation was not having a nationally standardized brief training protocol for staff. In February of 2019, a 10-minute staff training on the VA Rapid Naloxone Initiative was made available through the VA’s online Talent Management System. The system allowed facilities to assign and track staff training. The VA worked with the pharmaceutical company that created the nasal naloxone spray (Narcan®) to adapt their video for short training.

Working on this initiative identified the need to streamline, synergize, and improve overdose reporting and response. VA Police now systematically document their activities in the Police System/Report-Exec System, Patient Safety Managers report their activities in the Joint Patient Safety Reporting System, and clinical staff report overdoses in the electronic health record system and adverse drug events in the Drug Event Reporting System.

### Sustainment

#### Sustain an intervention

The initiative continues with ongoing central support from the VA Office of Mental Health and Suicide Prevention. The initiative also benefits from ongoing national and local leadership support from the VA Office of Security and Law Enforcement and National Center for Patient Safety.

At the local level, nasal naloxone is currently free to both facilities and at-risk Veterans, so ongoing cost is not a concern. A directive is also being developed that should help support sustainment.

In May of 2019, the workgroup had another meeting to discuss future plans and the transition of ownership to the Office of Mental Health and Suicide Prevention.

#### Ongoing evaluation and reflection

As of November 2019, 82% of VA medical centers have equipped a total of 2,785 of police officers with naloxone and 56 facilities have deployed naloxone in 693 automated external defibrillator cabinets. As a result, this simple practice has resulted in 126 opioid overdose reversals (120 by VA Police and six by automated external defibrillator cabinet naloxone).

As of December 31, 2019, naloxone has been dispensed to over 217,469 unique Veterans with 32.3% being high-risk consumers with overlapping opioid and benzodiazepine prescriptions dispensed naloxone as well as 38.6% of Veterans with ≥50 mg Morphine Equivalent Daily Dose (MEDD) dispensed naloxone. These efforts have resulted in 990 opioid overdose reversals reported since initiation of the program.

Ensuring that VA consumers get the care they need post-overdose is critical and often lifesaving given the high rates of mortality following non-fatal overdoses (e.g., one study found that one in 10 individuals with a non-fatal overdose die within two years).

For additional information on the on-going efforts of the Rapid Naloxone Initiative, please visit VHA Academic Detailing Services’ Opioid Overdose Education and Naloxone Distribution (OEND) (https://www.pbm.va.gov/PBM/academicdetailingservice/Opioid_Overdose_Education_and_Naloxone_Distribution.asp) and https://www.ci2i.research.va.gov/CI2IRESEARCH/resources.asp

#### Suggested Readings

1 Oliva EM, Christopher MLD, Wells D, . Opioid overdose education and naloxone distribution: Development of the Veterans Health Administration’s national program. J Am Pharm Assoc. (2003). 2017;57(2S):S168–S179 e164.
2 Bounthavong M, Harvey MA, Wells DL, . Trends in naloxone prescriptions prescribed after implementation of a National Academic Detailing Service in the Veterans Health Administration: A preliminary analysis. J Am Pharm Assoc (2003). 2017;57(2S).
3 Veterans Health Administration Innovation Ecosystem: https://www.va.gov/INNOVATIONECOSYSTEM/views/who-we-are/diffusion-of-excellence.html