# Implementation Check List

Implement an Intervention

◻ Select implementation strategies
  Deploy implementation strategies to promote uptake of EPs
◻ Tailor strategies to local settings
  Tailor based on mechanism of behavior change, EP complexity, setting variation, phase of implementation, etc. Consider technical, adaptive, and relational skill sets
◻ Disseminate implementation plan and support tools
  Create a playbook for frontline providers and interventionists

Activate Implementation Teams

◻ Convey top-down practice support “push” to local sites from leadership
  Transactional-focused strategies promote accountability and technical skill building
◻ Empower bottom-up “pull” to enhance stakeholder buy-in at local level
  Transformational-focused strategies empower individual stakeholders to develop skills, strengths, and motivation to “own” the change process
◻ Create stakeholder feedback channels
  Foster psychological safety and learning climates/ cultures

Develop Measures and Data

◻ Report progress to stakeholders
  Provide feedback on goal attainment to multi-level stakeholders
◻ Make data accessible to stakeholders
  Effective use of data helps foster learning and monitoring of clinical impact
◻ Adjust plan based on feedback
  Local teams should iteratively refine implementation to optimize local fit and uptake