# Sustainment

Sustainment^3^ is a process that involves:

- Assessing the effective practice’s performance on an ongoing basis
- Adapting the effective practice over time to maintain or improve clinical effectiveness
- Periodically reviewing to decide whether to continue to sustain a practice or de-implement it
- Creating a business plan to support ongoing effective practice delivery

The goal of this phase is to integrate the effective practice into habitual workflows in clinical care settings and employ it at the local health care facility level without special external support, such as grant or start-up funds.

A defining characteristic of a sustainable practice is that it is viewed as an essential part of ongoing routine clinical care and is valued by both providers and by organizational leaders at the local and system levels.

## Sustain an Intervention

What’s in this section?

Key Concepts

Sustainability describes the extent to which an effective practice can continue to be delivered, especially if external support or funding ends.^8,247^ An effective practice only has an impact on its intended consumer population if it is reliably delivered over time.

Sustainment is not a final endpoint for frontline clinicians unless the practice is de-implemented or stopped in favor of a new or more effective practice. The goals for Sustainment are to:

- Integrate the practice into care so it is viewed as a routine practice or habit
- Continue to fully deliver the core components of the effective practice over time
- Take ownership of the effective practice by building ongoing costs and processes to sustain the practice in local operating budgets and decision-making

Sustaining an effective practice involves a combination of disciplined use of data and operational flexibility to handle a rapidly changing health care environment. Local implementation leaders work with frontline stakeholders to develop and test adaptations to support program effectiveness and fit for new and/or changing contexts and population needs.^54,59,248^ Ideally, implementers strive for continuous improvements over the prior periods’ performance even as returns diminish over time as the improvements become smaller.

Do not assume a practice will continue after start-up funds for an implementation initiative go away. Rather, research suggest that the majority of implementers struggle to sustain the gains achieved during Implementation efforts due to an inability to fully sustain all components of an effective practice.^249–251^

Reductions in practice outcomes suggest a poor fit between the practice and its context. Following initial implementation, practices that sustain performance gains after adoption (“holding the gains”) represent a neutral to slightly less favorable implementation outcome because outcomes are not continuing to improve. A negative result happens when outcomes relapse over time to levels close to Pre-implementation.^252^

As Figure 18 shows, multilevel factors can interact to influence an organization’s capacity to sustain a practice. These factors involve characteristics of the effective practice, the people delivering the intervention, implementation processes, factors specific to an organization, and external environmental influences. Many of the specific determinants influencing sustainability are cataloged by investigators to help guide planning and decision-making.^248,253^

Table 18 Multilevel Factors Influencing Sustainment: The Integrated Sustainability Framework

Adapted from^248^

### Planning for Sustainment

The Program Sustainability Assessment Tool (https://sustaintool.org/) offers an efficient way to better understand multilevel factors that can be underdeveloped and negatively affect a practice’s ability to be sustained.

The tool organizes these factors across eight domains, including:

- Funding stability
- Partnerships
- Communications
- Organizational capacity
- Program evaluation
- Program adaptation
- Strategic planning
- Environmental

Strategic planning—the capacity to define the program’s goal, direction, and strategies—is the central domain on which all the other capacities are dependent. Planning for Sustainment can take place during Pre-implementation^118,196^ by using resources like the Program Sustainability Assessment Tool to assess an organization’s areas of weakness in supporting new clinical practices. Accordingly, you can target specific organizational structures and processes for strengthening during Implementation using strategies suggested by Leeman and colleagues to improve integration of the practice into routine care, build capacity for sustained use, and support the scale-up of the practice to other clinics, services, and facilities in your health system.^27,83,103^

Table 19 Classifications of Implementation Strategies Used to Build Capacity for Effective Practice Sustainment

Classification | Target for strategy action | Examples of specific Expert Recommendations for Implementing Change (ERIC) implementation strategies
Integration strategies | Factors that enable or impede optimal integration of a specific effective practice into a specific setting by helping frontline stakeholders address barriers to implementation among clinicians or inner organizational setting | For a specific effective practice:; - Institute reminder systems; - Revise clinician roles and responsibilities; - Provide supervision/ feedback; - Modify medical record systems; - Implement tools for quality monitoring (process, fidelity)
Capacity-building strategies | Motivation and capability to engage in implementation process strategies (in general but not to a specific effective practice) carried about by individuals, teams, and systems that build frontline stakeholders’ general delivery capacity by targeting individual-level and implementation process determinants | Across multiple settings:; - Training to build general capacity; - Technical assistance and facilitation for implementation processes; - Tools to support implementation processes
Scale-up strategies | Motivation and capacity to integrate a specific effective practice into a health system using individuals, teams, and systems that build frontline stakeholders’ innovation-specific delivery capacity by targeting individual, inner-setting, and outer-setting barriers or weaknesses | Across multiple settings:; - Training to build capacity specific to effective practice; - Technical assistance and facilitation (specific to effective practice); - Implementation toolkits; - Learning/quality improvement collaboratives; - Benchmarking; - Infrastructure development; - Changes to service fee lists or medication formularies

Adapted from^103^

Some of the general capacity strengthening strategies may be accomplished by support services funded by centralized operational offices, such as technical assistance, training, or practice facilitation/improvement coaching. Some innovation-specific capacity-building strategies should be carried out by local implementers to optimize fit of the new practice with the setting.

### Develop a Business Plan to Continue Effective Practice as Routine Care

Increasingly, local health care organizations are asked to take a more entrepreneurial role in the ownership of effective practices and quality improvement projects after initial implementation resources go away.^254,255^

During Implementation, local hospital leaders and managers plan for Sustainment in a critical and systematic way. Program evaluation data from Implementation can help develop a customized business plan.

When planning from a business perspective, the focus becomes centered on customer service and creating value in a financially sustainable way. A business plan requires thinking about:^254^

- Establishing new sources of funding support
- Justifying how a practice fits in the organization’s mission, structures, and clinical processes
- Setting performance benchmarks to determine practice effectiveness
- Spreading costs among and coordinating with partners (other services, operational offices)
- Demonstrating value of the practice
- Analyzing efficiency
- Determining cost per unit of service
- Calculating break-even points

To make a case for sustaining or spreading a practice within a health system, consider presenting the effective practice’s cost analysis, showing the return on investment on the implementation strategies used to promote practice uptake.

Decision makers may also desire a cost-effectiveness analysis, which compares costs to changes in quantitative measures of health-related outcomes or standardized outcomes, such as quality-adjusted/disability-adjusted life years as in the case of a cost-utility analysis.^172,178,256^ Consider presenting analyses from the perspectives of multiple stake-holders, such as payers, consumers, and communities.

A business plan can substantiate shared costs by different service departments and systems-level program offices. For example, effec tive practices designed to treat complex health conditions, such as cancer, heart failure, or serious mental illness, need care coordination across multiple clinicians.

Costs need to be spread across participating services or units. Some fundamental delivery capabilities may be best “owned” by a centralized operational office, such as ongoing provision of audit and feedback or technical assistance on complex issues (e.g., billing and service coding decisions). Understanding how these costs are shared locally and with national or regional program offices can help improve local budget decision-making.^212^

The VA’s Health Services Research and Development Service Health Economics Resource Center (HERC) (https://www.herc.research.va.gov/) is as an embedded national resource center that supports VA economic research^173^ to increase health care efficiency and value for Veterans and the nation. HERC provides tools and resources to assist researchers and operational leaders in conducting economic analyses for implementation research.

### Monitor for Change in Effective Practices and Whether a Different Practice is Needed

There are several reasons to reassess the decision to sustain or discontinue use of a clinical practice:

- Change in the evidence for the benefits (or harms) of a practice
- Change in clinical practice guidelines related to the practice
- Release of a new or similar clinical practice with greater benefits

While the health care field puts a strong emphasis on adopting effective practices, less attention is put on the equally important decision to de-implement low-value care practices.

Low-value care can be defined as health care services or treatments that provide little or no benefit to consumers, have the potential to cause harm, incur unnecessary costs to consumers, or waste limited health care resources.^40,41^

De-implementation is a situation when an established effective practice is reduced, replaced, or stopped because it has been found ineffective, harmful, inefficient, or no longer necessary even in the absence of a specific, superior alternative practice.^44,45,47^ Table 20 illustrates the continuum or reasons for de-implementing an effective practice.

Table 20 The Continuum of De-Implementation of Low-Value Care Practices

| Reduction or partial reversal | Related replacement | Unrelated replacement | Full reversal or discontinuation
Description | Reducing the frequency, breadth, intensity, or scale of an existing practice so it is only provided to a sub-group of consumers who have been proved to receive the most benefit | Replacing an existing practice with a closely related and more effective practice | Replacing an existing practice with a more effective intervention unrelated to current care | Universally stopping an ineffective or contraindicated practice
Examples | - Lengthen interval of cervical cancer Pap smear from one to three years; - Initiate breast cancer screening at age 50 vs. age 40 for women of average risk; - De-intensify diabetes medications in older adults | - Replace inhaled corticosteroids with long-acting beta agonists or muscarinic antagonists; - Perform coronary procedures via radial artery rather than femoral artery | - Physical therapy instead of opioids; - Chronic stable angina treated medically instead of with coronary bypass surgery or percutaneous coronary interventions | - Stopping hormone replacement therapy for prevention of chronic conditions in postmenopausal women; - Choosing Wisely recommendation against pre-operative or procedure electrocardiogram screening for asymptomatic consumers with low perioperative risk of death or myocardial infarction
Effects on clinicians | - May reduce clinical efforts by requiring only continued effort on a subset of consumers; - New clinical efforts needed for risk stratification to identify and appropriately treat eligible consumers | - Little impact on clinical efforts and practice patterns over the long term because substituted practice largely fits existing workflows | - Requires engagement and buy-in from at least two different stakeholder groups to implement the unrelated practice and change old clinical behaviors and workflows | - Focus on deimplementation of procedure and no new practices added

Adapted from^44,45^

In large health care systems like the Veterans Health Administration, de-implementation is highly relevant when addressing the common occurrence of overtreatment and over-testing among older adults. Most clinical practice guidelines continue to focus on how to escalate care intensity rather than on how to de-intensify treatments and tests.

National campaigns—such as Choosing Wisely^®257^—call for the reduction of inappropriate services or prescriptions; however, most of these recommendations focus on reducing one-time diagnostic procedures or treatment services at the start of a discrete episode of care. There is an absence of guidance for both consumers and clinicians on how to begin to stop or reverse the intensity or frequency of clinical practices that are part of a consumer’s ongoing care for a chronic condition.

Implementation scientists have observed a number of significant barriers to de-implementation among health care clinicians and organizations:^258^

- Few clinical trials examine de-implementation, leading to less evidence to guide clinicians’ decisions in terms of de-implementing care or stopping a clinical practice
- Clinicians may be suspicious of the degree to which cost savings are behind a de-implementation recommendation
- Clinicians may be concerned about how de-implementing a practice might affect their score on performance measures or their exposure to legal liability
- Lack of time and effective decision-support tools limit discussions related to de-implementing low-value practices in a consumer’s treatment plan

#### Using the Roadmap to Systematically De-Implement Low-Value Care Practices

De-implementation is a new and evolving area of health care. While it is not always clear when and how to de-implement a clinical practice, the roadmap provides a general framework with which to approach this practical problem:

1. Identify and prioritize practices that may be appropriate for de-implementation
  - Refer to clinical practice guidelines for practices to reduce, replace, or discontinue
  - Use local outcomes data to identify practices that no longer yield high-value results
  - Look to health services literature on guidance for de-implementing services in a particular area of clinical care
2. Engage relevant stakeholders in the process of planning and de-implementing
  - Seek to understand various perspectives on how to most efficiently overcome barriers and change clinician behaviors
3. Assess relevant multilevel factors when de-implementing a practice
  - Consider how widespread the practice is in use in the system
  - Anticipate the possible resources needed to de-implement the practice
  - Consider the impact of de-implementation on clinicians and organization units
4. Use behavioral change theory to identify and select implementation strategies^259–261^
  - Consider training, education, reminder prompts, and audit and feedback strategies as necessary but insufficient to change clinician behavior
  - Look to social psychology and behavioral economics for more advanced strategies to change clinician behavior to cease or reduce the low-value practice and adopt new alternative behaviors and decision-making processes^262^
5. Implement and evaluate the execution of de-implementation strategies
  - Use performance measures developed to monitor the de-implementation of health care services to overcome clinical inertia and hold clinicians accountable^263,264^

### Weigh Costs of Maintaining the Effective Practice

Use a strong evaluation plan to reassess the continued sustainment of an effective practice. Sustainable clinical practices can demonstrate program value through measurable results and program evaluation.^255^ Clinical practices are more likely to be maintained when they show—through established quality indicators and performance measures—that the practice benefits key stakeholders.^265^ Nonetheless, while the strength of practice outcomes is helpful, evidence suggests that some programs continue to persist even when they do not show clinical effectiveness.

Another consideration is the return on investment of scarce resources. Could the resources that are allocated to sustain a specific practice be employed more effectively to generate greater returns on consumer health outcomes and quality indicators? This is both an economic and ethical cost-benefit analysis that should be considered from multiple perspectives, including the perspective of consumers and their families, the hospital, and the community.

## Transition Ownership to Stakeholders

### Provide Management Support

The goal for the effective practice implementation project is for the effective practice to be supported internally without the need for external support or management. Because of this, for prolonged sustainment, leadership and management should recieve guidance and training on how to support the practice, including the identification and use of implementation strategies and other required resources, monitoring of practice use and maintenance over time, and opportunities for adaptation where appropriate.^266^

An implementation plan (i.e., an implementation playbook) that describes the implementation processes for the effective practice is essential for operations to ultimately own and sustain the practice over time. As the practice is integrated to become routine, implementation activities should shift from innovation-specific capacity-building strategies to general capacity-building activities, including training (e.g., booster sessions, onboarding new staff), establishing standard operating procedures, updating tools, and maintaining evaluation and feedback systems.

### Plan and Budget for Resources

Local leaders must understand how the investment into the implementation impacts their annual operating budget. Commonly, health care leaders want to know the total annual cost of the clinical practice, its components (including implementation costs), return on investment, and budget impact analyses help justify the benefit of committing resources in one practice compared to investments in other clinical solutions.

In an era of rising health care costs, competing demands to implement new practices, and constrained resources, economic evaluation measurement practices establish accurate estimates of practice operating costs. Implementation evaluators should work with health system economists and business analysts to adopt evaluation methods to track and develop accurate financial estimates for budgeting purposes.^267^

Economic evaluation of implementation costs is an evolving area of research. Presently, most estimates of these costs are based on periodic activity-driven assessments of the effort and resources employed across each phase of the implementation process.^268^ The Cost of Implementing New Strategies^178^ is a new, activity-based evaluation approach that enables the estimation of both direct and indirect expenses needed to complete an implementation task or activity. The Cost of Implementing New Strategies evaluation demonstrates that resource allocation, particularly of direct costs, varies by stage of implementation. Cost structures can also differ between competing implementation strategies that are delivering the same practice.

The beliefs of middle managers and medical center leadership in terms of program importance are key to garnering support for resources (e.g., space, dedicated full-time equivalent, materials). A manager’s ability or willingness to promote or support budget funding for a practice depends on the alignment of practice activities with hospital priorities and needs.^85^ Hence, it is essential to work with staff and leadership to understand the value of an effective practice.

### Support Continuous Learning and Innovation

Best practices related to effective practice delivery, evaluation, and conceptualization are continually evolving based on new research findings and practice implementation trials. Similarly, best practices related to program evaluation are under continual refinement to assist staff and leadership in obtaining the most accurate and useful view of their clinical practice performance.

Some complex practices that have been widely implemented in health systems using strategies like communities of practice, virtual learning, or quality improvement collaboratives. These cases represent a cost-effective sustainment strategy for stakeholders to share innovations, problem solve emergent challenges, and share new information. Locally, managers and leaders should ensure local training budgets anticipate the need for training new staff, providing booster sessions, and supporting professional development of new skills that support quality improvement for the effective practice.

Finally, new quality metrics are continually being developed and launched to the field by health care leadership with the expectation that sites and operational programs will be aware of such measures and their application. Rollout of new performance measures should plan to provide basic training and education materials to ensure staff and clinicians can accurately use and interpret new metrics. Sites must maintain an awareness of these shifts in knowledge and the ways to apply such shifts to the oversight and delivery of their effective practice.

## Ongoing Evaluation and Reflection

### Consumer Outcomes

A key aspect of deciding whether to sustain an intervention is the demonstration that an effective practice continues to generate quality outcomes for consumers, particularly at a population level. Health systems should leverage information technology systems to extract administrative and clinical data to provide low-cost reporting systems to enable system leaders to monitor individual and population consumer outcomes to ensure continued benefits of a practice with respect to access, morbidity, mortality, unnecessary use, accidental harms, and consumer savings with respect to more efficient care delivery.

Outcomes should include consumer-reported outcomes, such as improved quality of life and satisfaction with care. When a practice fails to consistently attain benchmark standards of effectiveness, quality, or consumer satisfaction, system leaders should review alternative options to enhance outcomes, starting a new cycle of de-implementation and Pre-implementation planning.

### Delivery of the Effective Practice

Consistent with new perspectives on the roles of fidelity and adaptation in sustainment, evaluators and clinicians strive to optimize the fit between the practice and the external environment in which it is delivered.^59^

Ongoing monitoring and assessment of clinical outcomes and contextual characteristics are needed to provide feedback regarding practice effectiveness. Using practical measures, such as checklists to assess aspects of fidelity and adaptation, can enable clinicians to be sensitive to changes in the fit between practice and context. Similarly, continuously engaging stakeholders over time can increase fit while developing solutions that might cause problems with Sustainment.

Consistent with a learning health system approach, clinicians are encouraged to test effective practice adaptations using pilot trials and rapid-cycle tests to determine how to optimize and improve the practice rather than let it remain static.

As a practice spreads over diverse settings and consumer populations within a system, evaluators should ensure adopting sites fully implement all components of a practice to avoid partial Sustainment. Furthermore, managers and clinicians should establish communication channels to problem solve delivery challenges and share positive adaptations and practices (e.g., communities of practice, virtual quality improvement collaboratives).

### Clinician and System Costs

The impacts of implementing an effective practice on the delivery system should be assessed against the impact on clinicians and strategic measures of health system performance.

Commonly, health system leaders are interested in understanding how key clinical practices support whole system measures to assess overall performance of the health care system in achieving strategic goals, such as the Quadruple Aim: improving population health, enhancing the individual consumer experience of care, decreasing per capita cost of care, and improving the work life of health care clinicians, including clinicians and staff.^269,270^

Evaluators should also consider the costs and benefits of sustaining an effective practice against indicators of workforce resilience. For more intensive clinical practices, it is important to consider the impact a practice has on clinician performance through key indicators like clinician satisfaction, well-being, and job burden. System administrative data and workforce surveys can provide evidence for the benefit or burden associated with the delivery of the effective practice over time compared to clinicians delivering comparable practices. Other indicators might include:

- Job-career satisfaction
- Clinician satisfaction
- Burnout
- Control over work
- Clinician turnover
- Likelihood of leaving current practice within X years
- Patient panel overcapacity
- Working extended hours
- Work-life balance