# Pre-Implementation Check List

Identify a Problem and Solution

◻ Identify high-priority need and goals
  Establish a shared understanding of the problem to be solved by the EP
◻ Agree on effective practices (EP) and settings
  Use systematic reviews and literature to identify and employ best EPs
◻ Clarify EP core elements, adaptation options (consumer, provider input)
  Establish fidelity measures, work with end users and consider contextual needs to explore adaptations, pilot and track adaptations

Engage Stakeholders

◻ Cultivate leadership/stakeholder support
  Seek input early and often from leaders, mid-managers, and frontline stakeholders
◻ Assess capacity, including barriers and solutions to EP delivery
  e.g., Implementation Mapping, process frameworks
◻ Package EP with delivery adaptations
  Match implementation strategies to barriers, create toolkit with menu of adaptations

Develop Measures and Data

◻ Design evaluation to match goals
  Select an evaluation design that is feasible and answers operational questions
◻ Identify measures of success and data sources
  Develop data collection plan selecting a limited number of meaningful, pragmatic, and relevant measures, using qualitative methods strategically
◻ Establish baseline performance
  Establish baseline performance and set realistic target benchmarks