# Implementation

Implementation involves finalizing the selection and deployment of implementation strategies to enhance uptake of an effective practice. Implementation can be enhanced through the strategic use of both transactional and transformational management strategies that help the frontline workforce successfully integrate the evidence-based innovation into routine clinical practice. ^108^

- Implementation requires strategies and an implementation plan adapted/tailored to variations across potential adoption settings and sites to address local barriers and resource constraints.
- Implementation strategies combine technical, adaptive, and relational skill sets to spread and integrate the effective practice for Sustainment and use transformative leadership approaches to empower frontline workers to own their local implementation process.
- Measurement information and reporting systems should provide timely feedback on implementation progress relative to performance benchmarks, engage multilevel stakeholders in iterative problem-solving to adjust implementation plan strategies, and find ways to improve performance and spread the practice to other settings.

## Implement an Intervention

What’s in this section?

Key Concepts

### Select Implementation Strategies

Implementation requires you to decide which strategies to use to support practice uptake based on Pre-implementation planning. Implementation strategies are methods or techniques used to enhance the adoption, implementation, scale-up (or spread), and sustainment of a program or practice.^71,126,202^ They detail how to implement a practice as part of an implementation plan.^71^

Adopting an innovation is challenging because it requires changing the ways in which people act and think about delivering “routine” care services. Implementation strategies are action-oriented, theory-based methods that support behavior change at the clinician, team, service, and organizational levels.

Implementation scientists have compiled and defined nearly 80 individual implementation strategies. The Expert Recommendations for Implementing Change (ERIC) study classified these according to nine categories of similar strategies (Table 10).^126-128,203^

Table 10 Examples of Implementation Strategies Across Nine Thematic Categories^*^

Use evaluative and iterative strategies | Audit & provide feedback, conduct rapid cycle PDSAs, stage implementation scale-up
Provide interactive assistance | Facilitation, local technical assistance, clinical supervision, centralize technical assistance
Adapt and tailor to context | Tailor strategies, promote adaptability, use data experts, use data warehousing methods
Develop stakeholder interrelationships | Identify and prepare champions, obtain formal commitments, identify early adopters
Train and educate stakeholders | Develop educational materials, offer ongoing and dynamic trainings, provide consultation
Support clinicians | Clinician reminders, create new clinical teams, revised professional roles, relay clinical data
Engage consumers | Involve consumers and family members, use mass media, activate participants
Use financial strategies | Alter incentive structures, access new funding, alter consumer fees
Change infrastructure | Change record systems, change physical structures/equipment, change credentialing

* Adapted from ^126,127^

Implementation strategies aim to improve implementation outcomes, such as those detailed by Proctor and colleagues, including acceptability, adoption, appropriateness, feasibility, implementation cost, penetration, and sustainability. Achieving quality implementation outcomes is related to attaining improved clinical- and service-level outcomes.^160^

In Resources, we provide a comprehensive list of implementation strategies compiled by the Expert Recommendations for Implementing Change (ERIC) study^126,127^ and others^128^ that organizes strategies according to functional themes, defines each strategy, and provides information relevant to applying strategies to particular contexts.

#### Matching Strategies to the Complexity of a Practice

Many effective practices are considered “complex” because they consist of multiple components and steps as part of routine care. A complex practice may require the involvement and coordination of people working across different disciplines and levels of the health system to be successful.^204^ The interaction of complex practices with diverse settings, consumer populations, and delivery staff invites variation in how well a practice is delivered.

To ensure the successful delivery of complex, multi-component practices, multiple implementation strategies can be selected to enact changes across organizational levels. The Pre-implementation exercise from Table 1 advocates for strategies to target specific barrier(s) identified in your capacity assessment and seek to lessen the influence of these negative contextual factors. When strategies reduce barriers, optimize fit with context, and cause changes in practice delivery, efficiency, and consistency, implementation quality should increase, resulting in improved outcomes.

Across implementation strategies, there is significant variation in each strategy’s level of complexity, intensity, and ability to target specific implementation barriers.^64,205^ Not every strategy is effective or necessary in a setting to achieve an improvement efforts’ desired outcomes.^27,103^ However, it is helpful to prioritize strategies that are feasible to enact in light of available resources (e.g., time, people) and that have a high probability of making a positive impact on delivery processes.

Avoid targeting barriers that are not feasible to change or have a low impact on outcomes.

This variability across diverse sites and settings underscores the need for an implementation plan that strategically combines technical and adaptive strategies to help local sites efficiently overcome barriers and integrate a practice for a sustained benefit.^206^ We encourage managers and leaders to broadly think about implementation strategies that fit into one of two broad categories:

- Technical strategies include the application of trainings, resources, performance metrics, policies, and incentives to “push” an effective practice into use from a top-down leadership perspective. These strategies are consistent with transactional management practices by promoting accountability to organizational goals and performance standards while supporting frontline stakeholders’ ability to achieve these goals with competence and quality.
- Adaptive strategies “pull” the adoption of effective practices at the local level by engaging the intrinsic motivation and expertise of local stakeholders. These strategies are consistent with transformational management practices that seek to align a practice with local stakeholders’ interests, talents, and motivations to want to own and adapt the practice to make it sustainable for long-term use.

### Tailor Strategies to Local Settings

Select implementation strategies that improve the fit of an effective practice with local settings and consumers.

Implementation has traditionally been a top-down process largely overseen by either organizational leaders or investigators. This approach aims to build delivery system capacity through technical strategies, such as providing frontline workers with tools, trainings, technical assistance and audits with feedback on implementation performance.^83,110^ This approach is well-suited for situations when many of the adopting sites or teams possess sufficient capacity or self-motivation to adopt the effective practice with little support or connection to intrinsic sources of motivation.^108^

However, it is increasingly clear that basic strategies, such as guideline dissemination or clinician training, are insufficient alone to improve outcomes among sites facing significant local barriers and resource constraints.^207,208^ Implementation experts propose several practical—but theory-guided—ways to help you select strategies that proactively tailor a practice to local contextual needs and capabilities (e.g., practice facilitation, assess and redesign workflows).^27,64^

Until recently, there has been limited guidance on how to systematically match barriers and facilitators reported by stakeholders in Pre-implementation with these strategies.^64^ Evidence suggests that implementers and investigators repeatedly rely on the strategies they are familiar with rather than using individual and organizational behavior change theories to match appropriate strategies to the local barriers and capacity constraints.^209–211^ We offer a better way to approach this challenge.

Much like developing adaptation options to improve the fit of the effective practice for local end-users, you can tailor implementation strategies to account for local contextual factors as shown in Table 11.

Table 11 Examples of Factors to Tailor Implementation Strategies for Local Context

Factor to Address Through Tailoring | Examples
Characteristics of the effective practice ^212^ ^–^ ^214^ | Complexity, effectiveness, cost, cultural appropriateness, compatibility with local workflows
Characteristics of adopting settings ^27^ ^,^ ^213^ | Variation in innovation capacity, resource availability, leadership structures, organizational readiness
Characteristics and preferences of implementing stakeholders ^213^ ^,^ ^214^ | Location (hospital vs. clinic), supporting resources, size of team responsible for outcome, knowledge, discipline, motivation
Level of contextual barriers ^27^ ^,^ ^83^ | Consumer, clinician, clinic/service, hospital, system, or policy/external environment levels
Known health disparities ^73^ ^,^ ^76^ | Race/ethnicity, gender, geography, sexual orientation
Phase deployment or practice integration ^205^ | Pre-implementation, Implementation, Sustainment
Target action of strategy ^103^ | Dissemination, capacity building, implementation process, integration of practice into local workflows, or scale-up through health system
Stage of effective practice adoption ^93^ | Innovator, early adopter, early-majority adopter, late-majority adopter, late adopter

Depending on the complexity and scope of the practices being implemented, you should strive to design an implementation blueprint/plan that uses the most cost-effective mix of strategies to achieve your implementation objectives. This means your plan should have an adequate range of strategies to address the variation in barriers found across adopting sites. This mix of strategies serves as an implementation playbook for local implementation teams to cover essential tasks:

- Planning and preparation strategies
- Dissemination strategies to deploy the practice to adopting sites and contexts
- Implementation process strategies
- Capacity-building strategies for late adopters or sites with significant barriers to practice adoption
- Scale-up strategies to spread the practice within sites and to other sites in a system
- Strategies to integrate the practice for long-term sustainment without external support

Finally, as you develop a comprehensive implementation blueprint/plan, we encourage you to document the following decisions regarding the selection and use of implementation strategies.^71,103^

These evaluation details contribute to a learning health system by advancing institutional knowledge regarding what strategies were selected for deploying a specific effective practice and why. As an effective practice spreads, include these details in the practice packaging materials to help clinical end users understand why strategies were selected, what they entail, when they should be employed, and by whom.

Table 12 Evaluator Guidelines for Naming, Defining, and Operationalizing Implementation Strategies

Name it | Specify the behavior change technique or implementation strategy
Define it | Operationally define the implementation strategy and any discrete components
Specify it
The actors | Identify who enacts the strategy
The action | Specify the action, steps, behaviors, decisions, or processes
Action target | Identify strategy targets according to theory (i.e., barriers, facilitators)
Unit of analysis to assess implementation outcomes | Identify the level of the organization or health setting the strategy targets (e.g., individual, clinic, service, hospital, etc.)
Dose | Specify the dose (i.e., how much) of the implementation strategy is delivered
Time/phase | Identify when the strategy is used
Implementation outcome | Identify the implementation outcome(s) likely to be affected by each strategy
Justification | Determine theoretical or empirical justification for the implementation strategy

Ongoing process evaluation can help stakeholders understand when these implementation strategies worked, where they were effective (or not), and how much these activities cost to deliver effective outcomes. This information influences future decision-making by creating an evidence base of implementation strategies that would be most effective and yield the greatest return on investment for similar effective practice deployments.^71,215^

#### Tailoring Your Implementation Plan for Rates of Practice Adoption

For effective practices to impact populations, consider how practices are spread and adopted by clinical sites and consumers.^216^ The diffusion of innovations theory is helpful in understanding the process by which an innovation is communicated over time through members of a social system or network.^108^ Four key concepts relate to the concept of diffusion and are defined in Table 13.

Table 13 Key Concepts in Diffusion of Innovations Theory

Concept | Definition
Innovation | An idea, object, or practice that is perceived as new by an individual, organization, or community, and is intended to be spread
Communication channels | The means of transmitting the new idea from one person to another
Social system | A group of individuals who adopt the innovation together
Time | How long it takes to adopt the innovation

Adapted from^8,108,216^

Diffusion of an effective practice requires a multilevel change process that usually takes place in diverse settings with different implementation strategies.

- At the individual level, adopting a new clinical practice involves changing the behaviors and thought processes of relevant clinical stakeholders (e.g., attitudes, beliefs, knowledge, motivations).
- At the organization level, it may entail redesigning clinical workflows and processes, changing standard operating procedures, or altering professional roles and responsibilities.
- At the community or systems level, diffusion can include using media, advancing new policies, or building coalitions to support a practice or initiative.

According to E.M. Rogers, the author of the diffusion of innovations theory, several factors determine how quickly and to what extent an innovation is adopted and diffused.^108,216^ By considering the benefits of an innovation (see 4), it can be introduced effectively to appeal to important clinical opinion leaders.

Table 14 Key Attributes Affecting the Speed and Extent of an Innovation’s Diffusion

Attribute | Key Defining Question
Relative advantage | Is the innovation better than the innovation it replaces?
Compatibility | Does the innovation fit with the intended audience’s needs?
Complexity | Is the innovation easy to use?
Trialability | Can you test the innovation before making a decision to adopt?
Observability | Are the results of the innovation observable and easily measurable?

Adapted from^8,108,216^

Rogers found that the process of adoption follows a classic “bell curve” distribution of readiness and ability (Figure 15). The diffusion of innovations theory specifies five categories of adopters: innovators, early adopters, early-majority adopters, late-majority adopters, and late adopters.^108^ When an innovation is introduced, the majority of people are either early- or late-majority adopters with fewer who are early adopters or late adopters. Very few are innovators who are the first to use the innovation.

Figure 15 Scale-up and Spread Process Across the Diffusion of Innovations Curve

During scale-up and spread, different types of implementation strategies may be more effective in reaching the adopters you are trying to engage. A recent report from the VA Evidence Synthesis Program (https://www.hsrd.research.va.gov/publications/esp/reports.cfm)^93^ highlights a few ways to reach audiences that are hard to engage in a “re-personalize” phase that emphasizes a tailored approach more often seen in the earliest phases of spread when customizing a clinical practice to a small number of innovator pilot settings

Growing research evidence suggests that early-adopter and early-majority sites are characterized by greater capacity (i.e., buy-in, readiness, or implementation capacity) to adopt and innovate than late-majority sites, which might lack knowledge, motivation, skills, or other resources and supports to readily adopt a practice.^108,217^ Settings with greater implementation capacity are also likely to self-select and use more advanced implementation strategies, enabling them to achieve better clinical/quality outcomes than sites with less improvement capacity.^205,218^

While early-majority sites may function well with standard implementation strategies, such as training, tools, performance monitoring and feedback systems, and technical assistance,^219^ sites that are not early adopters may require more intensive, multi-component strategies like facilitation^220^ that employ a variety of discrete strategies over time to help local facilities problem solve implementation barriers. It is important to explore why these sites are not readily adopting the practice (e.g., due to limited resources or competing demands) in order to work with them to adapt practices and implementation strategies that fit their needs. The VA Evidence Synthesis Program’s Report on Scaling Beyond Early Adopters (https://www.hsrd.research.va.gov/publications/esp/scaling.cfm) is a good reference for addressing these types of barriers.^93^

Roger’s adoption curve can help planners tailor the timing and allocation of resources to build delivery capacity through basic implementation support strategies^48,83^ for majority adopters and more intensive and expensive implementation strategies for later adopters.^221^ To plan for Sustainment, it is critical for a practice to be fully implemented prior to the end of initial implementation start-up funding. Thus, selecting implementation strategies to overcome the unique challenges of late adopters helps a health system achieve a greater level of population impact for the long term.

### Disseminate Implementation Plan and Support Tools

Implementation begins with the dissemination of the effective practice package to participating facilities/clinics and may include training of the effective practice, technical assistance, and monitoring and feedback on key clinical outcomes. Dissemination strategies depend on practical considerations, such as the:

Health system leaders communicate expectations pertaining to the implementation effort, including differentiating resources available to the field, such as:

- Implementation timelines and milestone dates
- Data monitoring and reporting systems
- Repositories of implementation or effective-practice tools (e.g., toolkits)
- Centralized delivery support resources, such as technical assistance or other forms of support personnel (e.g., facilitators, improvement coaches, health information technology programmers)
- Local delivery support obligations (e.g., clinical champion, internal facilitation, obligation of local data programmers to support electronic-medical-record-template troubleshooting)
- Incentive structures, performance measure targets
- Implementation and clinical benchmarks relative to an implementation timeline

Scale-up plans can leverage system-wide assets that span the entire health system, including:^38^

- Shared information technology servers/networks
- Social media and marketing mechanisms (i.e., local and centralized services/channels)
- E-mail listservs
- Performance measure dashboards or clinical monitoring/reporting
- Practice-based research networks or quality improvement collaboratives among clinicians
- Existing clinical communities of practice (e.g., clinical program office calls, social media)

Effective dissemination involves understanding your key end-users, selecting the best communication channels for sharing information with internal and external stakeholders, and providing the most appropriate products for each stakeholder group (See Table 15). Effective dissemination increases demand for the effective practice and builds partnerships across levels of the health system.

Table 15 Dissemination Strategies to Increase Practice Uptake Among Stakeholders

Stakeholder | Communication Channel | Mode | Examples
Consumers and caregivers | Interpersonal | Word of mouth | - Clinician counseling; - Consumer peers/influencers; - Town halls at hospitals; - Meet with patient advocacy organizations
Consumers and caregivers | Mass media | Written | - Brochures, consumer guides, handouts, care summaries; - Posters, flyers in clinics; - Mailings; - Newsletters; - Emails; - Magazines, newspapers
Consumers and caregivers | Mass media | Media | - Information screens in clinics; - Social media (Facebook, Twitter, YouTube); - Public websites; - TV and radio ads
Clinicians and clinical teams | Interpersonal | Word of mouth | - Peers; - Clinical champions; - Academic detailing; - Internal/external facilitators; - Cyber seminars; - Conference presentations; - Communities of practice; - Quality improvement collaboratives; - Practice-based research networks
Clinicians and clinical teams | Mass media | Written | - Internal or professional newsletters, listservs Implementation toolkits
Clinicians and clinical teams | Mass media | Media | - Online continuing education trainings; - Electronic reminders; - Electronic decision aids; - Internal websites; - Professional blogs; - Clinical practice guidance; - Journal articles; - Evidence syntheses
Service and facility level workforce | Interpersonal | Presentations | - In-service; - Academic detailing
Service and facility level workforce | Mass media | Written | - Standard operating procedures; - New and ongoing training; - Local and national policies
Service and facility level workforce | Mass media | Media | - Centralized e-resources; - Podcast; - Health system messages; - Newspaper; - Radio
System and policy level | Interpersonal | Face to face | - Policymaker briefs; - C-suite briefs; - Patient advocacy
System and policy level | Mass media | TV, radio, social media, and internet | - News stories; - Editorials; - Commercials

Within the VA health care system, several operational entities support the spread and adoption of new practices through dissemination and diffusion strategies, including through a dedicated VHA Innovation Ecosystem (https://www.va.gov/INNOVATIONECOSYSTEM/views/explore/what-is-innovation-ecosystem.html) that features devoted personnel, facilities, and programming to support the spread and scale of promising practices.^35,36,38^

The VA’s Center for Information Dissemination and Education Resources (CIDER) is another essential resource center dedicated to supporting the implementation of effective practices by using various communication strategies, such as publications, cyberseminars, national meetings and conferences, social media, and both HSR&D and QUERI websites to share information with clinicians, managers, policymakers, investigators, and the general public.

### Planning for the Scale and Spread of an Effective Practice in a Health System

In large health systems like the Veterans Health Administration, there comes a point when health system leaders must plan for the spread and scale of an effective practice for sustained integration.

The sequence of improvement conceptualized by the Institute for Healthcare Improvement is displayed in Figure 16, which illustrates the lifecycle of an effective clinical practice or quality improvement innovation. Moving from testing to proof of concept under local conditions using either clinical trials or traditional rapid-cycle testing, the goal is to yield a reliable and robust clinical innovation that works well across diverse settings and populations. As the sequence shows, the ultimate goal is to develop a solid implementation plan that not only integrates a practice into routine care processes but enables the process to rapidly diffuse to other settings and locations.

There is not a clear consensus on these popular terms, which we operationally define as the following:^222,223^

- Spread refers to the adoption and replication of an effective practice from an original site of innovation to other facilities in a local hospital system, regional network, or national health system to reach more consumers eligible for the new practice (sometimes called horizontal scale-up).
- Scale-up involves deliberate system-level investments in infrastructure and fixed costs to ensure that the effective practice can be delivered to large numbers of consumers with diminishing marginal costs over time for sustainable outcomes. Scale-up often entails strategic planning and use of strategies to influence budgeting, policy and legal regulations, and knowledge sharing across an organization or system.

Figure 16 The Institute for Healthcare Improvement’s Sequence of Improvement^*^ * Reprinted with permission.

Spread and scale of effective practices is largely an understudied area in implementation science; however, we integrate the key elements necessary to spread an effective practice across units of a hospital and health system:^214,223–227^

- Emphasis on leadership and stakeholder engagement and alignment throughout the process
- Activation of social networks and communications at all levels of the organization
- Creation of a scalable effective practice intervention package and implementation plan
- Emphasis on an iterative and flexible approach to addressing implementation challenges at the local level while promoting accountability to performance standards
- Use of rigorous evaluation methods to monitor and revise implementation efforts
- Implementation of an effective practice with an emphasis on Sustainment

#### Igniting an Initiative to Bring a Practice to Scale

The Veterans Health Administration has considerable experience as a national health system in terms of developing innovative strategies to scale,^36,38,224,228^ yet considerable wisdom has been acquired from other sectors on this topic. In a 2015 Institute of Medicine workshop report,^229^ Joe McCannon, co-founder of the Billions Institute (https://www.billionsinstitute.com/) nonprofit for leading large-scale social change efforts, observed that three prerequisite factors are necessary for effectively taking an innovation to scale:

1. A promising practice with promising evidence to be built on through continuous learning and refinement going forward
2. Attention from influential leaders and stakeholders at national and local levels
3. A conducive environment that provides energy and attention for spread and scale fueled by a new policy or legislation, public attention, or an emergent crisis

The challenge is taking an effective local practice and scaling and spreading it more broadly in the face of real barriers. The health care “marketplace” is a crowded arena of competing practices in which any given practice is competing with a huge volume of new information, ideas, and innovations. There is little evidence that a promising practice will be taken up simply based on its merit or intrinsic value in the face of the following challenges.

Table 16 Barriers Undermining Change and Adoption of New practices

Conflicting values | Inertia
Need for business as usual | Resignation and apathy
Competition | Fear of change

Ten attributes and behaviors distinguish typical scale-up initiatives versus exceptional initiatives as summarized in Table 17.

Table 17 Attributes of Typical Versus Exceptional Spread and Scale Initiatives

TYPICAL | EXCEPTIONAL
Comprehensive strategy development | Bias toward starting
Emphasis on consensus | Invite debate and new ideas
General goals for expansion | Explicit, time-bound aims
Design for success | Design for success and scale
Broad knowledge of audience | Detailed audience segmentation
One stimulant | Many stimulants
One teaching/training method | Many learning methods
Replication | Adaptation
Summative evaluation is the priority | Formative evaluation (daily data) is the priority
Management gives the approval | Management removes barriers

Source:^229,230^

The Institute of Medicine summarized many observations by McCannon for successful scale and spread initiatives:

- [image] Get started. The natural tendency in a typical initiative attempting to scale a complex health practice is to take considerable time to comprehensively plan for all potential contingencies and outcomes that create inertia. The best way to address complexity is to engage in the process and get started.
- [image] Avoid pleasing all stakeholders. Typical initiatives place a strong emphasis on attempting to achieve consensus among all stakeholders, which is difficult to achieve in a health system. Focus on obtaining broad consensus on the aim of the initiative but not on the process of smaller steps to enact it.
- [image] Understand what full scale looks like. Successful initiatives have clear, time-bound aims and a concrete vision of what the scale-up initiative needs to accomplish. Define what full scale looks like in terms of a number of sites that will spread the practice.
- [image] Design for Success and Scale. Most resource-intensive initiatives struggle to scale because they only design for success and do not address the need to reduce costs and develop economies of scale over time. Consistent with Roger’s diffusion of innovations theory, a scalable practice should be simple, user-friendly, and allow potential adopters the ability to easily test and clearly see the practice’s benefits and value for their setting. Exceptionally designed scale-ups also plan for infrastructure needs as the practice spreads (i.e., people, financings, space, equipment and supplies, data collection, technology, logistics and oversite).
- [image] Understand the audience. As noted previously by Roger’s diffusion of innovations theory and a recent VA Evidenced Synthesis Report, it is crucial to understand that adoption of a practice occurs over a predictable range of distribution. It helps to segment the audience of stakeholders with the influence to adopt a practice based on different characteristics such as discipline (e.g., administrator, physician, nurse), geography (e.g., state, region), readiness for the practice (e.g., experienced, intermediate, novice), type of facilities (e.g., medical center versus community-based outpatient clinics), and the relevant mix of customers served by a facility (e.g., demographics, military service era).
- [image] Positive stimuli. A stimulus is the incentive or driving force for change. A typical health care initiative to spread a practice is dominated by one stimulus—payment. In contrast, successful initiatives use several different stimuli that range from positive to negative to drive change. Effective stimuli provide emotional connection, empowerment, collaboration, recognition, enjoyment, transparency, sense-making, scientific evidence, and if necessary, regulation or punishment.
- [image] Teaching versus learning. Commonly, initiatives are scaled out relying on one teaching method to learn an innovation centered around a didactic lesson in which practice users are passive learners. Successful scale initiatives rely on multiple methods of learning through hands-on applications like the Plan-Do-Study-Act cycle. Active implementation strategies—like practice facilitation—help frontline clinicians actively engage in mastering a practice through interactive problem-solving and reflection.
- [image] Replication versus adaptation. Consistent with our principles, scale and spread cannot rely simply on the static replication of an effective practice, but must have a focus on disciplined adaptation to address changes in consumer populations, policies, and local contexts.
- [image] Evaluation. While traditional scale-up initiatives often are heavily funded to determine summative outcomes (i.e., whether a practice works), exceptional initiatives focus on providing timely data (e.g., daily) to make frequent refinements to implementation on a regular basis.
- [image] Management Approach. In large scale and spread efforts, it is easy for leaders to fall into a trap in which they tightly manage efforts through data-monitoring systems that rank performance and provide approval to high performers and punishment to low performers; this results in a culture of fear and manipulating the system. In comparison, leaders who are successful at having impact at scale use their time productively to work with local and regional facility leaders to identify specific barriers to practice uptake and use their influence to remove these barriers. This management practice promotes a culture of positive collaboration versus fear and helps frontline stakeholders invest in the outcomes of the scale and spread initiative. Similarly, it is also important to develop shared culture and values among clinical stakeholders to embrace quality improvement and the adoption of new innovations using implementation strategies.

## Activate Implementation Teams

### Leadership Uses Top-Down Practice Support to Push Change to Local Sites

Implementation includes the use of leadership management styles to help enhance the uptake of new effective practices through a mix of transactional and transformational leadership practices. The behaviors of senior organizational leaders have a significant influence on creating an organizational climate, culture, and environment conducive to innovation, learning, and improvement.

- [image] Transactional leadership practices are ideal for making incremental changes to current organizational policies and procedures by using incentives and disciplinary power to motivate employees to meet performance objectives or targets.^231–233^ This style is well-suited for pushing out new effective practices and developing the systems to monitor performance.
- [image] Transformational leadership practices support collaborative work through teams to identify a change, create a vision to inspire employees to persevere through the change, and work with employees to achieve a goal for the greater benefit of the organization. This leadership style motivates frontline employees and middle managers by engaging and empowering them to take an active role in the implementation process. Transformational strategies help improve employee morale and satisfaction by aligning tasks with personal values, encouraging skills development, and inspiring greater ownership of their work.^234,235^

In supporting the implementation of a new effective practice, transformational leadership is instrumental in bringing stakeholders together to develop an improvement aim that aligns with stakeholders’ needs and demonstrating how it addresses local “pain points”. However, transactional leadership is useful for creating the “push” to get a policy, mandate, or clinical directive disseminated by creating structures that create accountability for local leaders and clinicians who implement the practice. As mentioned above, the use of positive and negative stimuli/incentives is important and generally should fall on an 80/20 ratio of positive- to negative-incentive strategies.

Transactional practices rely on implementation strategies that align rewards for meeting performance benchmarks with respect to goals and targets for adoption, implementation, and change in clinical outcomes. Transactional leadership practices aim to promote accountability using measurement-based systems, job descriptions, and clinician/leadership incentive programs aligned with implementation outcomes.

While transactional leadership strategies create structures to support quality implementation of an effective practice, evidence suggests that transformational leadership practices are more consistent with the tenants of a learning health system. In organizations emphasizing these principles, there is greater uptake of practices, improved clinical and implementation outcomes, increased job satisfaction, and decreased employee turnover, burnout, and demoralization among frontline stakeholders.

### Empower Bottom-Up Pull to Enhance Stakeholder Buy-In at the Local Level

Implementation strategies should not only aim to build capacity to implement a specific effective practice, but to build broad capacity at the local level to implement future practices and innovations as skills are developed in these methods.

Empowering local frontline clinicians and managers to decide on the strategies to implement the effective practice in their facility fosters ownership in the process, and in turn, motivation and commitment. Clinical champions can garner motivational support by reframing the implementation process as an opportunity for local clinicians to learn and own the process, rather than using punitive strategies to shame, penalize, or criticize the local team.

For complex innovations, like implementing a new model of care, empowering frontline staff (e.g., medical assistants, support staff) by changing roles and responsibilities can be challenging,^236^ but these adaptations offer the benefit of reducing clinician burnout by allowing staff to work at the top of their license. Effective implementation efforts require a combination of skill sets to help sites adopt and sustain a practice:

- [image] Technical – Content expertise about the effective practice; proficiency in relevant evaluation practices pertaining to fidelity/adaptation assessment, performance benchmarking, and process evaluation; and knowledge on how to match capacity-building strategies to meet local site needs
- [image] Adaptive – Capability to address variations in local organizational and clinician capacities; readiness to adopt a practice by fostering user-centered design principles; problem-solving solutions to workflow redesign and technology challenges; and identifying and repairing local structural weaknesses to support practice sustainment
- [image] Relational – Capability to employ motivational and psychological strategies to encourage organizational change across interdisciplinary stakeholders and distributed levels of management and leadership

A learning climate is created when leaders integrate implementation efforts into organizational missions by prioritizing efforts, setting goals, and fostering accountability while empowering frontline stakeholders to make changes that lead to innovation and improvement.^5,237^ This approach may be a change for leaders accustomed to traditional top-down management practices, but the long-term benefit is the development of resilient implementation capacity (e.g., knowledge, skills, communication channels) among frontline employees to support adoption of other effective practices.

### Create Stakeholder Feedback Channels

Reinforcing the establishment of formal communication channels allows stakeholders to share feedback on the progress of their implementation efforts.^238^ For rapid learning to occur, stakeholders should feel comfortable not only sharing the details of successful strategies to overcome implementation challenges, but also the failures.

A prerequisite condition for these channels is the establishment of psychological safety,^239,240^ the perception that stakeholders can take interpersonal risks without suffering punishment.^241^ In a psychologically safe environment, individuals are willing to contribute ideas, questions, and concerns, which supports learning. In environments where leaders do not foster psychological safety, individuals are less willing to speak up for fear of being perceived as ignorant, incompetent, negative, or disruptive.^5^

Health care environments can foster hierarchical cultures where individuals of lower status self-censor for fear of retaliation or punishment.^242^ Environments like this discourage learning through rapid experimentation, failure, and reflection.^243^ Effective teamwork is critical in health care settings where clinical teams represent the basic organizational unit; however, a recent review found that a psychologically safe work environment was the most predictive factor of team and organization success and was the cornerstone of four other predictors of performance—clear goals, dependable coworkers, meaningful work, and a belief that work has impact.^240^

Senior implementation leaders can model safe communication standards to local implementation teams by setting clear ground rules on learning collaborative/community sessions. Implementation strategies, such as external facilitation^220^ or improvement coaching, also provide an opportunity to coach dysfunctional teams to cultivate positive communication patterns.

Increasing evidence indicates that when implementation strategies help local leaders (e.g., directors, managers, supervisors) adopt positive management behaviors, it translates into psychologically safe and high-functioning teams. This improves organizational outcomes through rapid learning and better clinical, safety, and employee outcomes.^5^ The ability to foster effective feedback channels could take weeks to years based on the commitment of senior leaders and managers to demonstrate consistency in communicating expectations for speaking up about errors, mistakes, or failures by positively affirming rather than punishing the messenger.

## Monitor Implementation Progress

### Report Progress to Stakeholders

For health care organizations to learn, innovate, and improve, frontline managers and clinicians need timely feedback about their current level of performance relative to goals and evidence-based benchmarks. Organizational learning that drives improvements at all levels of the health system is not only driven by data but also feedback loops among stakeholders that foster accountability and reflection on what is working or not working in implementing a new practice or innovation.^196^

In Pre-implementation, leaders and stakeholders develop a data collection and measurement plan that builds a continuous data monitoring and reporting system across all levels of the organization. Reporting systems must strive to balance performance feedback with engagement strategies to support positive clinician behavior change.^200^ Implementation progress should therefore include implementation progress at multiple levels, including system, regional network, facility, service, unit/team, and individual clinician (when appropriate).

Performance feedback should be meaningful and relevant to clinicians’ direct delivery of care, whether it be through a service, team, or individual clinician. Feedback should be presented in easily digestible formats that help clinicians understand what actions to take to modify their current care behaviors. Moreover, regular performance meetings with senior leaders, managers, and frontline clinicians should support reflection and problem-solving to use feedback data to drive local efforts for continuous improvement on key outcomes.^199^

Audit and feedback are essential implementation strategies used to support thoughtful engagement in performance feedback. Audit refers to the assessment of performance to a specific target or benchmark. Feedback is the communication of that performance. Frequently, data is provided without a comparison standard to interpret current performance (from within or outside the organization). Evaluators should monitor how frontline clinicians make sense of feedback data and respond to stakeholders’ concerns about the validity, reliability, and accuracy of reported measures.

Program evaluators can also develop communication channels to periodically share the results of formative evaluations with stakeholders across the system through practice-based networks, communities of practice, and virtual learning collaboratives. This process reinforces the participation of stakeholders in formative data collection and can be impactful by rapidly communicating failures and successes across the organization to support improved delivery (e.g., fidelity, adaptations) and/or use of specific implementation strategies.

### Make Data Accessible to Stakeholders

Operational stakeholders need continuous monitoring of implementation activities and outcomes (performance measures) to know whether they are achieving goals or evidence-based benchmarks. Performance feedback data that is hard to access and share makes it less timely and useful for implementation and quality improvement purposes. However, simply reporting performance data is not enough to ensure high quality, best practices, and effective care.^244^

Well-designed performance measures help managers and frontline clinicians assess and improve program outcomes and the processes linked to them. In Pre-implementation, stakeholders create a logic model to help stakeholders understand these relationships. In turn, a limited number of measures should have been selected that could be easily obtained at the local level on a regular frequency and shared for iterative improvement efforts.

Data that is accessible and transparent should be available at all levels of the organization, but particularly at the service, unit, and clinician levels. This data must be digestible and relevant to operational data users to make changes in local clinical implementation efforts. Data can be made accessible and usable by posting it on performance dashboards, posting visible summary reports in clinical breakrooms, or sharing and discussing it during recurring meetings between clinicians, managers, and senior leaders.

Accessible and continuously reported data enables local implementation teams to use data to experiment and refine implementation processes and then assess the impact of these changes in relatively short periods of time, which is essential for helping an effective practice fit in a local setting.

### Adjust Plan Based on Feedback

Learning health care systems and high-reliability organizations use data and measurements to drive improvement and innovation. Well-designed performance measures are insufficient to bring about changes without an improvement framework or process to make sense of this feedback.

“Until a new process or practice is completely routine, each use of it is an experiment”

– Organizational Learning Expert, Amy Edmondson ^5^

Senior leaders create the strategic vision for implementing a new practice in a health system by providing the resources and performance standards to hold local leaders accountable for carrying out an implementation plan. While implementation strategies provide the overarching strategy for implementing an effective practice and navigating barriers, implementation at the local level is often driven by small, incremental, and cyclically-implemented tests of change.

Effective performance measurement systems encourage organizational learning and improvement by using data to help managers and clinicians assess and improve program outcomes and the processes linked to them. Feedback from performance measures helps local implementation teams know how they are doing in achieving implementation goals or performance benchmarks. Failure to achieve performance goals encourages the use of improvement methods like Plan-Do-Study-Act cycles.^245,246^

Figure 17 Plan-Do-Study-Act Cycle for Iterative and Continuous Learning

As Figure 17 shows, a Plan-Do-Study-Act cycle is an iterative problem-solving approach that addresses gaps between current performance and benchmarked goals. Upon identification of a gap in performance, reflect on the possible causes of the failure and develop a solution (plan), test the solution (do), analyze the resulting outcomes (study), and act on whether to refine, stop, or continue the solution.

To improve and adopt new practices, organizations must be willing to support systematic experimentation at the local level. While failures are inherent to this process, these are small, deliberate failures that offer feedback to learn and adjust processes and behaviors.

Plan-Do-Study-Act cycles also offer a systematic way to help local improvement teams adjust to changes in clinical resource availability, clinical priorities, or the discovery of unintended consequences caused by a new practice. Finally, Plan-Do-Study-Act cycles offer a micro-approach to selecting, implementing, testing, and adjusting adaptations to an evidence-based intervention to assess what helps optimize fit with consumers and clinicians in a local context while maintaining clinical effectiveness.^9^