# Pre-Implementation

The QUERI Roadmap presents Pre-Implementation as a series of collaborative steps taken by operational and investigator partners that:

- Work with frontline stakeholders to identify an effective practice that addresses a priority area of care
- Engage stakeholders at all levels of the organization to actively contribute to planning the implementation of the practice and develop adaptations that improve fit between the practice and the contexts in which it will be delivered
- Diagnose local delivery capabilities and assess barriers to implementation across settings with the goal of developing implementation strategies to overcome these barriers
- Agree upon an evaluation plan and meaningful measures that enable stakeholders to know whether the implementation of the practice is achieving the desired improvements on key performance benchmarks

## Identify a Problem and a Solution

What’s in this section?

Key Concepts

### Identify a High-Priority Need and Related Goals

#### “What keeps you awake at night?”

Begin the Pre-implementation phase by identifying a health care problem for systematic improvement. Your search can use empirical data (e.g., financial, epidemiological, or health services data) and input from pragmatic data sources, including suggestions from health system leadership, clinicians, consumers, and other stakeholders, to find a clinical care issue that aligns with a local or national clinical priority need,^6,21–25^ such as:

This quality gap between current practices and available effective clinical practices constitutes the “problem,” which can be clearly defined by:

- Describing the problem or quality gap
- Specifying the clinical settings and consumer populations or the types of clinical stakeholders who are affected by the problem
- The desired improvements or benefits in outcomes over current performance
- Boundaries of the implementation effort (e.g., services involved, resources, timeline, etc.)^26,27^

Depending on the scope of the effort, hospital or health system leadership can form a planning team to oversee and have ownership of the partnered implementation process. A clinical leader typically oversees the implementation effort and addresses operational challenges. An embedded implementation scientist with relevant knowledge and a history of working with the clinical partner can co-lead the implementation and evaluation activities.

Implementation planners may then work to develop goals that set quantifiable objectives for improvement over recent baseline performance. When setting goals, research questions, and/or evaluation design for the project, engage stakeholders across relevant disciplines, roles, and responsibilities to confirm a shared understanding and obtain buy-in.

Improvement goals are informed by internal and external benchmarks of quality as well as input from stakeholders. Performance goals need to be clinically meaningful to frontline stakeholders, also aligning with local and national clinical care priorities and the organization’s mission and values.

### Agree on Effective Practices and Settings

High-impact implementation begins by finding the best available practice to solve the problem. An effective practice is a health-focused innovation, intervention, program, policy, or technology with consistent, credible evidence supporting its ability to have a meaningful impact on consumer health behaviors or outcomes while minimizing harms.

Using evidence-based practices enhances the effectiveness of the care provide to consumers and their families and saves time and resources by improving the quality, timeliness, or efficiency of current clinical workflows.

Begin the Pre-implementation phase by searching for empirically supported practices that address the problem by reviewing relevant scientific research, high-quality evidence syntheses based on standard systematic review and/or meta-analytic methods, and/or clinical practice recommendations from professional and government entities.

Note if the evidence underlying the practice has limitations. For example, was the evidence for a practice based on studies with settings, delivery methods, or populations similar to those of your own organization?^28^ If these factors differ, you may need to pilot the practice to “scale out” to these new contexts or consumer populations prior to full implementation to verify the practice is effective in your setting.^29,30^

In some cases, evidence for a solution may not yet exist in a systematic review or as the outcome of a randomized clinical trial. In this situation, consider expanding your search to identify examples of positive outliers within your organization and promising practices exhibited by similar high-performing organizations.^21,31–33^

Sometimes, the best solution for a particular problem is a promising practice, which we define as a technique, intervention, program, or methodology that, through experience and rigorous evaluation, has proven to reliably lead to a desired result.^34^

The VA has created a formal process called Diffusion of Excellence (https://www.va.gov/INNOVATIONECOSYSTEM/views/explore/diffusion-of-excellence.html), which actively identifies promising practices and innovations developed at the local level as well as evidence-based practices that have not been widely adopted.^35–38^ Each year, practices are submitted to a national competition, where investigators and health system leaders select the top practices with the greatest potential for health system impact. These practices in turn receive support for scale up and spread across VA.

The VA Evidence Synthesis Program offers timely and accurate syntheses of specific health care topics of importance to clinicians, managers, and policy makers as they work to improve the health and health care of Veterans.

Outside VA, look to resources like Cochrane (https://www.cochrane.org/), the U.S. Preventive Services Task Force (https://uspreventiveservicestaskforce.org/uspstf/), and the Agency for Healthcare Research Quality Evidence-based Practice Center Program (https://www.ahrq.gov/research/findings/evidence-based-reports/overview/index.html).

Going forward in this guide, we use the term “effective practice” to include both evidence-based practices and promising practices with potential for high impact on local-, regional-, or national-level quality improvement or implementation efforts.

Consider the following questions when deciding whether to implement a practice:^39^

- Are there concurrent improvement initiatives addressing the same problem?
- Do frontline stakeholders and managers perceive the evidence as strong enough to reliably yield the desired improvement in outcome?
- What is the feasibility of implementing the practice?
- Does the practice create a larger workload for frontline stakeholders without supplying more delivery capacity (i.e., time, personnel)?
- Is the practice simple and user-friendly in design and application? Does the practice fit in workflows?
- What is the burden on consumers, their families, and/or caregivers?

Finally, there is a growing recognition of the problem of low-value care services that merit “de-implementation.” In many cases, the goal may be to implement a new effective practice while acting to de-implement a low value care practice at the same time. “Low-value” care may be defined as health care services or treatments that provide little or no benefit to consumers, have the potential to cause harm, incur unnecessary costs to consumers, or waste limited resources.^40,41^ An estimated 25% to 34% of all health care costs in the United States reflect low-value care practices,^42,43^ and thus, reveal a large area for improvement.

De-implementation calls for a practice to be reduced, replaced, or stopped because it has been found ineffective, harmful, inefficient, or no longer necessary, even in the absence of a superior alternative practice.^44,45^ While the focus of strategies to de-implement low-value care services may be slightly different than those to implement a practice,^44,46,47^ the steps in the QUERI Roadmap are still be applicable to planning and executing a de-implementation initiative.

### Clarify Effective Practice Core Elements and Options for Delivery Adaptations

Upon selecting an effective practice, outline the core elements of the practice and develop a menu of options that gives implementing facilities flexibility to adapt practice delivery. This also optimizes planning for staffing, training, supervision, and program support needs.^48^

#### Core and Peripheral Elements

Core elements are the critical features of an effective practice that were tested in rigorous clinical trials and linked with improved outcomes.^48,49^

Core elements of an effective practice need to be delivered with fidelity to ensure the desired outcomes are achieved. Fidelity refers to the degree to which an effective practice is implemented without compromising the core components essential for the practice’s effectiveness.^50,51^

Core elements can include materials, measures, and protocols on how to deliver a practice, as well as the core logic and underlying theory supporting the practice as shown in Figure 3.^49,52^ The nature and scope of these components depend on the complexity of the effective practice.

Peripheral elements by comparison (e.g., “menu options”) refer to the modifiable aspects of an effective practice that do not affect its core components^49^ but optimize the fit between the practice and contextual influences affecting practice delivery, such as consumer, cultural, and setting characteristics.^53^

A logic model can enhance clarity. A logic model is a visual graphic that shows how your effective practice produces desired outcomes.^55–57^ Logic models describe the core logic or casual relationships between program core elements, the problem, and key measures of success (See Using a Logic Model as a Planning Tool and Identify Measures of Success and Data Sources).

Figure 3 Examples of Core and Peripheral Components to Effective Practices

(Adapted from^49,54^)

#### Balancing Fidelity and Adaptation

It is important to balance the tension between the need for practice fidelity with frontline stakeholders’ need to flexibly adapt practice delivery for the diverse contexts in which they are implementing.^58,59^

Maintaining fidelity involves consistently assessing the degree to which the core elements of the practice are implemented as intended and as prescribed in the original protocol.^8,50^ Fidelity can be measured by comparing current practice delivery with protocol in terms of:^60^

1. Adherence to the original protocol
2. Dose or the amount of the practice delivered
3. Quality of practice delivery, and
4. Consumer reaction and acceptance

Fidelity monitoring is essential because poor delivery of a practice results in less desirable outcomes. Moreover, without fidelity monitoring, it can be difficult to determine what aspect of the practice contributed to reduced outcomes. However, effective practices are not limited by fidelity to a one-size-fits-all approach.^61^ Practice adaptations are inevitable and necessary.

Adaptation is best defined as a process of the thoughtful and deliberate alteration of the design or delivery of a practice with an aim of improving its fit or effectiveness in a given context.^62,63^ While adaptability refers to the characteristics of a practice that lend themselves to modification, the QUERI Roadmap also views adaptation as an implementation strategy to optimize a practice over time—from Pre-implementation through Sustainment.^58,64^ Consider stakeholder input as you assess whether to adapt and improve an effective practice for specific settings or population characteristics in light of the capacity and available resources.

While any change to a practice is a modification, consider the following distinctions:^53^

- Planned/proactive modifications (adaptations) are made deliberately through a planning process prior to delivery to maximize fit and implementation success while minimizing disruption to the practice.
- Unplanned/reactive modifications occur over the course of practice implementation, either in an impromptu manner or in reaction to constraints or challenges, and may or may not need to be aligned with core elements to be effective.
- Fidelity-consistent modifications preserve or align with core elements that are needed for a practice to be effective.
- Fidelity-inconsistent modifications alter the practice in a way that does not preserve its core elements; this likely results in diminished practice effectiveness.

Modifications are ultimately judged on whether they positively or negatively affect outcomes:^62^

+ Modifications that increases the fit between an effective practice and end users (i.e., consumers, clinicians), which may lead to improved practice engagement, acceptability, and clinical outcomes, particularly among minority or underserved populations.
+ Modifications that improve outcomes by aligning the practice with end users’ needs.
− Modifications that remove core elements or do not align with a context’s needs; these modifications can result in reduced practice effectiveness.

As Figure 4 shows, fidelity and adaptation are complementary processes that can positively or negatively influence implementation success.^61^

Figure 4 Optimizing Implementation Effectiveness with Fidelity and Adaptive Fit to Context

Implementation effectiveness is optimized in the green quadrant when practices are delivered with high fidelity and when the implementation strategy positively adapts the practice to fit local contexts. Conversely, poor implementation is likely when there is a lack of fidelity and practice fit with the local delivery context. The yellow quadrants illustrate how implementation effectiveness can be quite variable if either fidelity or adaptivity are suboptimal.

#### Adapting Your Practice

You might be asking yourself, “How do I know whether an adaptation is needed or appropriate?” Use the tools in the roadmap’s RESOURCES section to help evaluate whether or not to make adaptations to an effective practice:

##### The Cancer Prevention and Control Research Network’s Adaptation Planning Tool ^65^

Helps you consider adaptations based on a simple stoplight system to evaluate their potential effects on core elements:

- Green Light modifications are fidelity consistent
- Yellow Light modifications should be made cautiously
- Red Light modifications may be fidelity inconsistent and should be avoided

##### The Iterative Decision-making Tool for Evaluation of Adaptations (IDEA) ^66^

Helps tailor the adaptation process to the situation by evaluating key decisions, including whether an adaptation is:

- Necessary
- Fidelity consistent with core elements
- Feasible based on implementation timeframe
- Able to be piloted before full implementation
- Influential on key implementation or clinical outcomes
- Valuable from the stakeholders’ perspective

The Iterative Decision-making for Evaluation of Adaptations (IDEA) framework emphasizes that adaptation is not straightforward. Rather, it is a dynamic process that benefits from planned, deliberative decision points to evaluate and potentially iteratively test the benefit of incorporating an adaptation within practical time and resource constraints. Several evaluation models and frameworks^67^ can help make planned, systematic, and theory-based adaptations to practices before trying to deliver a practice at scale. We illustrate one basic, five-step process to adapt a practice during any roadmap phase:^8^

Figure 5 A Systematic Approach to Adapt Your Clinical Intervention or Effective Practice

(Adapted from^65^)

#### Monitoring Adaptations for Organizational Learning

Monitoring the fidelity of a practice is important because it helps ensure the desired improvement in outcomes. Similarly, monitoring adaptation during implementation efforts is also critical to support organizational learning. Understanding the nature, origin, timing, and impact of modifications on outcomes can help develop practice-based knowledge to optimize practice fit to a specific context.^53,54,68–70^

To better study adaptations, implementation scientists developed methods to systematically evaluate and document adaptations.^53,68,71^ Figure 6 illustrates an abbreviated version of the updated FRAME (Framework for Reporting Adaptations and Modifications-Enhanced), which facilitates the classification of different types of modifications over time, including whether the modifications were planned/unplanned, fidelity consistent, and when they occurred.

Figure 6 Framework for Reporting Adaptations and Modifications-Enhanced

Adapted from^53^ Note: This is an abbreviated version of the FRAME and does not include all elements.

#### Using Adaptation Tools

In light of the increased interest in understanding how adaptations influence the uptake of clinical innovations, Rabin and colleagues^70^ suggest the following criteria when selecting ideal pragmatic methods to assess adaptation:

- Documents in real time over the lifetime of an implementation/quality improvement project
- Easily replicable
- Nonburdensome to users and beneficiaries
- Low complexity
- Low cost and requires modest resources
- Provides both quantitative and qualitative information on adaptation
- Assesses adaptations from the perspective of multiple stakeholders
- Uses multiple methods to gather data (e.g., interview, survey, observation, documents)
- Tracks adaptations to both the effective practices and implementation strategies used

In RESOURCES, we include helpful pragmatic tools for tracking adaptations, including a modified version of the FRAME checklist developed by Wiltsey-Stirman and colleagues^53,68^ to efficiently interview frontline clinicians about modifications and adaptations to assess the effects of planned and unplanned modifications on implementation effectiveness.

More information on tools to track adaptations based on the FRAME (e.g., FRAME Interview Coding Manual, monthly self-reported Adaptation Checklists) can be found on the F.A.S.T Lab website (http://med.stanford.edu/fastlab.html) (The Fidelity, Adaptation, Sustainability, and Training Lab at the National Department of Veterans Affairs Center for PTSD and Stanford University).

We also include a brief interview guide developed by the VA’s Triple Aim QUERI Program^70^ to help assess whether adaptations have been made to a practice over time; this guide and related methods are derived from the FRAME^68^ and RE-AIM evaluation frameworks.^72^ This interview guide is part of a multi-method assessment approach to evaluate adaptation over time and is linked to a case study illustrating the application of these methods in four diverse health systems.

### Culturally Tailored Adaptations for Consumer Impact

Health disparities are significant differences in health or health care between two or more groups due to social, economic, or environmental disadvantage and can be based on:^73,74^

Race/ethnicity | Religion | Military service era
Gender | Socioeconomic status | Functional limitation
Age | Sexual orientation | Geography (rural/urban)
Mental health | Sex identity | Cognition

In many health settings, effective practice implementations are rarely tailored to high-risk or vulnerable consumers with greater health needs who could most benefit from treatment.^73,75,76^ When there is poor fit between an effective practice and the individuals who use or consume the practice, clinical and quality outcomes are likely to suffer.^61^ Effective practices can and should be tailored to different cultures while still preserving core functions.

Cultural adaptation is the “systematic modification of an effective practice to consider the importance of language, culture, and context in such a way that the practice is compatible with the consumer’s cultural patterns, meanings, and values.”^77^

Effective practices can reduce health inequities if they are designed to address the barriers that are preventing individuals and communities from living their healthiest life. During the Pre-implementation phase, both senior- and local-level planners should look to local health system and/or public health epidemiologic reports to consider ways to address health disparities in the target population.^73^

Effective practices and messaging can be targeted to specific at-risk groups or tailored at the consumer level to increase the relevance and impact of the message to consumers. Like a piece of clothing with a good fit, a tailored practice is more likely to be acted on because of the way it has been personalized to an individual’s personal or cultural characteristics or needs.^78^

In local health service or clinic settings, a diverse group of stakeholders can be engaged to review effective practice materials and recommend ways to customize practices to local and vulnerable populations. This step can ensure the materials are relevant, acceptable, and personalized. Stakeholders may include:

- Consumers and their families
- Frontline stakeholders working with an at-risk population
- Health education committees
- Patient advocacy groups
- Hospital health communications specialists
- Investigators with diverse backgrounds

In large health systems, central clinical program offices or resource centers may be available to consult with and provide you with resources and tools to adapt practices to your consumers and setting. For VA, an exemplary resource is the VA Office for Health Equity (OHE; https://www.va.gov/healthequity/)

## Engage Stakeholders

### Cultivate Leadership and Stakeholder Support

Gaining the support of local leaders and frontline stakeholders to implement a new practice is a key task during the Pre-implementation phase.^48,79^ Senior implementation leaders are essential to creating a compelling vision and empowering frontline stakeholders to adapt the practice to fit their local settings and populations.

WHO ARE MY STAKEHOLDERS?

Getting the right people involved in an implementation initiative is a critical first step. Stakeholders make up the broad spectrum of potential partners who may have a direct or indirect role in supporting the design, delivery, or receipt of the practice.

Internal stakeholders are those in a health system—most notably, consumers/Veterans and their families or caregivers—though they might also include those who coordinate, fund, or support implementation efforts, including:^8^

HEALTH SYSTEM LEADERSHIP | CARE DELIVERY | TECHNICAL AND SUPPORT ROLES
National program leaders | General clinicians | Research experts
System or facility leaders | Specialty clinicians | Information technology
Mid-level clinical managers | Medical assistants | Bioengineering
Service or department chiefs | Lab personnel | Systems redesign engineers
Frontline supervisors | Peer specialists^*^ | Technicians

External stakeholders work outside the health system and can offer unique views and experiences. These stakeholders may include:

Non-profit organizations | Clinicians/practices from outside your health system | Patient advocates
Insurance companies and other types of payers | Policymakers/local leaders | Local, state, or community organizations

* Also known as community health workers

Successful implementation requires organizations to design for sustainment from the start of Pre-implementation phase through the end of the Implementation phase. Designing an implementation process for sustainability is about empowering local stakeholders to be actively involved in all aspects of planning, delivering, measuring, and refining a practice so they feel ownership of the practice and understand the value of the practice. Conversely, top-down policy directives or mandates give frontline staff little ownership in a practice. Implementation efforts that engage frontline stakeholders are more successful in adapting the practice to their context and identifying resources and the means to sustain a practice once initial funding is expended.

#### Empowering the Frontline to Innovate

The communication and management strategies that system and local hospital leaders use to mobilize support of frontline stakeholders can greatly enhance or hinder an implementation effort.^80,81^ At a basic level, leaders must interact with frontline employees and managers to clearly communicate how a new practice supports local priorities and clinical needs and to understand stakeholders’ perspectives.

To go beyond superficial “buy-in” for a new practice, stakeholders need to understand the strength of the evidence for the practice and how it serves as an improvement over current care with respect to quality, outcomes, and/or costs.

Senior leaders can garner sustained stakeholder commitment by making the effort personally and professionally relevant to frontline staff and clinicians; this requires actively involving stakeholders in the implementation process so they have an ownership stake in the outcomes.^48,82^ Leaders and managers can achieve this by:^5,39,79,83-85^

1. Conveying a clear and compelling purpose
2. Aligning the value of an effective practice with stakeholders’ interests and values of:
  - Improving work flow
  - Delivering better care to consumers
  - Addressing important local care needs or “pain points”
3. Seeking frontline stakeholders’ feedback early and often to give them an ownership stake in the implementation process
4. Giving stakeholders control over how the practice is adapted to improve fit with local contexts^86,87^

Senior leadership support is essential for implementing and sustaining practices. Evidence suggests that health care organizations with a distributed leadership structure build greater capacity for adopting effective practices than relying simply on top-down appoaches.^88^

Spreading responsibility across levels of the organization—from service chiefs to middle managers and frontline supervisors—maximizes the complementary skills, viewpoints, and resources needed for the implementation. Distributed leadership reduces organizational frag mentation between leaders at the “top” of the health system and those employees at the “bottom” who are charged with carrying out changes to frontline care.

“If you want to go quickly, go alone. If you want to go far, go together.”

– African proverb

Leadership support at implementing facilities is essential for translating the aims of an implementation effort into action^88^ by committing people, protected time, space, and other resources. While senior hospital leaders’ support and attention for an effort is vital,^89^ hospital leaders often face competing demands for their time and attention.^90^ For sustained focus on the implementation, these leaders must engage frontline and mid-level leaders to take ownership of local implementation efforts.

Mid-level managers and frontline supervisors are critical for managing operational oversight of implementation efforts and coordinating with frontline stakeholders and staff who actively work to implement the changes. Mid-level managers are the communication bridge between top-level leaders and frontline innovators trying to make a new practice fit in a local setting. Frontline stakeholders and their clinical teams also look to middle managers to set expectations, clarify roles and responsibilities, support conflict resolution, provide coverage strategies to engage in improvement activities, monitor and reflect on performance outcomes, and enable frontline-team-initiated innovations.^91,92^

#### Navigating Concerns About Change

New clinical innovations and improvement efforts can be met with skepticism by frontline stakeholders because these changes are often viewed as complex, costly, challenging, and time-consuming. Make it an ongoing priority to address these concerns with staff.

The following table highlights some common challenges facing hard-to-engage sites, including sources of concern held by key stakeholders as identified by a Department of Veterans Affairs Evidence Synthesis Program report:

Table 1 Characteristics of Hard-to-Engage Sites in Implementation Initiatives

Common Challenge | Valid Factors Underlying Implementation Challenges
Limited bandwidth or resource availability | - Understaffing of key personnel; - Time constraints; - Lack of administrative support; - Frontline staff burnout; - Departure of team members; - Lack of funding; - Implementation as an unfunded collateral duty
Local solutions to the same problem | - Presence of a local innovation/solution; - Lower priority for adoption of a different practice; - Disruption of existing workflows to switch practices
Competing priorities with other Initiatives | - Local priorities may not align with implementation initiative; - Higher-priority local initiatives may cause resource shortages; - Leadership attention preoccupied with other initiatives
Interdisciplinary coordination | - Stakeholders siloed by specialty or geographic distance; - Different priorities, values, or culture among clinical teams, services, or facilities within a system

Adapted from^93^

New practices that increase frontline stakeholders’ workloads without additional resources (e.g. protected time, personnel) may face resistance because these changes place a greater burden on clinicians without increasing job control or their ability to deliver better care.^39^ These forms of work stress can decrease the psychological well-being of clinicians and lead to apathy, burnout, disengagement and turnover, and often poor health outcomes including depression and suicide, which undermines the delivery of high-quality care.

Similarly, top-down mandates or policy directives can meet resistance from frontline managers and stakeholders who have no voice in the process and, therefore, have little stake in whether the practice succeeds or fails. Make sure to frame an implementation effort so it aligns with local stakeholder needs, values, and priorities, and stay alert for any indications of stakeholder discomfort or disengagement with the implementation process.

Initial resistance to an implementation initiative can be a helpful form of feedback. Take this feedback as a sign that a site or local stakeholders need to understand and weigh the added value of the new practice.^93^ This form of engagement often reflects a pragmatic approach to manage scarce resources prudently before committing to adoption. This cautious approach is different from situations where sites disengage from the implementation conversation, which suggests a more urgent need to better understand local site perspectives and concerns.

Among hard-to-engage facilities or services, a site’s delay in adoption can be framed as a strength. This “long-view” strategy can be more effective in some cases, where rushing to adopt a new practice can lead to shallow levels of practice implementation and failure to sustain outcomes over time.

For sites with a late implementation start, there is an advantage of being able to draw upon the support and experience of earlier adopting sites to develop a plan that readies local stakeholders for successful implementation.^94,95^ While some late adopters may want to hide their local difficulties from their peers, others may see it as an opportunity to address local priorities and need for support.

Stakeholder input can improve implementation by

- Streamlining or tailoring a practice to ensure its relevance and acceptability among consumers and stakeholders
- Identifying potential barriers to practice uptake
- Recommending strategies to address health disparities
- Developing permanent solutions rather than temporary “workarounds”
- Identifying meaningful outcome measures

We believe deeper and engaged stakeholder participation occurs when stakeholders have an equal voice and actively collaborate with implementation scientists and operational planners throughout all phases of the roadmap.^96,97^

Engage these stakeholders early and often through mechanisms such as steering or advisory committees, interviews, focus groups, user testing, and observations of work routines. It is particularly important to engage relevant stakeholders at key decision-points.

#### Building and Maintaining Effective Partnerships

Early and regular communication is essential to building productive and resilient long-term partnerships. Open lines of communication build relationships and ensure mutual respect, trust, and credibility from the outset of the partnership.^11,98^

Investigators can actively seek to understand the priorities of their operations partners and work closely with them to establish aims, questions, evaluation designs, and measures that remain relevant and meaningful over time.^99^ Operational partners value flexibility, responsiveness, and interim data and products. Investigators work to maintain the rigor and integrity of the scientific process even if it takes more time (e.g., complex evaluation designs, carefully written results for publication).^99^

Engagement requires managing the balance between methodological rigor and the need for timely solutions to clinical problems.^100^

Establishing regular, candid, and psychologically safe communications between partners promotes a shared agenda and increases the probability that implementation efforts will be effective.^98,101^ Strong partnerships rely on setting joint expectations about project timelines, roles, responsibilities, shared resources, deliverables, and preferences for ongoing communication.^99^

Using a memorandum of understanding helps to formalize the partnership and promote shared understanding of key details and goals. Prioritizing face-to-face meetings between partners is essential to jointly review progress, define expectations, and refine aspects of the partnership and explore potential future collaborations.

Investigators play a key role in fostering institutional learning by sharing important information from partnered evaluation and implementation efforts with policy leaders, managers, and frontline stakeholders throughout the system.

Contact the VA Center for Evaluation & Implementation Resources (https://www.queri.research.va.gov/ceir/) for more information on the QUERI Partnered Evaluation Toolkit for building effective partnerships for quality improvement and implementation science.

### Assess Capacity Including Barriers and Facilitators to Practice Delivery

Developing an implementation plan begins with a diagnostic assessment^9,23,84,102-105^ of an organization’s readiness to implement a practice and the potential barriers to practice delivery.

Capacity assessment is an action-oriented process used to understand multilevel contextual factors that may influence implementation efforts. The goal of this step is to design an implementation plan that uses theory-based strategies to change and organizational behaviors to support not only practice adoption and implementation but also enable sustainment.

Organizational readiness refers to an organization’s willingness and ability to adopt and implement an effective practice and is comprised of three components:^106,107^

- Motivation – Incentives or disincentives that make an effective practice more or less desirable, a priority to adopt by local clinicians, a relative advantage over other practices, and a practice’s perceived complexity, compatibility, trialability, and outcomes that are clearly observable by clinical users.^108^
- General capacity – Attributes of an organization and its connections with other organizations and/or communities that affect its ability to implement a new practice, such as the organization’s culture, climate, innovativeness, resource use, leadership, staffing capacity, and operation structures.
- Innovation-specific capacity – Innovation-specific human, technical, and fiscal conditions necessary to support the successful implementation of an effective practice, including the knowledge, skills, and abilities needed for practice delivery; clinical program champions; implementation climate, notably support from managers; and supportive relationships inside and outside the organization.

Traditionally, implementation initiatives have favored a top-down model of implementation that “pushes” a new practice into use with capacity-building strategies that are specific to that single innovation.^109^ However, learning health system leaders prefer implementation strategies that build local capacity for implementation, in which the process for prioritizing areas for improvement and selecting an evidence-based solution is started by—or “pulled” by—frontline stake-holders over time.^103,107^

Organizational readiness varies considerably within large health systems serving diverse communities and settings. General and practice-specific capabilities are often constrained by the quality of available resources, including technology, evaluation infrastructure, materials, time, and money.^110^ Implementing new effective practices requires changing existing and organizational behaviors within these constraints to improve processes.

In the figure below, we present a systematic series of steps that can help guide from problem to solution to implementation during the Pre-implementation phase.^111^ Note the effective methods that can guide you through similar steps, including implementation/intervention mapping^25,84,105^ and many of the implementation science process frameworks.^15,24,48,110,112,113^

Figure 7 A Systematic Approach to Designing an Implementation Plan

Adapted from^102,111,114^

#### A Systematic Approach to Designing an Implementation Plan

##### STEP 1 Assess gaps using current knowledge

Pre-implementation begins with operational and research partners using organizational quantitative and qualitative data to identify gaps in quality of care or service delivery and, agreeing on a clinical problem area for improvement.

##### STEP 2 Use available knowledge to identify an effective practice solution to address the gap

Following agreement on a clinical problem area for improvement, conduct a literature review, or evidence synthesis, to find an effective practice that provides a solution to the clinical area for improvement. The practice should be feasible and provide a substantive benefit to resolve the gap in care. Consider if any existing, low-value practices require de-implementation to make room in workflows and/or avoid conflicts with the new practice.

##### STEP 3 Map out and analyze behaviors, steps, processes, and/or decision points that make up the effective practice

Engage frontline stakeholders at several representative sites involved in the implementation effort to understand variation in the work flows necessary to deliver the practice with quality using one or more of the following methods:

- Process Mapping – Used to understand how clinical processes contribute to outcomes in a new practice by creating a flow diagram that depicts steps of a clinical process, staff roles, and specifications of inputs and outputs to identify modifiable areas for improvement.^115,116^
- Practice Mapping – Helps makes a practice visible to clinical stakeholders who can^71^ map out the series of sequential behavioral steps and decisions in a current practice to identify ways to make clinical processes more efficient, reduce errors, or improve outcomes.^117^
- Root Cause Analysis – Maps out the causes of service failures and safety problems using a systems analysis approach in which interdisciplinary teams ask three questions: “What happened?” “Why did it happen?” and “How do we prevent it from happening again?”^118^

Consider how mapping practices, programs, guidelines, behaviors, and decision points benefits implementation efforts. Effective practices consist of a bundle of behaviors and decisions. In health care, these practices are organized in different ways:^111^

- Practices are focused on building smaller blocks of care delivery, such as prescribing a medication, dressing a wound, or assessing a consumer.
- Programs bundle practices together into more complete “packages” and may or may not be fully evidence-based in their bundled form (e.g., care coordination or infection-control bundles).
- Clinical practice guidelines summarize many different recommendations for a specific clinical area and are often not operationalized as practices.

Effective practices typically involve many people with different roles and supporting tools (e.g., specific templates in the electronic medical record). Clinicians and consumers are often faced with decision points. Understanding when, where, and how these behaviors and decisions break down and affect outcomes is crucial to developing solutions that address errors and negative variation.

Assessing all the behaviors that go into an effective practice is challenging and local implementation teams can use strategies, like process mapping. A visual map allows planners to understand where to focus implementation activities to make the behavior changes necessary to implement a new practice with fidelity while reinforcing replicable standards of practice that sustain the change.

##### STEP 4 Assess barriers and/or facilitators related to implementing the effective practice

By mapping out the behaviors, decisions, roles, and processes that comprise an effective practice, you can begin to see factors affecting the delivery of a practice. Other ways to identify these contextual influences on the implementation process include:^25,84^

- Brainstorming with local stakeholders and program planners to generate potential influences based on participants’ clinical experience from similar practices
- Reviewing the scientific literature for barriers and facilitators identified by investigators implementing similar effective practices
- Observing the physical settings to identify issues
- Interviewing stakeholders using theory-based interview guides
- Conducting brief surveys of stakeholders (usually after some interviews)

There are many implementation science frameworks^7,119^ that help identify barriers and facilitation factors. See RESOURCES for a brief overview. The framework selected may have to do with the type of effective practice or the implementation setting.

For more information on choosing dissemination or implementation science theory and models to guide your planning, visit: Dissemination & Implementation Models in Research & Practice (http://www.dissemination-implementation.org/).

##### STEP 5 Use theory to link barriers to evidence-based change techniques

Once you identify relevant barriers (and facilitators), work to organize them according to type and influence using a concept or intervention mapping process or quality improvement tools, like driver diagrams or fishbone diagrams.^64,120^ Using visual methods, you can map barriers to specific behaviors, decision points, and roles/responsibilities that need to change to adopt the practice and achieve the desired outcomes.

Most clinical behaviors are carried out by individual clinicians and staff. Consequently, many implementation strategies incorporate theory-based techniques that help change what people think and how they decide to carry out clinical care duties.

To enact change, consider the context in which individual clinicians work. For example, the Pre-implementation capacity assessment should identify organizational factors that influence how people think and behave, including social norms, organizational culture, job status (hierarchy), leadership characteristics, and performance plans and incentives.

When supporting improvement in a given context, use local strengths or enabling factors for behavior change. For example, consider the resources available to support delivery (e.g., dedicated time, personnel, past experience, supportive leadership) and the degree to which different disciplines communicate and coordinate their health care delivery across a hospital or system.

Then, link barriers with modifiable factors and theoretical mechanisms of behavior change that can be tailored for intervention.^103^ Theory-based behavioral change techniques help specify the:

- Barriers that are altered by a behavior change
- Causal mechanism(s) of change
- Level of change (e.g., individual, service, organizational) to enhance implementation
- Technique or strategy and the details of who, when, and what outcomes are affected by the intervention^23,71^

Table 2 illustrates one method of developing components of a comprehensive implementation intervention for multilevel barriers. In this case example, clinical leaders at VA needed to develop a plan to ensure naloxone, an effective medication for reversing the effects of opiate overdoses, is widely available to clinicians, consumers, and their caregivers. A systematic approach to distributing naloxone was crucial to address a national epidemic of accidental overdose deaths that affected Veterans at even higher rates than the civilian population.

Often, you may use more than one approach to overcome a barrier, and similarly, more than one theory may guide the identification of an implementation strategy to improve implementation outcomes.^105^

- Link barriers at the clinician- or clinical-team-level to catalogs of behavior change techniques grounded in psychological or social theories and designed to cause changes in important thoughts and behaviors of individual clinicians, managers, or clinical treatment teams.^104,121–125^
- Link organizational and higher-level barriers to catalogs of implementation strategies (See ERIC in the General Resources section) to cause broader changes among groups of stakeholders ranging from practice-level to system-level changes, such as policy or financing.^103,126–128^ Frequently, implementation strategies involve more than one strategy whereby discrete strategies are mapped to the causal mechanism of change.

The Department of Veterans Affairs Opioid Overdose Education and Naloxone Distribution (OEND) initiative was the first national quality improvement effort in the United States to develop a standardized approach for providing education and training on naloxone use for various health systems and to at-risk consumers and their family members.^129^ Implementation planners rapidly assessed potential barriers to delivering OEND across multiple levels of the health system and identified modifiable mechanisms of change to reduce these barriers.

Table 2 A Theory-based Approach to Mapping Barriers to Implementation Strategies: The Department of Veterans Affairs OEND Initiative

Barrier Level | Barrier | Mechanism of Change^25,124^ | Implementation Strategy/Technique^121,126^
Veteran | Risk awareness | Perceived vulnerability | Risk communication, use mass media
Veteran | Ability to use naloxone in overdose | Caregiver knowledge, self-efficacy, skills | Develop and distribute educational materials, obtain family feedback, activate Veterans and family
Veteran | Cost | | Alter office fees, make billing easier (naloxone provided free of charge)
Clinician/clinical team | Ability to identify high-risk Veterans | Knowledge, clinical decision-making | Develop clinical analytics to identify at-risk Veterans
Clinician/clinical team | Lack of expertise in naloxone prescribing | Knowledge, skills, goals, self-efficacy, subjective norms | Offer educational trainings, train-the-trainer
Clinician/clinical team | Prescribing naloxone | Behavioral cueing, environment resources | Change electronic medical record templates
Clinician/clinical team | Awareness of progress | Feedback processes, subjective norms | Audit and feedback, relay data to clinicians
Hospital/practice | Competing priorities | Professional role change, reinforcement | Mandate change, policy directives(s) for all facilities, identify and prepare champions
Hospital/practice | Implementation variability | Knowledge, subjective norms | Values, standardize tools, guidance, resources implementation plans
Hospital/practice | Cost to facilities | Reinforcement | Policy change, change cost to hospital (no cost)
Health system | Low availability of naloxone | Environmental context, social roles | Use advisory boards and national workgroups
Health system | Unstandardized naloxone kit | Environment resource | Place naloxone kits on national formulary
Health system | Lack of best practice | Knowledge, skills, decision processes, social learning | Create learning collaborative, centralized technical assistance and facilitation
Health system | Coordination across service disciplines | Professional role, norms, motivation | Change availability of services and mix of clinicians offering treatment
Health system | Union support | Professional role, social influences, norms | Obtain formal commitments

##### STEP 6 Design an implementation strategy to overcome barriers

Implementation strategies are specific tools or methods used to support the uptake of the effective practice (See Select Implementation Strategies for more information).

De-implementation of low value services may be necessary to ensure successful use of the effective practice. Low-value care is defined as health care services or treatments that provide little or no benefit to Veterans or have the potential to cause harm, incur unnecessary costs, or waste limited health care resources.^40,41^ De-implementation calls for a practice to be reduced, replaced, or stopped because it is ineffective, harmful, inefficient, or no longer necessary, even in the absence of a superior alternative practice.^44,45,47^

##### STEP 7 Develop a logic model to align activities and monitor outcomes

A logic model is a useful way to visually summarize the alignment of theory, behavioral change techniques, processes measures, and outcomes. In the next section of Pre-implementation, “Develop Measures and Data,” we describe how to create a logic model to help stakeholders under stand key activities and measures.

#### Using a Logic Model as a Planning Tool

Logic models are tools that visually display how implementation activities produce desired outcomes. It illustrates the core logic or casual relationships between core elements, the problem, and key measures of success given certain assumptions about how the practice works within certain contexts.

Logic models answer the following questions:^57^

- What problem is the effective practice trying to solve and what outcomes represent success?
- What activities and supports are necessary to achieve these outcomes?
- What inputs and resources are needed to deliver these activities and supports?

The resulting model helps clarify the implementation process by supplying a roadmap that shows elements and activities that lead to the desired outcomes. This helps communicate elements of the clinical practice and the implementation process to different stakeholders and promotes buy-in. Specifically, a model helps:^130^

- Refine your practice’s mission, values, goals, and objectives with stakeholders
- Foster agreement regarding the most important desired outcomes
- Identify the most effective path to pursue given organizational and resource constraints (see Core Elements)
- Identify existing or additional (or weak and strong) components of the practice and ways to enhance performance (Menu of Adaptations)

The benefit of building a logic model comes from the process of discussing, analyzing, and justifying key relationships and linkages between activities and outcomes among frontline staff, evaluators, and health system leaders. Greater stakeholder buy-in can foster resource commitments for long-term sustainment and help identify potential barriers so frontline stakeholders can address them during Pre-implementation or early Implementation.

A basic logic model usually has two sides comprised of process and outcome elements. The process side includes the effective practice’s inputs (e.g., resources), activities, and outputs (i.e., direct products). The outcome side shows the intended effects of the practice, which can be short-term, intermediate, and/or long-term. Assumptions and relevant details about contextual factors influencing adoption may also be included in a logic model. Often these are noted in a box below or to the left of the model as show in Figure 8.

Figure 8 Layout of a general logic model

Source.^130^

This next figure shows a more detailed logic model to help define common model components.^130^

Figure 9 Basic Logic Model

adapted from^56,131,132^

- Purpose or mission is the clinical problem or need that motivates an implementation or quality improvement effort.
- Theory/Context describes the climate or context in which a change takes place, including the health condition, needs, and history of a specific problem. You may describe the political, policy, or economic climate for supporting a change, including the justification for using an effective practice to solve a problem. What is the theory behind the elements of the effective practice?
- Inputs include the resources, infrastructure, or supports necessary to implement the effective practice (e.g., time, equipment, materials, money, volunteers, training, and technical assistance)—what is invested. Inputs can also include constraints on the practice implementation.
- Activities are specific steps taken to produce desired outcomes—what you do. You can clarify whether activities occur early versus later and whether activities deliver the practice versus implementation strategies to enable effective practice uptake.
- Outputs are direct, tangible measures or results of activities—what you get. These early outputs often serve as documentation of progress and describe what the effective practice does and who it reaches (e.g., number of people reached and treated or the frequency, type, duration, and intensity of the practice delivered [dose]).
- Outcomes are the desired results of the effective practice—what you hope to achieve. These outcomes are described as short, medium, or long-term depending on the objective, length of the practice, and expectations for the practice.
  - Short-term outcomes are the immediate effects of the practice. They may include outcomes that reflect the quality of implementation processes or changes in knowledge, attitudes, or beliefs of the intended audience (e.g., clinicians, administrators, consumers).
  - Intermediate- or medium-term outcomes are behavior, normative, or policy changes in a target setting.
  - Long-term outcomes are the desired changes in clinical indicators, and/or health outcomes.
  - Impacts refer to the ultimate impacts of the practice on system or population outcomes (e.g., mortality, health disparities).
- Assumptions are the beliefs about a practice and the resources required. Assumptions include the way we think the practice will work based on research, best practices, experience, or common sense. The decisions made about implementing a practice are often based on these assumptions. Assumptions may cover funding stability over the course of implementation; training and education results in high-fidelity delivery; clinician motivation to attend trainings; staff hiring or re-allocation; or a policy directive leading to individual clinician behavior change.
- Contextual Factors describe the multilevel influences from both inside an organization and the broader social environment that interact and influence the practice. These factors may influence implementation, participation, and the achievement of outcomes and may or may not be modifiable. Implementation strategies and evaluation methods can help clinicians respond and adjust for these factors.

### Package Effective Practices with Delivery Adaptations

Modifying effective practices makes them more user-friendly and acceptable for real-world use after clinical trial validation.^133,134^ Packaging requires developing, pilot testing, and finalizing a user-friendly practice that enables facilities to efficiently adopt and implement the practice. Furthermore, this package prepares local implementation teams to rapidly scale-up and spread the effective practice across diverse settings with impact and fidelity.

The effort and resources to package an effective practice depend on the complexity of the practice and the extent to which there is an existing manualized set of empirically tested materials to support dissemination and implementation of the practice.

A user-centered design approach^135,136^ to package development involves garnering input from end-users—notably, frontline clinicians—in the use of the effective practice, often through development, validation, and rapid-cycle testing of the practice’s components in a real-world setting. User-centered design emphasizes simplicity, ease of use, aesthetics, and fit with the problem. The central implementation team drafts the package. End users vet the package and provide feedback in an iterative fashion to ensure the format and content are user-friendly.

In health systems like VA, these practice packages are often disseminated as toolkits and posted on electronic websites for easy access. Tool-kits may include an overview of setup procedures, underlying theories and logic, scripts, consumer materials, standard operating procedures, job descriptions, standardized medical record templates, marketing materials, and instructions for implementation across different settings.

An implementation package typically provides descriptions and procedures for fundamental capacity-building strategies for local frontline stakeholders:

1. Tools to plan, implement, or evaluate the effective practice
2. Training content for educational or skill-building sessions
3. Technical assistance that supplies interactive and individualized support to the specific needs of teams
4. Assessment and feedback that describes the systems of monitoring and offering feedback to managers and frontline stakeholders^83^

#### Continuous Engagement and Input from Frontline Stakeholders

Effective practice package designers can consult regularly with end-users to review and offer feedback on tools and resources and test the effective practice package, staff training and technical assistance plans, and the organization of the implementation plan. When holding these meetings, stakeholders can offer recommendations on the content to customize the effective practice across settings.

Packaging designers (i.e., investigators and operational staff) can use virtual sessions to test the feasibility of specific tools or resources by using rapid-cycle testing, comparing a standard versus adapted version of materials (A/B testing), and conducting cognitive end-user walkthroughs to improve the usability of the package over time.^135^

Once the package has been iteratively developed, it can be pilot tested for usability and functionality at a small number of facilities before implementation. Packaging designers can invite diverse facilities to elicit feedback on their needs and priorities, including from potentially negative end-user feedback.^36,52,64,136^ Facilities need adequate time to pilot the package and provide information on feasibility, acceptance, appropriateness, usability and any other contextual problems with the overall package, so that it can be refined based on their input.

#### Creating a Menu of Adaptations

Evaluators can work with frontline stakeholders who will deliver the practice^58^ to develop a menu of adaptations before fully implementing. Ideally, these adaptations are identified proactively during Pre-implementation rather than reactively during Implementation.^53,66,68^

Piloting these adaptations^52,134,136^ with those who will eventually use or deliver the practice—like clinicians and consumers—can help ensure fidelity to the original core elements and sustainment of the practice over time.^54,59,68^

Systematical assessment of these adaptations over time helps determine which adaptations support or improve implementation effectiveness (“positive deviance”) and which adaptations result in reduced outcomes (“negative deviance”).^54^ Investigators can use this process to better understand how, when, and where these adaptations can be replicated to improve the uptake of similar effective practices.

VA investigators created a simple tracking system to help record these practice adaptations with a focus on: 1) by whom the modification is made; 2) what is modified; 3) the level of the delivery; 4) the context of the modification; and 5) the nature of the modification.^68,70^ Two approaches for systematically tracking modifications and adaptations are described in the General Resources for Implementation and Quality Improvement section of this guide.

### User-Centered Design to Enhance Practice Adaptations

Many effective practices are based upon complex treatment protocols developed for highly resourced clinical trials that may need adaptation or redesign to simplify their use for real-world conditions and diverse consumers. User-centered design is a participatory approach that aims to ground the characteristics of an effective practice with information obtained from the individuals who use that practice (e.g., consumers, clinicians) with a goal of maximizing “usability in context.”^135^

Usability is the extent to which an effective practice can be used by stakeholders to achieve specific goals in a particular context.^133^ In the early design process, implementers seek to understand the needs, desires, preferences, values, experiences and recommendations of people who will use the effective practice.^135^

This type of iterative pilot testing starts in the Pre-implementation phase and may continue through early implementation. Testing adaptations and monitoring fidelity to core elements is crucial to ensure that clinical effectiveness of a practice is maintained. Similarly, keep track of adaptations made to the original practice, measure their effect on usability using a standardized measure, and monitor changes in clinical outcomes associated with significant adaptations.^136^

In participatory intervention research, collaborating with stakeholders to ensure the user-friendliness, acceptability, and feasibility of a clinical intervention is a fundamental step to preparing a program for implementation. User-centered design offers a rigorous and systematic approach to improve practice delivery and impact. Lyon and Koerner^136^ observed that there is a need to evaluate the application of these principles and understand how the results improve key outcomes at the levels of:

- Consumer (acceptability, improved functioning)
- Clinician (adoption, acceptability)
- System (appropriateness, efficiency, program reach/penetration)

Qualities of a well-designed and usable effective practice:^136^

- Fit – Fits the particular context
- Simple – Is straightforward and easy to use
- Learnable – Enables rapid understanding on how to use and apply the practice
- Efficient – Minimizes the time, effort, and cost of using the practice
- Memorable – Facilitates remembering and applying key elements without supports
- Error reducing – Prevents or allows recovery from misapplication of practice
- Acceptable/satisfying – Ensures the practice is valuable or acceptable especially compared to other practices

## Develop Measures and Data

### Design Evaluation to Match Goals

Program evaluation is the systematic collection of information about the activities, characteristics, and outcomes of effective practices. This allows implementers to make judgements about the practice, improve practice effectiveness, and/or inform decisions about future practice development.^139^

Evaluation encourages the examination of the operational delivery of an effective practice, including which activities take place, who conducts the activities, and who is reached as a result.

Evaluation also substantiates how closely the effective practice adheres to implementation protocols, and when adaptations were made to a practice that improved or reduced effectiveness. Through program evaluation, you can determine whether the practice’s activities and implementation strategies were implemented as planned. Evaluation also identifies strengths and weaknesses in implementation delivery for improvement.^139^

Evaluating the implementation of effective practices and quality improvement innovations is complex due to the nature of such work, which involves iterative, adaptive, and context-specific changes.^140^ The design of an evaluation should reflect this complexity and strive to use clearly defined and prioritized measurement plans to understand the practice’s impact on key outcomes and variation across sites.

Accordingly, leaders are encouraged to adopt best planning practices^141,142^ early in Pre-implementation to understand their effective practice and develop the most acceptable, feasible, and cost-effective evaluation design in light of limits set by resources, time, and political context.

An example is an evaluability assessment, which is an evaluation strategy that is useful with relatively new effective practices that have not been implemented at scale or undergone testing’. Evaluability assessments are consistent with the QUERI Roadmap and closely align with recommended planning steps in Pre-implementation:

1. Involve the intended users of the information in planning to obtain commitment to the implementation and define the scope and purpose of initiative
2. Clarify the intended practice by engaging stakeholders as part of the process of defining goals and expectations, describing core elements, and seeking feedback about practice usability, relevant contextual factors, available resources, capacity to make change, and possible strategies
3. Create or revise a logic model to clarify program activities and expectations among stakeholders and pilot the practice to identify data/measurement issues for conducting a full evaluation
4. Agree on necessary changes in activities or goals to improve fit (menu of adaptations)
5. Explore evaluation design options to answer high-priority questions and then select a design that realistically considers resource, time, and political constraints
6. Agree on evaluation priorities (key outcomes) and intended uses of information (e.g., quality improvement, budgeting/planning, performance measurement) to support system learning

#### Why Should Evaluation Matter to Frontline Stakeholders?

New laws and policies require many public health agencies and private health organizations to use rigorous evaluation methods—preferably randomization—to examine the implementation of new practices or policies.^143,144^ Clinical services may be asked to tie evidence into budget requests through a learning health system approach that provides evidence for practices and policies.^145.^ This increases the system’s capacity to use evidence, evaluation, and data as tools to improve outcomes.

The aim of rigorous, systematic evaluations of effective practices is to help policymakers decide how to best invest resources to avoid waste or expense on ineffective programs and/or implementation methods.^146^ Strong program evaluations use mixed methods involving both quantitative and qualitative data collection methods because quantitative results are often insufficient to explain why a practice was implemented well—or not. Qualitative data collected from staff meeting minutes, interviews with stakeholders, and focus groups with consumers help provide data that explains why results occurred.

Ultimately, program evaluation is a tool used to demonstrate accountability to health system stakeholders, who may include consumers, stakeholders, funding sources, policy makers, and/or members of local communities.

While program evaluation seems to be “pushed” on frontline stake-holders as part of a top-down mandate, the goal is for frontline stakeholders to be “pulled” to involvement by an inner source of motivation to know how a clinical practice is performing and what can be done to further improve it.^5,139,147^

While both push and pull management strategies can motivate stakeholders to conduct quality evaluations of their work, these efforts are more likely to be sustained when frontline clinicians see the results as useful through feedback mechanisms (e.g., electronic dashboards, performance monitoring meetings) that can help them do their jobs while better serving consumers.^148^

The VA QUERI Partnered Evidence-based Policy Resource Center (PEPReC) (https://www.peprec.research.va.gov/) is dedicated to helping clinical programs meet high standards by providing timely, rigorous data analyses to support the development of high-priority policy, planning, and management initiatives and quantitative program evaluations.

#### Selecting an Evaluation Design

As a general rule, use the most rigorous design to answer the agreed-upon evaluation questions while accounting for real-world constraints. Operational partners are often interested in questions about how to show impact as quickly as possible, so time and evaluation measures that show improvement are important considerations.

In contrast, investigators are often interested in questions that center on which implementation strategies to provide, to whom, and when to achieve successful implementation outcomes.^149^ Accordingly, implementation scientists prefer study designs that compare the effectiveness of strategies or the ideal provision of different types and/or intensities of implementation strategies, including:

- Hybrid implementation-effectiveness trials (types I to III)
- Cluster or group randomized trials
- Stepped-wedge cluster randomized design
- Factorial designs
- Sequential Multiple-Assignment Randomized Trials (SMARTS)

Many Resources are available to aid you in selecting a specific, randomized evaluation design but the embedded implementation research and evaluation team should have expertise in weighing the relative merits of each design.^139,140,146,150-153^ Also, consider how the design level of randomization, representative sites, and level of analysis (i.e., network, hospital, clinic) affects whether results are replicable across a wide range of settings when you seek to spread the practice further.^146,152^

Sometimes, the requirements of favored randomized designs conflict with the priorities of operational partners. This can occur when implementation of an effective practice is delayed or the stakeholders want to spread the implementation strategies more rapidly.^20,156^

Other times, timing and resources do not allow a randomized evaluation due to ethical concerns by operational partners or participating sites. This can occur when effective treatments are delayed based on group assignment or time to treatment. Rigorous program evaluations are still possible using observational, quasi-experimental, and natural experimental designs, such as:^149,154,155^

- Non-equivalent control group design
- Stepped wedge design (without randomization)
- Interrupted time series
- Regression discontinuity design

Evaluators maintain design rigor by striving for group equivalence at pre-intervention assessment by using matching or matched controls. Similarly, to maintain strong internal validity, designs can use multiple pre- and post-test observations and then repeat interventions.

The VA Center for Evaluation & Implementation Resources (https://www.queri.research.va.gov/ceir/default.cfm) provides consultation to VA investigators AND operational partners for planning the designs, evaluation methods, and uses of implementation strategies.

Previous implementation studies have successfully enabled randomization by creating equal opportunity for sites to obtain implementation strategies sooner rather than later, especially when the implementation strategies require start-up resources or additional time to deploy, which precludes sites from supporting the implementation at once. Operations stakeholders may also find value in a comparison group, especially if they want to know whether the financial commitment of supporting the implementation strategies in an ongoing way is worth it. For more information on making the case for randomization, see the Community Partners in Care study^157^ and the Oregon Medicaid Experience studies.^158^

For implementation evaluations, Institutional Review Boards determined that randomization alone does not define research.^20^ Generally, these types of evaluations are considered non-research as long as they do not state that they are contributing to generalizable knowledge but that the results are used to inform overall programmatic or system improvements (see section above on research versus non-research for more information).

However, projects that involve randomization or other means of systematic allocation require registration in ClinicalTrials.gov or Biomed Central (https://www.biomedcentral.com/getpublished/writing-resources/trial-registration) before being published in scientific journals. Registration of these trials is not limited to research protocols, and implementation and program evaluations have been registered in these systems.

### Identify Measures of Success and Data Sources

There are many different types of outcome measures that can be assessed to determine whether the implementation of an effective practice has been successful.

As Figure 10 shows, implementation evaluations pay attention to three categories of outcomes:^159^

Consumer outcomes – Measure the outcomes an effective practice was designed to impact, such as symptoms, functioning, satisfaction, and other consumer-reported measures of care^160^ that can be examined at the consumer or population level of impact.

Implementation outcomes – Measure the effects of deliberate and purposeful actions to implement new treatments, practices, and services using multilevel implementation strategies.

Service or system outcomes – Long-term indicators of the population impact of an effective practice that pertain to access (timeliness), efficiency, safety, effectiveness, equity, consumer centeredness, or other aspects of quality, such as overuse, underuse, unintended consequences, or misuse of care delivery.^161,162^

Figure 10 Key Implementation Science Evaluation Outcomes

Adapted from^8,160^

As shown in Table 3, implementation outcomes measure the effectiveness/success of implementation strategies, proximal measures of the implementation process, and intermediate outcomes that influence service and consumer outcomes.

In other words, if an effective practice or clinical innovation does not lead to improved consumer or service outcomes as expected, frontline stakeholders, managers, and senior health system leaders must understand whether this failure was due to:

- Poor design or fit of the effective practice with a priority health care context or consumer populations or
- Incomplete or poor implementation of an otherwise effective practice

Table 3 defines ten implementation outcomes, shows when to assess them during implementation, and provides methods to measure them.

Table 3 Implementation Outcomes

Implementation Outcomes | Definition | Implementation Stage | Example Ways to Measure
Acceptability | The extent to which implementation stakeholders perceive a treatment, service, practice, or innovation as agreeable, palatable, or satisfactory. | - Early for adoption; - Implementation; - Sustainment | - Survey; - Interviews; - Focus groups; - Administrative data; - Refusals
Adaptation | The degree to which an effective practice or implementation strategy changes to suit the needs of a local setting or priority population. | - Pre-implementation; - Sustainment | - Checklist; - Survey; - Interview
Adoption | Intention, initial decision, or action by stakeholders to try or employ an effective practice (“uptake”). | - Implementation | - Administration data; - Observation; - Interviews; - Survey
Appropriateness | Perceived fit, relevance, or compatibility of the effective practice for a given setting, stakeholder, and/or problem. | - Pre-implementation | - Survey; - Interview; - Focus groups
Effectiveness ** | Effect of the implementation strategy on key outcomes. | - Implementation; - Sustainment | - Observation; - Interviews; - Focus groups
Feasibility | Extent to which an innovation or effective practice can be successfully used or carried out within a given agency or setting. | - Implementation | - Survey; - Administrative data
Fidelity ** | Degree to which an effective practice or implementation strategy is delivered as prescribed in the original protocol or intended by developers; this may include multiple dimensions of content, process, exposure, and dosage. | - Implementation; - Sustainment | - Observation; - Checklists; - Self-report; - Administrative data
Implementation Cost | Financial impact of an implementation effort; this may include costs of treatment delivery, cost of the implementation strategy, and cost of using the service setting. | - Implementation; - Sustainment | - Administrative data; - Checklist
Penetration ** | Extent to which an innovation or effective practice is integrated within a service setting, organization, or health system (“reach”). | - Implementation; - Sustainment | - Checklists; - Program audits
Sustainability ** | Extent to which the effective practice is supported and/or institutionalized within a service’s ongoing, stable operations. | - Sustainment | - Interviews; - Program audits; - Checklists

** Adapted from^8,159,163^ **In RE-AIM evaluation framework, Reach = penetration; Maintenance = sustainability, Effectiveness is the same; Implementation = Fidelity; EP = effective practice

#### The Reach, Effectiveness, Adoption, Implementation, and Maintenance (RE-AIM) Framework

While there are a number of evaluation frameworks,^7^ the RE-AIM framework is among the most widely used to support systematic planning, mid-course adjustments, evaluation, and reporting. RE-AIM is helpful for assessing program impact at a population level for clinical outcomes (Effectiveness, Maintenance) and implementation outcomes (Reach, Adoption, Implementation). The framework also pays close attention to external validity by comparing how generalizable findings are to the consumer population(s) served by a health system and its local hospitals.^164^ The framework’s creators also advocate for the systematic use of qualitative methods to understand and explain contextual factors influencing quantitative results for each dimension.^165–167^

Table 4 The RE-AIM Program Planning and Evaluation Model

RE-AIM Dimension | Pragmatic Questions to Consider | Measurement Considerations
Reach | Who is (was) intended to benefit and who participates or is exposed to the intervention? | The number, proportion, and representativeness of individuals who are willing to participate or use an effective practice.
Effectiveness | What are (were) the most important benefits you are trying to achieve and what is (was) the likelihood of negative outcomes? | The impact of an effective practice on key outcomes among subgroups of a population, including negative (unintended consequences), quality-of-life, and economic outcomes.
Adoption | Where is (was) the clinical practice or policy applied and who applied it? | The absolute number, proportion, and representation of settings and staff who are willing to start an effective practice and those who are not.
Implementation | How consistently is (was) the program or policy delivered (fidelity),; how will it be (was it) adapted,; how much will (did) it cost, and; why will (did) the results come about? | The intervention staff’s fidelity to the various components of an effective practice’s protocol (i.e., delivery as intended) is one of several implementation outcomes (see Table 3).
Maintenance | When will (was) the initiative become operational; How long will (was) it be sustained (setting level); and How long are the results sustained (individual level)? Measured by longevity of effects (individual level) and program sustainment (setting level). | The extent to which an effective practice or policy becomes institutionalized or part of routine practice and policy.

Adapted from^168,169^ Terms in parentheses are phrased for post-intervention evaluation. The basic questions are phrased for use in program or policy planning.

#### Tools for Measuring Implementation Outcomes

There are many valid measures and methods for evaluating implementation outcomes—some of which can be assessed by using a combination of qualitative and quantitative (mixed methods) strategies to assess multilevel stakeholders’ attitudes, beliefs, intentions, and behaviors. Some of the measures for examining implementation outcomes can be found through the Society of Implementation Research Collaboration (https://societyforimplementationresearchcollaboration.org/sirc-instrument-project/); however, membership is required to access most measures.

#### Other Key Outcomes

Balancing Measures assess the potential unintended consequences of implementing a new effective practice, such as consumer harm from over- or under-treatment or the decreases in care in other domains.^170^ For example, tight control of many chronic conditions, such as anxiety, high blood pressure, diabetes, and pain, have resulted in unintended harms to consumers, their families, and the communities where they live. These examples highlight the need for continuous monitoring of quantitative health outcomes and qualitative data from consumers and frontline stakeholders who are well-positioned to detect signs of unintended consequences.

Economic evaluation outcomes include estimates of the financial impact of adopting competing effective practices or whether to use different implementation strategies to achieve individual- and population-level impacts on health outcomes. There is currently very little information available to health system and local regional/hospital administrators about the comparative cost-effectiveness of different implementation strategies. It is currently a high priority within implementation science and health systems to understand the economical logistics of using one clinical intervention (implementation strategy) over another to address a clinical priority to use resources efficiently.^171,172^

The VA’s Health Services Research and Development Service Health Economics Resource Center (HERC) (http://www.herc.research.va.gov/) is as an embedded national resource center that supports VA economic research^173^ to increase health care efficiency and value for Veterans and the nation. HERC provides tools and resources to assist researchers and operational leaders in conducting economic analyses for implementation research.

Health economists can help program evaluators design, collect, and evaluate economic data to conduct analyses on cost-effectiveness, inform return on investment decisions, and forecast the potential scale-up or de-implementation of an effective practice

There are different types of health economic evaluations, and they differ based on whose perspective the analysis is conducted (i.e., whose cost is included, such as the health care sector, consumer/caregiver, or societal) and the length of time to evaluate impact. Economic evaluations often use a ratio that compares costs in the numerator to changes resulting from the effective practice in the denominator, as shown in Figure 11.

Non-VA Resources on economic evaluation can be found under RESOURCES (e.g., U.S. Centers for Disease Control & Prevention Polaris Economic Evaluation website).

Figure 11 Economic Consequences of Implementing Effective Health Practices

Adapted from figure 8.1, Neumann et al 2016

Historically, the gold standard was a cost-effectiveness analysis in which all costs are included in the numerator (a societal perspective) and quality adjusted life years are the denominator.^174,175^ Cost-effectiveness analyses have long been preferred over cost-benefit analyses, which requires measuring the denominator in dollars. Cost-benefit analyses are often used in other fields, such as environmental economics, but rarely used in health care because of disagreement among economists regarding how to monetize some types of health outcomes.^172^

In the past 20 years, many decision makers have struggled with cost-effectiveness analyses because they include costs outside their purview (i.e., costs to society) and the evaluation time frame is much longer than their budget cycles. Consequently, budget impact analyses became increasingly popular, and the International Society for Pharmacoeconomics and Outcomes Research promulgated standards for business impact analyses, which has been widely used in drug and device evaluations.^176^

A budget impact analysis focuses only on the costs (the numerator) of implementing a new practice from a specific payer’s perspective (e.g., health care system) over a shorter timeframe of one to three years. Thus, many of the costs in the numerator, such as caregiver or consumer costs, are excluded. This narrower and more pragmatic approach has appealed to many decision makers who have limited budgets and simply want to know, “Can I afford it?” A budget impact analysis also incorporates the number of people affected by adopting a new practice to calculate a true “unit” cost (cost/consumer) and is useful for estimating the total budget to fund the new practice and its related implementation costs.

Budget impact analysis is sometimes used interchangeably with return on investment, although this can be misleading because a return on investment often includes a “return” that is non-financial, such as consumer outcomes or reduced staff burnout. For evaluators, the added complexity of valuing these non-financial returns for multiple perspectives makes the return on investment less practical than a budget impact analysis.

Finally, while economic evaluations may have been conducted on the effective practice, there is a scarce amount of data available to compare the relative costs of using different implementation strategies to support uptake of different types of effective practices across settings and consumer populations. In situations where these costs do not exist, economists rely on micro-costing methods to estimate costs. Micro-costing requires direct measurements of relevant activities and assigns costs to them.

In recent years, frameworks have been developed to track implementation activities for micro-costing,^177,178^ which generally focuses on the costs needed to replicate the effective delivery of a practice. Sometimes, the implementation and effective practice costs are intertwined, and it may be necessary to measure costs collectively (e.g., treatments adapted for delivery by a special video or e-health delivery mode). These costs must be recorded regularly using costing surveys, standardized templates, or other methods.

Table 5 Comparison of Implementation and Effective Practices to Track for Micro-Costing

Implementation Costs | Effective Practice Costs
Implementation strategy costs (labor) | All costs to deliver the effective practice
Consumer/stakeholder engagement costs | Practice administration, consumer recruitment
Program adaptation costs | Creating/adapting program materials, supplies
Planning, staff recruitment, training, monitoring | Mailings, phone calls, text messages
Printing, adapting materials, supplies, data collection | Data entry, performance monitoring
| Trainings, meetings, travel
| Diagnostic or surveillance lab sample collection and testing
| All staffing

Note: Costs may change over time from Pre-implementation to Sustainment

#### Process Evaluation Data

Qualitative evaluation refers to an approach that does not rely on quantitative measurement or statistical analysis and aims to understand and explain why clinical interventions may or may not work by seeking multiple perspectives from individuals involved at different levels of the health care system.^179^ Qualitative methods often include individual and group interviews, participant observations, ethnography, field notes, and analyses of key documents (e.g., tracking iterative Plan-Do-Study-Act improvement cycle outcomes). Qualitative methods and data are forms of process evaluation. There are many excellent Resources on qualitative research methods.^180–183^

Process evaluation aims to identify influences on the processes delivering the clinical effective practice and/or implementation strategies. Process evaluation can be collected throughout the implementation process and help determine:

- How well a practice or implementation is working
- The extent to which a practice or strategy is implemented as designed (e.g., fidelity, dose, attendance, dropout)
- Whether a program is accessible or acceptable to a priority population of consumers

Process evaluation usually involves qualitative methods but may involve quantitative methods or a mix of both qualitative and quantitative (mixed methods) to study influences on the delivery of the effective practice and the strategies used to implement it. Process evaluation is useful for gaining insight into the contextual factors that explain why or how something occurred. Process evaluations can be formative or summative process evaluation methods.^184^

Formative evaluation is a rigorous assessment process designed to identify and make use of potential and actual influences on the progress, quality, and potential sustainment of implementation processes (i.e., effective practices and/or implementation strategies).^185,186^ Formative data is important in implementation evaluations because they:

- Help refine, improve, and evolve the implementation process and in some cases, adapt an implementation strategy and/or effective practice itself
- May be conducted before, during, and/or after implementation activities to provide data for immediate use to optimize an implementation effort and interpret findings after formal implementation activities end^30,186^

Formative methods are often guided by a theory or framework, particularly to organize semi-structured interview guides and plan key points of time to sample key clinical stakeholders during the implementation process.

Summative evaluation methods are used to make a number of summative judgements about the worth of an effective practice and/or implementation strategy relative to the intended purpose. Summative data provides an indication of an effective practice’s success in achieving the desired clinical impacts. This occurs at the end of an implementation evaluation.^30,186^

Table 6 Contrasting the Perspectives of Formative and Summative Evaluation

Formative Evaluation | Summative Evaluation
- How is the practice implemented? | - To what extent are desired changes occurring? For whom?
- Is the practice delivered at capacity? | - Is the practice making an impact?
- Are practice/implementation activities delivered as intended? | - What seemed to work? Not work?
- Are consumers being reached as intended? | - What were unintended outcomes?
- What are consumer reactions? | - Did the implementation activity have the intended effect?

Adapted from^55^

Several Resources are available to help evaluators use process evaluation methods.^187,188^

#### Sources of Health System Data

Health system consumer care and administrative databases are the primary source of data used to monitor outcomes during an implementation or quality improvement initiative. In many instances, these systems provide reliable data collection and reporting tools that track clinical outcomes from the electronic health record, as well as other valuable information related to consumer care. If you have access to information specialists (e.g., programmers, analysts, statisticians), administrative data can add value to projects evaluating clinical outcomes and process improvement.

Within the Veterans Health Administration, there are various sources of administrative and clinical data including:

Table 7 Select Sources and Types of Department of Veterans Affairs Clinical and Administrative Data Circa 2020

Data By Source
VA Corporate Data Warehouse (CDW): national repository comprising data from several VHA clinical and administrative systems, including the electronic health record (EHR)
VHA User Enrollment Databases: Assistant Deputy Under Secretary for Health (ADUSH) Enrollment Files, Planning Systems Support Group (PSSG) Geocoded Enrollee Files
VA Patient Portal and Survey Data: MyHealtheVet, Bereaved Family Survey, and the Survey of Health Care Experiences of Patients (SHEP)
Tools for EHR review: CPRS, Joint Legacy Viewer (JLV), Compensation and Pension Records Interchange (CAPRI), and Cerner Millennium
Data By Topic
Cost Data: Health Economics Resource Center (HERC) cost data, Managerial Cost Accounting (MCA) National Data Extracts, Centers for Medicare & Medicaid Services (CMS) claims data
Utilization Data: CDW, HERC Average Cost Dataset, ADUSH Enrollment Files, MCA, Medical SAS (MedSAS) Inpatient and Outpatient files
Death and Vital Status Data: CDW, VHA Vital Status File (VSF), Mortality Data Repository (MDR)
Pharmacy Data: CDW, Pharmacy Benefits Management Database (PBM), Pharmacy National Data Extracts (NDE)
Centers for Medicare & Medicaid Services Data for Veterans: Medicare, Medicaid, Patient Assessment, Healthcare Effectiveness and Information Set (HEDIS), United States Renal Data System (USRDS)
VA Facility and Employee Data: CDW, Veteran Administration Site Tracking (VAST) Database, Primary Care Management Module (PCMM) Web
Special Populations Data: VA Central Cancer Registry (VACCR), National Center for Homeless Veterans Registry, VA Airborne Hazards and Open Burn Pit Registry

Some data may be made available through clinical dashboards to apprise clinicians and policy leaders of the performance of related services.

To understand whether an improvement or implementation initiative is having the intended impact on clinical and quality outcomes, you need a clearly defined data and measurement plan that specifies:

- The source of data
- The frequency of data collection
- How the data is collected (e.g., self-reported, clinician-contributed, or system-generated)
- Who validates, processes, and analyzes the data before dissemination
- How the data are standardized for comparability across sites and stakeholders
- How the data is synthesized to be functional and usable by stakeholders at different levels of the organization
- How stakeholders and sites are selected to participate
- Whether data for comparator sites are obtained and included in reports
- When, where, and how qualitative methods (e.g., interviews, focus groups, observations) and surveys are conducted
- Who performs qualitative and quantitative analyses and what methods are used to ensure timeliness
- Whether some form of local, regional, or centralized technical assistance is available to help sites overcome data collection and reporting challenges

Developing a data collection and measurement plan early in Pre-implementation ensures proposed data reporting is feasible and can meet the expectations of implementation planners. To effectively use the wide variety of data available within a large health system like the VA, it is important to have a team with data expertise. Skilled programmers and analysts can guide the evaluation of relevant health system data throughout the processes of data extraction, cleaning, analysis, interpretation, and reporting. Many implementation failures are associated with an initiative’s inability to use and apply data, information, and knowledge to influence current practices and motivate change.^189^

The VA Information Resource Center (VIReC) (http://www.virec.research.va.gov/) is a key resource for navigating VA’s complex data environment. VIReC meets this challenge by developing and disseminating an array of resources for understanding and working with VA data as well as advocating for data user needs. As an embedded resource center with national scope, VIReC is dedicated to increasing access to data, methods, and knowledge resources, and supporting the use of the EHR for operational and research evaluations.

Many implementers underestimate the time, complexity, and resources necessary to develop functional data reports and systems, while overestimating the health care system’s ability to provide the desired data. Notably, electronic health record systems may have functional limitations that make it difficult to collect and provide certain types of data that are required by an improvement project. Using a logic model helps identify key data outcomes and ensures the measurement strategies used to collect this data are feasible, cost efficient, and timely.

#### Using a Logic Model as an Evaluation Tool

A logic model is often used to guide evaluation planning. In particular, it can help:^57,130^

- Determine what to evaluate
- Identify appropriate evaluation questions based on your practice
- Know what information to collect to answer these questions (indicator metrics)
- Determine when to collect data
- Determine data collection sources, methods, and measures

Logic models are also useful to help define the focus on four key evaluation domains:

1. Implementation (process) – Is the practice implemented as planned? Were all the activities carried out as expected? What influences the quality of the activities?
2. Effectiveness (outcomes) – Is the practice achieving its desired short-, medium-, and/or long-term effects/outcomes?
3. Efficiency – How much “product” or benefit is produced for a given level of inputs and resources? (See Economic Evaluation Outcomes)
4. Causal Attribution – Is the progress toward outcomes due to the practice? In health care settings, causal attribution can be more difficult to determine, especially in terms of program impacts. However, implementation science evaluation methods have made it easier to determine the causality between activities and outputs and short- to medium-term outcomes. This can usually be accomplished with minimal effort by using a combination of surveys, interviews, and analyses from clinical care databases to establish causality.

Figure 12 Evaluation Domains Using a Logic Model

Graphic source.^130^

The boxes and arrows in the figure above indicate evaluation points where it is helpful to ask evaluation questions. As the practice progresses through the logic model (i.e., as the implementation effort matures), a new series of evaluation questions can be developed. While summative outcome evaluation looks back at the entire model, quality process evaluation models identify reasons for less-than-successful practice implementation (i.e., where did the model break down?).

Figure 13 Illustrates how a logic model helps formulate evaluation questions and indicator metrics for your practice

Graphic source^137^

The logic model in Figure 14 shows key parameters of a nationwide, partnered implementation initiative that aimed to reduce health risks in a vulnerable Veteran population. The Reengaging Veterans With Serious Mental Illness in Treatment (SMI Re-Engage) program was a joint effort by mental health leaders and VA investigators to reduce premature mortality in Veterans with serious mental illnesses, such as bipolar or schizophrenia spectrum disorders.^190,191^ Veterans with these psychiatric diagnoses already face greater health risks than those without these diagnoses, but these health risks can be compounded when an individual goes long periods of time without treatment for both mental and physical health needs. The following logic model communicates the essential aspects of this population-level improvement initiative to all that are involved, even as the program has been sustained over time.^192^

Figure 14 Example of a Logic Model for Implementation of a Public Safety Intervention

While these models vary in size and complexity, understanding the implementation of an effective practice from start to finish assists in developing measures of implementation outcomes, clinical outcomes, and longer-term service outcomes (population impact indictors). Over time, logic models will likely be refined and updated as real-world experience clarifies paths toward consistent outcomes (vs. theorized pathways) and measures are revised to better align with implementation activities. Figure 14 shows an example of a logic model in action.

More Resources^55-57,130^ can be found here for using a logic model for intervention and evaluation planning.

### Establish Baseline Performance

To assess the outcome of implementing an effective practice in a specific setting, you need an estimate of the Pre-implementation level of performance of the targeted measure of interest:^193^

- What performance data is currently available? Is this information useful to the current practice?
- What other information should be accessed? Is this data readily available?
- Are new data collection, cleaning, analysis, and reporting processes needed? If so, what resources are needed to complete this task?
- How often does data need to be collected and reported?

In most integrated health systems, like the Veterans Health Administration, operational program offices track performance on key clinical indices of care quality at the national, regional, hospital, clinical, and levels.

Internal and external benchmarks of quality and performance, as well as input from stakeholders, are used to define improvement target goals in the development of a logic model. Performance goals should align with local and national clinical care priorities and the organization’s mission and values.

Table 8 Sources of Quality Benchmarks for Performance Measurement

Examples of Publicly Available | Examples of Department of Veterans Affairs Specific
- National Quality Forum; - National Committee for Quality Assurance; - Hospital Compare (Centers for Medicare & Medicaid Service/Medicare); - Medicare Merit-based Payment System Quality Payment Program; - Professional society clinical practice recommendations (e.g., American College of Physicians, ADA, AMA, American Academy of Physicians); - Joint Commission on Accreditation of Health Care Organizations | - Veterans Health Administration Network Director Performance Plan; - Veterans Health Administration Medical Center Director Performance Plan; - Strategic Analytics for Improvement & Learning (SAIL); - Department of Veterans Affairs MISSION Act quality standards; - Operational office clinical performance measures and dashboards; - Department of Veterans Affairs clinical practice guideline recommendations

Baseline data also enables the formulation of meaningful performance goals for improvement by examining recent past performance and what is expected in the future based on implementing the effective practice. Baseline evaluations should include multiple aspects related to Pre-implementation performance in the targeted area:

- Clinical outcome (short, intermediate, and long-term)
- Appropriateness (overuse, underuse, misuse)
- Utilization
- Consumer-reported measures (outcomes, experience, preferences)
- Stakeholder-reported experiences
- Consumer-interaction
- Value (outcome/cost)
- Cost
- Unintended consequences

A standard aspect of the process of selecting a quality measure should involve conversations with stakeholders (i.e., clinical staff from all levels, customers, and system administrators) to determine if potential measures are considered meaningful and valid, particularly by frontline stakeholders.^194^ Leaders and frontline stakeholders should agree upon measures that are most important to improve care. Avoid starting with the wrong goal (e.g., beginning with measures of accountability stifles stakeholders’ desire to use data).^195^

Best Practice

Unless a benchmark is imposed on your program by outside stake-holders or regulators, take time to collect preliminary results before choosing a goal. Knowing your performance at the start of the project not only provides you with baseline data against which you can measure your progress, but it will guide your decision-making about how high to set your initial goals to improve clinical or quality outcomes.^196^

When operational partners lack appropriate clinical measures for an implementation project, investigators can assist in developing low-cost, pragmatic evaluation measures that are of clinical importance; evaluate the appropriateness of care; and provide expertise supported by a clinical evidence base, including measure specifications (e.g., numerator and denominator, clarity, validity, reliability, risk adjustment) that are feasible to collect and applicable to modifying care.^194,197,198^ Make sure to specify the underlying source of data for a measure, methods used to calculate the measure, and the time frame for which to report the measure.^193^ Given the proliferation of performance measures that are inaccurate and invalid, we strongly advise you to consider the American College of Physicians (https://www.acponline.org/) guidance for reviewing whether a performance measure is a valid and clinically meaningful.^194^

For large-scale, multisite initiatives requiring the creation or modification of electronic medical record templates to track clinical metrics and process measures, the VA Engineering Resource Centers can assist in enabling these tracking and reporting system changes. Likewise, at each medical center or health system, local system redesign engineers and clinical applications coordinators can support making changes to the health information system for evaluation and reporting purposes in local settings.

Table 9 Strategies to Develop Meaningful Measures for Frontline Staff

Secure frontline stakeholder buy-in
- Provide evidence of effective practice’s effectiveness and benefit to local setting; - Ensure measures are perceived as valid, evidence-based, and reliable; - Select measures that are relevant to organizational goals and mission
Use measures that matter and are meaningful to frontline stakeholders and managers
- Involve frontline stakeholders in the process of selecting and vetting measures; - Understand how stakeholders and staff make sense and use data or performance measures; - Use measures to inspire and create positive change; - Be mindful that some operational measures may not matter to stakeholders; - Use measures that reflect direct consumer care
Optimize strategies for data collection and reporting to multilevel stakeholders
- Limit number of reported measures; - Ensure it is cost effective to collect and report the measure data; - Present measures in formats that are accessible, clear, concise, and digestible; - Ensure measures do not conflict with each other (compatible); - Develop measures that are comparable across services, sites, regions, and time; - Use measures that can be provided in timely manner to change stakeholder behavior; - Hold regular accountability meetings to review measures
Avoid planning pitfalls and counterproductive strategies
- Overemphasis on measures of accountability or payment implying: 1) frontline stakeholders are motivated by fear or financial motivations 2) leaders prioritize bottom line over consumer care; - Inadequate estimates of time, resources, and analytic support to access, transform, report data; - Assume data user literacy; - Select measures that create extra work for frontline clinicians to input; - Use too many measures that create confusion and disengagement (“metric fatigue”)

Adapted from^148,199–201^