# Introduction

The QUERI Roadmap for Implementation and Quality Improvement describes how implementation science and quality improvement concepts, methods, and evaluation strategies can be used to improve health care outcomes and quality over time.

Learning health systems like the Veterans Health Administration strive to continuously innovate and respond to changing system priorities, policies, and treatment practices. Successful innovation to address these demands is driven by multidisciplinary teams of clinicians, consumers, managers, and investigators working together to develop reliable ways to implement practices that improve consumer outcomes, or in some cases, de-implement the use of low-value practices.

Technology accelerates the creation of medical knowledge and front-line clinicians need a systematic way to plan, adopt, adapt, and spread new clinical practices across diverse settings in the face of limited resources. This guide draws upon two decades of Department of Veterans Affairs QUERI (https://www.queri.research.va.gov/) experience addressing these challenges within the largest integrated health system in the United States and advancing the disciplines of implementation science and quality improvement in health care.^2^

Our leadership commissioned this guide based on a growing demand for a more user-friendly approach to planning and managing the implementation of effective practices, especially for frontline employees making these changes.^3^

Our goal for the QUERI Roadmap is to bring together best practices, methods, and metrics to create a common approach for multidisciplinary implementation teams accelerating knowledge into practice.

## Who Is This Guide For?

We developed the QUERI Roadmap as a pragmatic guide to enable individuals who wish to work within clinical settings and partner with clinical leaders and other stakeholders to support improvement efforts.^4^

By stakeholders, we mean anyone who has a direct or indirect role in supporting the adoption and use of an effective practice, including senior organizational leaders, managers, clinicians, support staff, and health care consumers.

Implementation scientists study the optimal way to move effective practices into real-world practice and apply their knowledge to help bring a diverse array of innovations to benefit consumers across various treatment specialties and settings.

In this guide we try to avoid the use of academic or technical words in order to promote communication across disciplines and share different perspectives, failures, and ideas that enable teams to solve complex health care problems.^5^

This guide offers a comprehensive approach or “roadmap” to pragmatically apply implementation science methods to overcome barriers to integrating effective practices or promising innovations in routine care. All stakeholders in a health system benefit from using rigorous implementation and evaluation methods.

Strong evaluation methods help us understand not only the performance of an effective practice, but also why and how a change happened during implementation, its cost, and its potential for sustained use. This practice-based knowledge is valuable to organizational leaders, investigators, and other stakeholders at the local and regional levels of an organization who desire the relevant knowledge and skills for optimizing implementation efforts.^6^

## How Do I Use this Guide?

The QUERI Roadmap serves as a comprehensive and practical approach to guide you through the process of implementing an effective clinical practice or quality improvement program.^3^

The roadmap is a framework that takes you through the entire implementation process,^7^ which we divide into three phases: Pre-implementation, Implementation, and Sustainment. Within each phase, there are three levels of core domains that pose questions to you and your team about activities needed to:

Although the roadmap is organized into three separate phases, in real-world practice, the activities and components described in each phase overlap and are not always distinct. In some cases, failures, setbacks, new information, or discoveries may require you to revisit a prior phase and adjust your planned process to achieve the outcomes you want.

Rather than focus on implementation theory or implementation research design—as covered in a related resource (https://cancercontrol.cancer.gov/IS/docs/NCI-ISaaG-Workbook.pdf) by our colleagues at the National Cancer Institute (https://cancercontrol.cancer.gov/IS/)^8^—the QUERI Roadmap offers practical mile markers to help you understand when and how to apply specific implementation methods to implement a practice.

We include three Case Studies to illustrate real-world applications of the QUERI Roadmap to implement diverse practices to address health care challenges.

## Resources

When you see Resources, click to see more information on a specific topic related to quality improvement, implementation science, or evaluation, including tools, websites, and other resources.

Bold Blue terms are linked to the Glossary at the back of the guide to define key concepts. Similarly, a comprehensive References list enables you to cross-reference the science underlying this guide.

We also provide links to VA Resources that can help support implementation and quality improvement efforts in the VA.

Most of the VA Resources are available via public-facing websites. Furthermore, VA resource centers highlighted in this guide illustrate best practices for applying evaluation and implementation methods that you might consider replicating in your health care setting. Finally, please note that some consultative services may only be available to VA health professionals.

## Why a Roadmap?

### A brief history of our role in implementation science and practice

QUERI was created in 1998 to deploy effective practices to support the VA’s transformation in the 1990’s from a hospital-based system to a large, integrated health system. Initially, our funded centers focused on implementing effective practices for specific health conditions (e.g., congestive heart failure, diabetes, mental disorders, spinal cord injury) that were identified and operationalized via a traditional “pipeline” approach. Figure 1^9,10^ shows our first Implementation Framework pipeline, which drove significant improvements in health outcomes and service delivery for Veterans. This process led to the formation of a QUERI-wide network of implementation experts and the international Implementation Research Group, which is now organized by our Center for Evaluation and Implementation Resources.

To better meet the rapidly changing needs of Veterans, clinicians, and VA health system, we update QUERI Strategic Plan goals every 5 years. The 2021-2025 QUERI Strategic Plan incorporates feedback from 150+ key stakeholders based on a national evaluation of overall program impact and incorporates practical implementation approaches to achieve quality improvements.^2,11–14^

Figure 1 The Foundation: QUERI Implementation Framework 1.0^*^ * To learn more, see past QUERI journal supplements: Medical Care, 2000; 38(6).; Journal of General Internal Medicine. 2006; vol. 21.; Implementation Science, 2008; vol. 3.

We saw an opportunity to make implementation science more user-friendly and accessible for frontline stakeholders who need to apply this knowledge. Thus, the QUERI Roadmap was commissioned to extend the previous “pipeline”^10^ framework for implementation activities that reflected a traditional, linear research process, to one that is more agile, iterative, and responsive to operational priorities.

The QUERI Roadmap also extends the traditional research pipeline by including recent advancements in implementation science while drawing on key lessons from our experiences and the experiences of other health system leaders in implementing new practices. For example, we learned that uptake of effective practices is based on the use of implementation strategies that empower and motivate frontline stakeholders to adopt and sustain a new practice.

In this guide, we view implementation as a dynamic process that requires active and engaged input from multilevel stakeholders to identify, implement, and sustain effective practices over time. The roadmap emphasizes designing and implementing practices for sustainability starting in Pre-implementation; this means once start-up resources disappear, the practice must be resilient and fully integrated into local clinical processes, workflows, and operating budgets as standard care.

The Learning Health System Knowledge to Action Framework^15–17^ (Figure 2) informs the roadmap and combines elements of a learning health system with Graham and colleagues’ Knowledge to Action Framework.

A learning health system is broadly defined as any organization that routinely and continuously seeks to generate and learn from data with the purposes of improving individual and consumer health.^17,18^ This framework operationalizes a continuous quality improvement approach to promote learning among all stakeholders. In this roadmap, we view implementation as an iterative process that generates new questions and knowledge based on rapid and systematic improvement cycles.

The Knowledge to Action Framework is a conceptual framework designed to reduce the long-time gap between when knowledge is created (research or practice-based knowledge) and the actual time it is put into use by clinicians, policymakers, consumers, or the public.^15^ The framework breaks this process into two primary components: 1) knowledge creation; and 2) an action cycle of implementing the knowledge into practice.

The Knowledge to Action Framework observes how these components interact with each other over time, variation in the settings where the knowledge is to be applied (hospitals, clinics), and barriers to knowledge use that may occur inside and outside the context of the adopting organization.^15,19^ Barriers to knowledge use must be identified and iteratively addressed through implementation strategies and ongoing evaluation. Through this interactive problem-solving process to tailor or adapt the knowledge for local contexts, you can develop further knowledge about this process and share it internally while also sharing it within the larger health care community to improve clinical practice.

Figure 2 Learning Health System Knowledge to Action Framework with QUERI Roadmap

- Health care system data are used to set local priorities for improvement
- Data on the priority problems and potential contributors helps find evidence-based solutions to improve local health system care (data to knowledge)
- Evidence-based knowledge informs quality improvement and implementation science guided efforts (knowledge to performance improvement)
- Continuous monitoring of local health system helps clinicians iteratively learn and develop practice-based knowledge while revealing new opportunities for improvement (performance to data)

Adapted from^3^

## Applying the Roadmap

### Is My Project Considered Research or Non-research?

The Common Rule (https://www.hhs.gov/ohrp/regulations-and-policy/regulations/finalized-revisions-common-rule/index.html) is the 1981 baseline standard of ethics by which any government-funded research in the United States is held accountable regarding biomedical and behavioral research involving human subjects. Recent changes to the Common Rule—including the broadening of research exemption categories and recognition of program evaluation as non-research—enable certain implementation-focused projects to be designated as non-research or “quality improvement.” As a result, more Institutional Review Boards are designating implementation projects and program evaluations as non-research,^20^ especially projects that compare different implementation strategies or evaluate the impacts of the program or practice on the health system.

In the VA, projects that are designed to inform improvement efforts within the health system can be designated as non-research if the work is not designed to produce information that expands the knowledge base of a scientific discipline or other scholarly field.

Examples of activities in a project that would be considered expanding the knowledge base of a scientific discipline include the development or validation of new surveys or the direct testing of theoretical models that inform care outside the health system. In general, implementation projects can be considered non-research if results are used to inform care improvements to the system and overall setting.

Note: Randomization alone does not define implementation projects as research. Implementation and quality improvement initiatives can involve randomization as long as the focus is on program or implementation evaluation and not testing a new treatment or practice for efficacy or effectiveness on patient health.

More importantly, you can publish non-research projects in scientific journals, but you must document non-research status for most journals. Consult with the journals and your local health system or academic research office regarding the best approach for documenting non-research status and whether the protocol would need to be reviewed by an Institutional Review Board.

The following online seminar provides guidance on how to best navigate this issue in the VA:

Jeans CK, Kilbourne AM, Booker F., Braganza M. VA Quality Enhancement Research Initiative (QUERI): Everything you need to know about a QUERI non-research (“quality improvement”) protocols. 2019. Available at: https://www.hsrd.research.va.gov/for_researchers/cyber_seminars/archives/3669-notes.pdf

In many cases, implementation projects can still be considered “research” but not “human subjects research.” In these cases, the projects are further exempt from Institutional Review Board review and may qualify for a waiver of subject-informed consent if the project is considered minimal risk.

For more information on the distinction of research vs. non-research (quality improvement), see RESOURCES and consult your local health system or academic research office for consultation.