# REFERENCES

1 Rikard SM, Strahan AE, Schmit KM, Guy GP, Jr. Chronic Pain Among Adults - United States, 2019-2021. MMWR Morb Mortal Wkly Rep. Apr 14 2023;72(15):379–385. doi:10.15585/mmwr.mm7215a1 37053114
2 Kligler B, Bair MJ, Banerjea R, . Clinical Policy Recommendations from the VHA State-of-the-Art Conference on Non-Pharmacological Approaches to Chronic Musculoskeletal Pain. J Gen Intern Med. May 2018;33(Suppl 1):16–23. doi:10.1007/s11606-018-4323-z
3 Becker WC, DeBar LL, Heapy AA, . A Research Agenda for Advancing Non-pharmacological Management of Chronic Musculoskeletal Pain: Findings from a VHA Stateof-the-art Conference. J Gen Intern Med. May 2018;33(Suppl 1):11–15. doi:10.1007/s11606-018-4345-6
4 Sterling M, de Zoete RMJ, Coppieters I, Farrell SF. Best Evidence Rehabilitation for Chronic Pain Part 4: Neck Pain. J Clin Med. Aug 15 2019;8(8)doi:10.3390/jcm8081219
5 Rice D, McNair P, Huysmans E, Letzen J, Finan P. Best Evidence Rehabilitation for Chronic Pain Part 5: Osteoarthritis. J Clin Med. Oct 24 2019;8(11)doi:10.3390/jcm8111769
6 PAIN MANAGEMENT. In: Administration DoVA-VH, editor. Washington, DC 2009.
7 Hill JC, Whitehurst DG, Lewis M, . Comparison of stratified primary care management for low back pain with current best practice (STarT Back): a randomised controlled trial. Lancet. Oct 29 2011;378(9802):1560–71. doi:10.1016/S0140-6736(11)60937-9 21963002
8 Vlaeyen JWS, Linton SJ. Fear-avoidance and its consequences in chronic musculoskeletal pain: a state of the art. Pain. Apr 2000;85(3):317–332. doi:10.1016/S0304-3959(99)00242-0 10781906
9 Milgram PK, Fumio. A Taxonomy of Mixed Reality Visual Displays. IEICE Transactions on Information Systems. 1994;E77-D(No. 12 December 1994)
10 Rauschnabel PA, Reto Felix, Chris Hinsch, Hamza Shahab, Florian Alt. What is XR? Towards a Framework for Augmented and Virtual Reality. Computers in Human Behavior. 2022;133(August)doi:10.1016/j.chb.2022.107289
11 Goudman L, Jansen J, Billot M, . Virtual Reality Applications in Chronic Pain Management: Systematic Review and Meta-analysis. JMIR Serious Games. May 10 2022;10(2):e34402. doi:10.2196/34402 35536641
12 Dreesmann NJ, Su H, Thompson HJ. A Systematic Review of Virtual Reality Therapeutics for Acute Pain Management. Pain Manag Nurs. Oct 2022;23(5):672–681. doi:10.1016/j.pmn.2022.05.004 35868974
13 Osumi M, Inomata K, Inoue Y, Otake Y, Morioka S, Sumitani M. Characteristics of Phantom Limb Pain Alleviated with Virtual Reality Rehabilitation. Pain Med. May 1 2019;20(5):1038–1046. doi:10.1093/pm/pny269 30576543
14 VA Diffusion Marketplace. https://marketplace.va.gov/
15 DistillerSR. DistillerSR Inc. https://www.distillersr.com/
16 Cochrane Handbook for Systematic Reviews of Interventions. Updated August 22, 2023. https://training.cochrane.org/handbook
17 Sterne JAC, Savovic J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ. Aug 28 2019;366:l4898. doi:10.1136/bmj.l4898 31462531
18 Sterne JA, Hernan MA, Reeves BC, . ROBINS-I: a tool for assessing risk of bias in non-randomised studies of interventions. BMJ. Oct 12 2016;355:i4919. doi:10.1136/bmj.i4919 27733354
19 metafor: Meta-Analysis Package for R. https://cran.r-project.org/web/packages/metafor/index.html
20 Sil S, Dahlquist LM, Thompson C, . The effects of coping style on virtual reality enhanced videogame distraction in children undergoing cold pressor pain. Psychosocial & Personality Development 2840. Journal of Behavioral Medicine. 2014;37(1):156–165. doi:10.1007/s10865-012-9479-0 23184062
21 Werbart A. Emile, or on devastation: When virtual boundlessness meets inner emptiness. Psychoanalytic Therapy 3315. The Psychoanalytic Quarterly. 2014;83(1):71–96. doi:10.1002/j.2167-4086.2014.00077.x 24470365
22 GRADEpro GDT. https://www.gradepro.org/
23 Maddox T, Liesl Oldstone, Charisse Y. Sparks, Josh Sackman, Alexis Oyao, Laura Garcia, Roselani U. Maddox, Kelsey Ffrench, Heidy Garcia, Takisha Adair, Ann Irvin, David Maislin, Brendan Keenan, Robert Bonakdar, Beth D. Darnall,. In-Home Virtual Reality Program for Chronic Lower Back Pain: A Randomized Sham-Controlled Effectiveness Trial in a Clinically Severe and Diverse Sample. Mayo Clinic Proceedings: Digital Health. 2023;1(4):563–573. doi:10.1016/j.mcpdig.2023.09.003
24 Harvie DS, Kelly J, Kluver J, Deen M, Spitzer E, Coppieters MW. A randomized controlled pilot study examining immediate effects of embodying a virtual reality superhero in people with chronic low back pain. Disability and rehabilitation Assistive technology. 2022:1–8. doi:10.1080/17483107.2022.2129846 32927999
25 Yilmaz Yelvar GD, Cirak Y, Dalkilinc M, Parlak Demir Y, Guner Z, Boydak A. Is physiotherapy integrated virtual walking effective on pain, function, and kinesiophobia in patients with non-specific low-back pain? Randomised controlled trial. European spine journal : official publication of the European Spine Society, the European Spinal Deformity Society, and the European Section of the Cervical Spine Research Society. 2017;26(2):538–545. doi:10.1007/s00586-016-4892-7
26 Kammler-Sücker KI, Löffler A, Flor H. Effects of personalized movement models in virtual reality on pain expectancy and motor behavior in patients with chronic back pain: a feasibility study. Article. Virtual Reality. 2023;doi:10.1007/s10055-023-00800-4
27 Eccleston C, Fisher E, Liikkanen S, . A prospective, double-blind, pilot, randomized, controlled trial of an “embodied” virtual reality intervention for adults with low back pain. Pain. 2022;163(9):1700–1715. doi:10.1097/j.pain.0000000000002617 35324507
28 Groenveld TD, Smits MLM, Knoop J, . Effect of a Behavioral Therapy-Based Virtual Reality Application on Quality of Life in Chronic Low Back Pain. Article. The Clinical journal of pain. 2023;39(6):278–285. doi:10.1097/AJP.0000000000001110 37002877
29 Garcia LM, Birckhead BJ, Krishnamurthy P, . An 8-Week Self-Administered At-Home Behavioral Skills-Based Virtual Reality Program for Chronic Low Back Pain: Double-Blind, Randomized, Placebo-Controlled Trial Conducted During COVID-19. Journal of medical Internet research. 2021;23(2):e26292. doi:10.2196/26292 33484240
30 Garcia LM, Birckhead BJ, Krishnamurthy P, . Three-Month Follow-Up Results of a Double-Blind, Randomized Placebo-Controlled Trial of 8-Week Self-Administered At-Home Behavioral Skills-Based Virtual Reality (VR) for Chronic Low Back Pain. The journal of pain. 2022;23(5):822–840. doi:10.1016/j.jpain.2021.12.002 34902548
31 Garcia L, Birckhead B, Krishnamurthy P, . Durability of the Treatment Effects of an 8-Week Self-administered Home-Based Virtual Reality Program for Chronic Low Back Pain: 6-Month Follow-up Study of a Randomized Clinical Trial. Journal of medical Internet research. 2022;24(5):e37480. Erratum in: J Med Internet Res. 2022 Jun 8;24(6):e40038 PMID: 35675658 [https://www.ncbi.nlm.nih.gov/pubmed/35675658]. doi:10.2196/37480 35612905
32 Maddox T, Garcia H, Ffrench K, . In-home virtual reality program for chronic low back pain: Durability of a randomized, placebo-controlled clinical trial to 18 months post-treatment. Regional Anesthesia and Pain Medicine. 2022:e22104093. doi:10.1136/rapm-2022-104093
33 Maddox T, Sparks C, Oldstone L, . Durable Chronic Low Back Pain Reductions to 24-Months Post-Treatment for An Accessible, 8-Week, In-Home Behavioral Skills-Based Virtual Reality Program: A Randomized Controlled Trial. Pain Med. May 23 2023;doi:10.1093/pm/pnad070
34 Anam S, Uchino E, Misawa H, Suetake N. Automatic bone boundary detection in hand radiographs by using modified level set method and diffusion filter. 2013:51–55.
35 Nambi G, Alghadier M, Kashoo FZ, . Effects of Virtual Reality Exercises versus Isokinetic Exercises in comparison with Conventional Exercises on the Imaging Findings and Inflammatory Biomarker Changes in Soccer Players with Non-Specific Low Back Pain: A Randomized Controlled Trial. International journal of environmental research and public health. 2022;20(1)doi:10.3390/ijerph20010524
36 Fatoye F, Gebrye T, Mbada CE, . Cost effectiveness of virtual reality game compared to clinic based McKenzie extension therapy for chronic non-specific low back pain. British journal of pain. 2022;16(6):601–609. doi:10.1177/20494637221109108 36452130
37 Nambi G, Abdelbasset WK, Elsayed SH, . Comparative Effects of Isokinetic Training and Virtual Reality Training on Sports Performances in University Football Players with Chronic Low Back Pain-Randomized Controlled Study. Evidence-based complementary and alternative medicine : eCAM. 2020;2020:2981273. doi:10.1155/2020/2981273 32617104
38 Afzal MW, Ahmad A, Mohseni Bandpei MA, Gilani SA, Hanif A, Waqas MS. Effects of virtual reality exercises and routine physical therapy on pain intensity and functional disability in patients with chronic low back pain. JPMA The Journal of the Pakistan Medical Association. 2022;72(3):413–417. doi:10.47391/JPMA.3424 35320216
39 Li Z, Yu Q, Luo H, . The Effect of Virtual Reality Training on Anticipatory Postural Adjustments in Patients with Chronic Nonspecific Low Back Pain: A Preliminary Study. Neural plasticity. 2021;2021:9975862. doi:10.1155/2021/9975862 34367274
40 Sato T, Shimizu K, Shiko Y, . Effects of Nintendo Ring Fit Adventure Exergame on Pain and Psychological Factors in Patients with Chronic Low Back Pain. Games for health journal. 2021;10(3):158–164. doi:10.1089/g4h.2020.0180 33891508
41 Nambi G, Abdelbasset WK, Alsubaie SF, . Short-Term Psychological and Hormonal Effects of Virtual Reality Training on Chronic Low Back Pain in Soccer Players. Journal of sport rehabilitation. 2021;30(6):884–893. doi:10.1123/jsr.2020-0075 33596538
42 Nambi G, Abdelbasset WK, Alrawaili SM, Alsubaie SF, Abodonya AM, Saleh AK. Virtual reality or isokinetic training; its effect on pain, kinesiophobia and serum stress hormones in chronic low back pain: A randomized controlled trial. Technology and health care : official journal of the European Society for Engineering and Medicine. 2021;29(1):155–166. doi:10.3233/THC-202301 32831210
43 Kim T, Lee J, Oh S, Kim S, Yoon B. Effectiveness of Simulated Horseback Riding for Patients With Chronic Low Back Pain: A Randomized Controlled Trial. Journal of sport rehabilitation. 2020;29(2):179–185. doi:10.1123/jsr.2018-0252 30676224
44 Zadro JR, Shirley D, Simic M, . Video-Game-Based Exercises for Older People With Chronic Low Back Pain: A Randomized Controlledtable Trial (GAMEBACK). Physical therapy. 2019;99(1):14–27. doi:10.1093/ptj/pzy112 30247715
45 Thomas JS, France CR, Applegate ME, Leitkam ST, Walkowski S. Feasibility and Safety of a Virtual Reality Dodgeball Intervention for Chronic Low Back Pain: A Randomized Clinical Trial. The journal of pain. 2016;17(12):1302–1317. doi:10.1016/j.jpain.2016.08.011 27616607
46 Monteiro-Junior RS, de Souza CP, Lattari E, . Wii-Workouts on Chronic Pain, Physical Capabilities and Mood of Older Women: A Randomized Controlled Double Blind Trial. CNS & neurological disorders drug targets. 2015;14(9):1157–64.26556092
47 Yoo JH, Kim SE, Lee MG, . The effect of horse simulator riding on visual analogue scale, body composition and trunk strength in the patients with chronic low back pain. International journal of clinical practice. 2014;68(8):941–9. Comment in: Int J Clin Pract. 2014 Aug;68(8):931 PMID: 25074333 [https://www.ncbi.nlm.nih.gov/pubmed/25074333]. doi:10.1111/ijcp.12414 25039929
48 Kim S-S, Min W-K, Kim J-H, Lee B-H. The Effects of VR-based Wii Fit Yoga on Physical Function in Middle-aged Female LBP Patients. Journal of physical therapy science. 2014;26(4):549–52. doi:10.1589/jpts.26.549 24764631
49 Oh HW, Lee MG, Jang JY, . Time-effects of horse simulator exercise on psychophysiological responses in men with chronic low back pain. Isokinetics and Exercise Science. 2014;22(2):153–163. doi:10.3233/IES-140533
50 Mbada CE, Makinde MO, Odole AC, . Comparative effects of clinic- And virtual reality-based McKenzie extension therapy in chronic non-specific low-back pain. Article. Human Movement. 2019;20(3):66–79. doi:10.5114/hm.2019.83998
51 Cetin H, Kose N, Oge HK. Virtual reality and motor control exercises to treat chronic neck pain: A randomized controlled trial. Musculoskeletal science & practice. 2022;62:102636. doi:10.1016/j.msksp.2022.102636 35952621
52 Nusser M, Knapp S, Kramer M, Krischak G. Effects of virtual reality-based neck-specific sensorimotor training in patients with chronic neck pain: A randomized controlled pilot trial. Journal of rehabilitation medicine. 2021;53(2):jrm00151. doi:10.2340/16501977-2786 33369684
53 Tejera DM, Beltran-Alacreu H, Cano-de-la-Cuerda R, . Effects of Virtual Reality versus Exercise on Pain, Functional, Somatosensory and Psychosocial Outcomes in Patients with Non-specific Chronic Neck Pain: A Randomized Clinical Trial. International journal of environmental research and public health. 2020;17(16)doi:10.3390/ijerph17165950
54 Sarig Bahat H, Croft K, Carter C, Hoddinott A, Sprecher E, Treleaven J. Remote kinematic training for patients with chronic neck pain: a randomised controlled trial. European spine journal : official publication of the European Spine Society, the European Spinal Deformity Society, and the European Section of the Cervical Spine Research Society. 2018;27(6):1309–1323. doi:10.1007/s00586-017-5323-0
55 Sarig Bahat H, Takasaki H, Chen X, Bet-Or Y, Treleaven J. Cervical kinematic training with and without interactive VR training for chronic neck pain - a randomized clinical trial. Manual therapy. 2015;20(1):68–78. doi:10.1016/j.math.2014.06.008 25066503
56 I R, M R, S E, S K, A RZ. A Novel Virtual Reality Technique (Cervigame R) Compared to Conventional Proprioceptive Training to Treat Neck Pain: A Randomized Controlled Trial. Journal of biomedical physics & engineering. 2019;9(3):355–366. doi:10.31661/jbpe.v0i0.556 31341881
57 Polat M, Kahveci A, Muci B, Gunendi Z, Kaymak Karatas G. The Effect of Virtual Reality Exercises on Pain, Functionality, Cardiopulmonary Capacity, and Quality of Life in Fibromyalgia Syndrome: A Randomized Controlled Study. Games for health journal. 2021;10(3):165–173. doi:10.1089/g4h.2020.0162 33689452
58 Carvalho MSd, Carvalho LC, Menezes FdS, Frazin A, Gomes EdC, Iunes DH. Effects of Exergames in Women with Fibromyalgia: A Randomized Controlled Study. Games for health journal. 2020;9(5):358–367. doi:10.1089/g4h.2019.0108 32379982
59 Villafaina S, Collado-Mateo D, Dominguez-Munoz FJ, Fuentes-Garcia JP, Gusi N. Benefits of 24-Week Exergame Intervention on Health-Related Quality of Life and Pain in Women with Fibromyalgia: A Single-Blind, Randomized Controlled Trial. Games for health journal. 2019;8(6):380–386. doi:10.1089/g4h.2019.0023 31259617
60 Collado-Mateo D, Dominguez-Munoz FJ, Adsuar JC, Garcia-Gordillo MA, Gusi N. Effects of Exergames on Quality of Life, Pain, and Disease Effect in Women With Fibromyalgia: A Randomized Controlled Trial. Archives of physical medicine and rehabilitation. 2017;98(9):1725–1731. doi:10.1016/j.apmr.2017.02.011 28322760
61 Collado-Mateo D, Dominguez-Munoz FJ, Adsuar JC, Merellano-Navarro E, Gusi N. Exergames for women with fibromyalgia: a randomised controlled trial to evaluate the effects on mobility skills, balance and fear of falling. PeerJ. 2017;5:e3211. doi:10.7717/peerj.3211 28439471
62 Martin-Martinez JP, Villafaina S, Collado-Mateo D, Perez-Gomez J, Gusi N. Effects of 24-week exergame intervention on physical function under single- and dual-task conditions in fibromyalgia: A randomized controlled trial. Scandinavian journal of medicine & science in sports. 2019;29(10):1610–1617. doi:10.1111/sms.13502 31206782
63 Villafaina S, Borrega-Mouquinho Y, Fuentes-Garcia JP, Collado-Mateo D, Gusi N. Effect of Exergame Training and Detraining on Lower-Body Strength, Agility, and Cardiorespiratory Fitness in Women with Fibromyalgia: Single-Blinded Randomized Controlled Trial. International journal of environmental research and public health. 2019;17(1)doi:10.3390/ijerph17010161
64 Garcia-Palacios A, Herrero R, Vizcaino Y, . Integrating virtual reality with activity management for the treatment of fibromyalgia: acceptability and preliminary efficacy. The Clinical journal of pain. 2015;31(6):564–72. doi:10.1097/AJP.0000000000000196 25551475
65 Ozlu A, Unver G, Tuna HI, Menekseoglu AK. The Effect of a Virtual Reality-Mediated Gamified Rehabilitation Program on Pain, Disability, Function, and Balance in Knee Osteoarthritis: A Prospective Randomized Controlled Study. Games for health journal. 2023;12(2):118–124. doi:10.1089/g4h.2022.0130 36603100
66 Elshazly FAA, Nambi GS, Elnegamy TE. Comparative study on virtual reality training (VRT) over sensory motor training (SMT) in unilateral chronic osteoarthritis—A randomized control trial. Int J Med Res Health Sci. 2016;5(8):7–16.
67 Lin Y-T, Lee W-C, Hsieh R-L. Active video games for knee osteoarthritis improve mobility but not WOMAC score: A randomized controlled trial. Annals of physical and rehabilitation medicine. 2020;63(6):458–465. doi:10.1016/j.rehab.2019.11.008 31981832
68 Mete E, Sari Z. The efficacy of exergaming in patients with knee osteoarthritis: A randomized controlled clinical trial. Physiotherapy research international : the journal for researchers and clinicians in physical therapy. 2022;27(3):e1952. doi:10.1002/pri.1952 35470534
69 Nambi G, Abdelbasset WK, Elsayed SH, Khalil MA, Alrawaili SM, Alsubaie SF. Comparative effects of virtual reality training and sensory motor training on bone morphogenic proteins and inflammatory biomarkers in post-traumatic osteoarthritis. Scientific reports. 2020;10(1):15864. doi:10.1038/s41598-020-72587-2 32985509
70 Cuneo A, Yang R, Zhou H, . The Utility of a Novel, Combined Biofeedback-Virtual Reality Device as Add-on Treatment for Chronic Migraine: A Randomized Pilot Study. The Clinical journal of pain. 2023;doi:10.1097/AJP.0000000000001114
71 Chuan A, Hatty M, Shelley M, . Feasibility of virtual reality-delivered pain psychology therapy for cancer-related neuropathic pain: a pilot randomised controlled trial. Anaesthesia. 2023;78(4):449–457. doi:10.1111/anae.15971 36734021
72 Darnall BD, Krishnamurthy P, Tsuei J, Minor JD. Self-Administered Skills-Based Virtual Reality Intervention for Chronic Pain: Randomized Controlled Pilot Study. JMIR formative research. 2020;4(7):e17293. doi:10.2196/17293 32374272
73 Reynolds LM, Cavadino A, Chin S, . The benefits and acceptability of virtual reality interventions for women with metastatic breast cancer in their homes; a pilot randomised trial. BMC cancer. 2022;22(1):360. Comment in: Int J Surg. 2022 Oct;106:106940 PMID: 36152921 [https://www.ncbi.nlm.nih.gov/pubmed/36152921]. doi:10.1186/s12885-021-09081-z 35366823
74 Wankhade S, Phansopkar P, Chitale N. Effect of virtual reality aided physical therapy in adjunct to traditional therapy in frozen shoulder patients. Article. Journal of Medical Pharmaceutical and Allied Sciences. 2022;11(4):5167–5171. doi:10.55522/jmpas.V11I4.1314
75 Ambrosino P, Iannuzzi GL, Formisano R, . Exergaming as an Additional Tool in Rehabilitation of Young Patients with Rheumatoid Arthritis: A Pilot Randomized Controlled Trial. Games for health journal. 2020;9(5):368–375. doi:10.1089/g4h.2019.0167 32315553
76 Gouveia E Silva EC, Lange B, Bacha JMR, Pompeu JE. Effects of the Interactive Videogame Nintendo Wii Sports on Upper Limb Motor Function of Individuals with Post-Polio Syndrome: A Randomized Clinical Trial. Games for health journal. 2020;9(6):461–471. doi:10.1089/g4h.2019.0192 32673102
77 Karahan AY, Tok F, Yildirim P, Ordahan B, Turkoglu G, Sahin N. The Effectiveness of Exergames in Patients with Ankylosing Spondylitis: A Randomized Controlled Trial. Advances in clinical and experimental medicine : official organ Wroclaw Medical University. 2016;25(5):931–936. doi:10.17219/acem/32590 28028958
78 Lewis JS, Newport R, Taylor G, Smith M, McCabe CS. Visual illusions modulate body perception disturbance and pain in Complex Regional Pain Syndrome: A randomized trial. European journal of pain (London, England). 2021;25(7):1551–1563. doi:10.1002/ejp.1766 33759278
79 Rothgangel A, Braun S, Winkens B, Beurskens A, Smeets R. Traditional and augmented reality mirror therapy for patients with chronic phantom limb pain (PACT study): results of a three-group, multicentre single-blind randomized controlled trial. Clinical rehabilitation. 2018;32(12):1591–1608. doi:10.1177/0269215518785948 30012007
80 Fascio E, Vitale JA, Sirtori P, Peretti G, Banfi G, Mangiavini L. Early Virtual-Reality-Based Home Rehabilitation after Total Hip Arthroplasty: A Randomized Controlled Trial. Article. Journal of Clinical Medicine. 2022;11(7)1766. doi:10.3390/jcm11071766 35407373
81 Ditchburn J-L, van Schaik P, Dixon J, MacSween A, Martin D. The effects of exergaming on pain, postural control, technology acceptance and flow experience in older people with chronic musculoskeletal pain: a randomised controlled trial. BMC sports science, medicine & rehabilitation. 2020;12:63. doi:10.1186/s13102-020-00211-x
82 Fuchs L, Kluska A, Novak D, Kosashvili Y. The influence of early virtual reality intervention on pain, anxiety, and function following primary total knee arthroplasty. Complementary therapies in clinical practice. 2022;49:101687. doi:10.1016/j.ctcp.2022.101687 36347152
83 Jin C, Feng Y, Ni Y, Shan Z. Virtual reality intervention in postoperative rehabilitation after total knee arthroplasty: A prospective and randomized controlled clinical trial. International Journal of Clinical and Experimental Medicine. 2018;11(6):6119–6124.
84 Eichler S, Salzwedel A, Rabe S, . The effectiveness of telerehabilitation as a supplement to rehabilitation in patients after total knee or hip replacement: randomized controlled trial. JMIR rehabilitation and assistive technologies. 2019;6(2):e14236.31697239
85 Janhunen M, Katajapuu N, Paloneva J, . Effects of a home-based, exergaming intervention on physical function and pain after total knee replacement in older adults: a randomised controlled trial. BMJ open sport & exercise medicine. 2023;9(1):e001416. doi:10.1136/bmjsem-2022-001416
86 Piqueras M, Marco E, Coll M, . Effectiveness of an interactive virtual telerehabilitation system in patients after total knee arthoplasty: a randomized controlled trial. Journal of rehabilitation medicine. 2013;45(4):392–396.23474735
87 Prvu Bettger J, Green CL, Holmes DN, . Effects of Virtual Exercise Rehabilitation In-Home Therapy Compared with Traditional Care After Total Knee Arthroplasty: VERITAS, a Randomized Controlled Trial. The Journal of bone and joint surgery American volume. 2020;102(2):101–109. doi:10.2106/JBJS.19.00695 31743238
88 Shim GY, Kim EH, Lee SJ, . Postoperative rehabilitation using a digital healthcare system in patients with total knee arthroplasty: a randomized controlled trial. Article. Archives of Orthopaedic and Trauma Surgery. 2023;doi:10.1007/s00402-023-04894-y
89 Golubnitschaja O, Liskova A, Koklesova L, . Caution, “normal” BMI: health risks associated with potentially masked individual underweight-EPMA Position Paper 2021. The EPMA journal. 2021;12(3):243–264. doi:10.1007/s13167-021-00251-4 34422142
90 Bahat HS, German D, Palomo G, Gold H, Nir YF. Self-Kinematic Training for Flight-Associated Neck Pain: a Randomized Controlled Trial. Aerospace medicine and human performance. 2020;91(10):790–797. doi:10.3357/AMHP.5546.2020 33187565
91 Abd-Elsayed A, Hussain N, Stanley G. Combining Virtual Reality and Behavioral Health to Promote Pain Resiliency: Analysis of a Novel BioPsychoSocial Modality for Solving Pain in the Workplace. Pain and therapy. 2021;10(2):1731–1740. doi:10.1007/s40122-021-00333-1 34657235
92 Rodriguez-Hernandez M, Criado-Alvarez J-J, Corregidor-Sanchez A-I, Martin-Conty JL, Mohedano-Moriano A, Polonio-Lopez B. Effects of Virtual Reality-Based Therapy on Quality of Life of Patients with Subacute Stroke: A Three-Month Follow-Up Randomized Controlled Trial. International journal of environmental research and public health. 2021;18(6)doi:10.3390/ijerph18062810
93 Rodríguez-Hernández M, Polonio-López B, Corregidor-Sánchez AI, Martín-Conty JL, Mohedano-Moriano A, Criado-Álvarez JJ. Can specific virtual reality combined with conventional rehabilitation improve poststroke hand motor function? A randomized clinical trial. Article. Journal of NeuroEngineering and Rehabilitation. 2023;20(1)38. doi:10.1186/s12984-023-01170-3 37016408
94 Taveggia G, Borboni A, Salvi L, . Efficacy of robot-assisted rehabilitation for the functional recovery of the upper limb in post-stroke patients: a randomized controlled study. European journal of physical and rehabilitation medicine. 2016;52(6):767–773.27406879
95 Ossmy O, Mukamel R. Using Virtual Reality to Transfer Motor Skill Knowledge from One Hand to Another. Journal of visualized experiments : JoVE. 2017;(127)doi:10.3791/55965
96 Rodriguez-Hernandez M, Polonio-Lopez B, Corregidor-Sanchez AI, Martin-Conty JL, Mohedano-Moriano A, Criado-Alvarez JJ. Effects of Specific Virtual Reality-Based Therapy for the Rehabilitation of the Upper Limb Motor Function Post-Ictus: Randomized Controlled Trial. Brain Sci. Apr 28 2021;11(5)doi:10.3390/brainsci11050555
97 Soler MD, Kumru H, Pelayo R, . Effectiveness of transcranial direct current stimulation and visual illusion on neuropathic pain in spinal cord injury. Brain : a journal of neurology. 2010;133(9):2565–77. doi:10.1093/brain/awq184 20685806
98 Morkisch NJ, Katrin; dos Santos, Luara Ferreira; Dohle, Christian. Modelling of therapeutic action during mirror therapy: A qualitative analysis as basis for technical solutions. Current Directions in Biomedical Engineering. 2017;3(No.1):45–48. doi:10.1515/cdbme-2017-0010
99 Moseley LG, Gallace A, Spence C. Is mirror therapy all it is cracked up to be? Current evidence and future directions. Pain. Aug 15 2008;138(1):7–10. doi:10.1016/j.pain.2008.06.026 18621484
100 Dy M, Olazo K, Lyles CR, . Usability and acceptability of virtual reality for chronic pain management among diverse patients in a safety-net setting: a qualitative analysis. JAMIA Open. Oct 2023;6(3):ooad050. doi:10.1093/jamiaopen/ooad050 37449058
101 Jones C, Miguel Cruz A, Smith-MacDonald L, Brown MRG, Vermetten E, Bremault-Phillips S. Technology Acceptance and Usability of a Virtual Reality Intervention for Military Members and Veterans With Posttraumatic Stress Disorder: Mixed Methods Unified Theory of Acceptance and Use of Technology Study. JMIR Form Res. Apr 21 2022;6(4):e33681. doi:10.2196/33681 35451971
102 Sagnier C L-EE, Lourdeaux D, Thouvenin I, Valléry G. User Acceptance of Virtual Reality: An Extended Technology Acceptance Model. International Journal of Human-Computer Interaction. 06 Jan 2020 2020;36(11):993–1007. doi:10.1080/10447318.2019.1708612
103 Allen EN, Chandler CI, Mandimika N, Leisegang C, Barnes K. Eliciting adverse effects data from participants in clinical trials. Cochrane Database Syst Rev. Jan 16 2018;1(1):MR000039. doi:10.1002/14651858.MR000039.pub2 29372930
104 Stanney K, Fidopiastis C, Foster L. Virtual Reality Is Sexist: But It Does Not Have to Be. Front Robot AI. 2020;7:4. doi:10.3389/frobt.2020.00004 33501173
105 Baker NA, Polhemus AH, Haan Ospina E, . The State of Science in the Use of Virtual Reality in the Treatment of Acute and Chronic Pain: A Systematic Scoping Review. The Clinical journal of pain. 2022;38(6):424–441. doi:10.1097/AJP.0000000000001029 35537072
106 Hayden JA, Ellis J, Ogilvie R, Malmivaara A, van Tulder MW. Exercise therapy for chronic low back pain. Cochrane Database Syst Rev. Sep 28 2021;9(9):CD009790. doi:10.1002/14651858.CD009790.pub2 34580864
107 Richmond H, Hall AM, Copsey B, . The Effectiveness of Cognitive Behavioural Treatment for Non-Specific Low Back Pain: A Systematic Review and Meta-Analysis. PLoS One. 2015;10(8):e0134192. doi:10.1371/journal.pone.0134192 26244668
108 Khoo EL, Small R, Cheng W, . Comparative evaluation of group-based mindfulness-based stress reduction and cognitive behavioural therapy for the treatment and management of chronic pain: A systematic review and network meta-analysis. Evid Based Ment Health. Feb 2019;22(1):26–35. doi:10.1136/ebmental-2018-300062 30705039
109 Heapy AA, Higgins DM, Goulet JL, . Interactive Voice Response-Based Self-management for Chronic Back Pain: The COPES Noninferiority Randomized Trial. JAMA Intern Med. Jun 1 2017;177(6):765–773. doi:10.1001/jamainternmed.2017.0223 28384682
110 Wells SY, Morland LA, Hurst S, . Veterans’ reasons for dropping out of prolonged exposure therapy across three delivery modalities: A qualitative examination. Psychol Serv. Aug 2023;20(3):483–495. doi:10.1037/ser0000714 36326662
111 Ankawi B, Piette, J.D., Buta, E. . Adherence to Daily Interactive Voice Response Calls for a Chronic Pain Intervention. Journal of Technology in Behavioral Science. 2022;(7):343–350. doi:10.1007/s41347-022-00254-6
112 Meis LA, Noorbaloochi S, Hagel Campbell EM, . Sticking it out in trauma-focused treatment for PTSD: It takes a village. J Consult Clin Psychol. Mar 2019;87(3):246–256. doi:10.1037/ccp0000386 30777776
113 Murphy JL, Cordova MJ, Dedert EA. Cognitive behavioral therapy for chronic pain in veterans: Evidence for clinical effectiveness in a model program. Psychol Serv. Feb 2022;19(1):95–102. doi:10.1037/ser0000506
114 Beehler GP, Loughran TA, King PR, . Patients’ perspectives of brief cognitive behavioral therapy for chronic pain: Treatment satisfaction, perceived utility, and global assessment of change. Fam Syst Health. Jun 2021;39(2):351–357. doi:10.1037/fsh0000606 34410777
115 Damschroder LJ, Aron DC, Keith RE, Kirsh SR, Alexander JA, Lowery JC. Fostering implementation of health services research findings into practice: a consolidated framework for advancing implementation science. Implement Sci. Aug 7 2009;4:50. doi:10.1186/1748-5908-4-50 19664226
116 Damschroder LJ, Hagedorn HJ. A guiding framework and approach for implementation research in substance use disorders treatment. Psychol Addict Behav. Jun 2011;25(2):194–205. doi:10.1037/a0022284 21443291
117 Birckhead B, Khalil C, Liu X, . Recommendations for Methodology of Virtual Reality Clinical Trials in Health Care by an International Working Group: Iterative Study. JMIR Ment Health. Jan 31 2019;6(1):e11973. doi:10.2196/11973 30702436
118 Brassel S, Power E, Campbell A, Brunner M, Togher L. Recommendations for the Design and Implementation of Virtual Reality for Acquired Brain Injury Rehabilitation: Systematic Review. J Med Internet Res. Jul 30 2021;23(7):e26344. doi:10.2196/26344 34328434
119 Becker WC, Dorflinger L, Edmond SN, Islam L, Heapy AA, Fraenkel L. Barriers and facilitators to use of non-pharmacological treatments in chronic pain. BMC Fam Pract. Mar 20 2017;18(1):41. doi:10.1186/s12875-017-0608-2 28320337
120 Sarig Bahat H, Hadar D, Treleaven J. Predictors for Positive Response to Home Kinematic Training in Chronic Neck Pain. Journal of manipulative and physiological therapeutics. 2020;43(8):779–790. doi:10.1016/j.jmpt.2019.12.008 32829943
121 Chin S, Cavadino A, Akroyd A, . An Investigation of Virtual Reality Nature Experiences in Patients With Metastatic Breast Cancer: Secondary Analysis of a Randomized Controlled Trial. JMIR cancer. 2022;8(3):e38300. doi:10.2196/38300 35867398
122 Tsai L, Milburn PA, Cecil CLt, Lowry PS, Hermans MR. Comparison of Recurrence and Postoperative Complications Between 3 Different Techniques for Surgical Repair of Idiopathic Hydrocele. Urology. 2019;125:239–242. doi:10.1016/j.urology.2018.12.004 30552941