# ACKNOWLEDGMENTS

The authors are grateful to external peer reviewers and the following individuals for their contributions to this project:

## Operational Partners

Operational partners are system-level stakeholders who help ensure relevance of the review topic to the VA, contribute to the development of and approve final project scope and timeframe for completion, provide feedback on the draft report, and provide consultation on strategies for dissemination of the report to the field and relevant groups.

- Anne Lord Bailey, PharmD, BCPS
  Executive Director, VA Strategic Initiatives Lab
  VA Immersive Lead, VA Office of Healthcare Innovation and Learning

- Friedhelm Sandbrink, MD
  Executive Director
  National Pain Management, Opioid Safety and PDMP (PMOP)

- Jennifer L Murphy, PhD
  Director of Pain Management
  National Pain Management, Opioid Safety and PDMP (PMOP)

- David Atkins, MD, MPH
  Former Director
  VA Health Services Research and Development (HSR&D)

- Jessica Cleveland, MSOR
  AAAS Science & Technology Policy Fellow
  VA Health Services Research and Development (HSR&D)

## Technical Expert Panel

To ensure robust, scientifically relevant work, the technical expert panel (TEP) guides topic refinement; provides input on key questions and eligibility criteria, advising on substantive issues or possibly overlooked areas of research; assures VA relevance; and provides feedback on work in progress. TEP members included:

- Thiru Annaswamy, MD, MA
  Professor and Chair, Physical Medicine & Rehabilitation
  Penn State College of Medicine

- Jeremy Bailenson, PhD
  Professor of Communication, Education, and Program in Symbolic Systems
  Director, Virtual Human Interaction Lab
  Stanford University

- Albert ‘Skip’ Rizzo, PhD
  Research Professor, Schools of Gerontology and Medicine
  Director for Medical Virtual Reality
  University of Southern California - Davis