# CONCLUSIONS

Evidence on benefits and harms of XR interventions to treat or prevent chronic pain is limited due to methodological concerns, small study size, and lack of reporting on adverse events. XR physical activity interventions may have benefits for some conditions (eg, chronic neck pain) but the evidence is very uncertain for others (eg, chronic low back pain and post-surgical pain and rehabilitation). XR psychological skills interventions may also have some benefit for chronic low back pain, but studies did not compare to analogous non-XR treatments. Future work is needed to better understand how and by what mechanisms XR interventions may impact pain outcomes, particularly in more diverse populations and settings. Larger studies and application of implementation frameworks are important next steps for advancing this field.