# DISCUSSION

In summary, trials most commonly evaluated XR interventions involving physical activity, and most often compared XR to standard, non-XR exercise interventions or conventional rehabilitation. XR physical activity interventions appear to have benefit for some conditions (eg, chronic neck pain), but the evidence is very uncertain for others (eg, chronic low back pain). XR psychological skills interventions were also evaluated for several different conditions, most often compared to a variety of non-active interventions, including usual care or VR sham. VR psychological skills may have some benefit for chronic low back pain, but these interventions were not compared with active treatments. While pain-related functioning and pain intensity were well reported by included studies, adverse events were not frequently addressed, and when reported, focused mostly on the XR group.

## Summary of Key Findings

### Chronic Low Back Pain (KQ1)

- 6 studies evaluated different types of VR interventions for chronic low back pain, with variable comparators (VR sham, usual care); only 1 VR study reported on adverse events (15% experienced VR-associated dizziness).
- The effect of VR embodiment (compared with either non-VR physical therapy or VR sham) on pain-related functioning and pain intensity is very uncertain (very low COE).
- VR psychological skills, compared with VR control or usual care, may result in greater improvement in pain-related functioning and pain intensity (low COE), but the evidence on adverse events is very uncertain (very low COE).
- All 16 AR studies evaluated AR physical activity interventions, compared most often with non-AR physical activity (k = 10); only 2 studies addressed adverse events, with both reporting no events detected.
- The effects of AR physical activity (compared with non-AR physical activity, medications, or usual care) on pain-related functioning, pain intensity, and adverse events are very uncertain (very low COE).

### Neck Pain (KQ1)

- 6 trials evaluated XR physical activity interventions (5 VR, 1 AR) for chronic neck pain, all compared with non-XR physical activity programs.
- VR physical activity interventions, compared with non-VR physical activity, may result in little to no difference in pain-related functioning at 3-6 weeks (low COE) and the evidence is very uncertain for effects at 3-4 months (very low COE); for pain intensity, VR physical activity interventions may result in greater improvement at 3-6 weeks but little to no difference at 3-4 months (low COE).
- AR physical activity intervention, compared with non-AR physical activity, may improve pain-related functioning and reduce pain intensity (low COE).
- The evidence is very uncertain on adverse effects of XR physical activity interventions for neck pain (very low COE); 5 studies evaluated adverse events, but 3 only reported events for the XR group and 2 studies did not detect events in either group.

### Fibromyalgia (KQ1)

- 5 trials evaluated AR interventions for fibromyalgia, with 4 of these being physical activity programs using Wii or Kinect; no trial reported on adverse events.
- The effects of AR physical activity interventions (compared with either non-AR physical activity or usual care) on pain-related functioning and pain intensity are very uncertain (very low COE).
- The effect of AR-enhanced CBT, compared with usual care, on pain-related functioning is very uncertain (very low COE).

### Chronic Knee Pain (KQ1)

- 5 trials evaluated XR physical activity interventions (1 VR, 4 AR) for chronic knee pain, all compared with non-XR rehabilitation programs; only 1 trial reported on adverse events.
- A VR physical activity intervention may result in better pain-related functioning and less pain at 7 weeks, compared with standard rehabilitation (low COE).
- The effects of AR interventions (compared with standard rehabilitation) on pain-related functioning, pain intensity, and adverse events are very uncertain (very low COE).

### Post-Surgical Pain & Rehabilitation (KQ2)

- 7 trials evaluated XR physical activity interventions (2 VR, 5 AR) for rehabilitation after knee or hip replacement surgery, all compared with non-XR standard rehabilitation; only 1 trial reported on adverse events.
- The effects of XR physical activity interventions (compared with standard rehabilitation) on pain-related functioning, pain intensity, and adverse events are very uncertain (very low COE).

### Other Conditions (KQ1 & KQ2)

- 15 studies evaluated a range of XR interventions (7 VR, 8 AR) for a variety of other pain conditions; these were all small (total n = 36-75), half were physical activity interventions (k = 8), and a quarter were psychological skills programs (k = 4).

## Limitations

Defining and separating VR and AR interventions can be challenging, and existing frameworks for XR technologies sometimes differ in where boundaries are drawn. Although most previous systematic reviews of XR interventions for pain did not stratify results by level of immersion, we sought to operationalize the distinction between full immersion (ie, VR) and partially immersive experiences (ie, AR) in order to provide greater clarity on benefits and harms. To ensure we addressed a broad range of clinically relevant XR interventions, we included some AR interventions that many would consider minimally immersive. We also categorized XR intervention types into broad categories that led to grouping together interventions with varying schedules, durations, and content. We limited eligibility to English-language studies, and thus did not include or review non-English studies.

## EVIDENCE GAPS & FUTURE RESEARCH

The evidence on XR interventions for chronic pain is hampered by serious methodological concerns (half of eligible studies were rated high for RoB) and by the small size of most study samples. Three-quarters of ongoing (or recently completed) trials on XR interventions for chronic pain were also quite small, with expected total n < 100. Due to concerns regarding the limits of randomization to achieve balance in very small trials (with respect to baseline measures and unmeasured confounding), we elected to calculate the between-group differences in change scores (Diff ∆), instead of directly comparing follow-up scores. Although we undertook this strategy to provide the most informative interpretation of study findings, this approach cannot eliminate risks of bias that would be successfully addressed by randomization in sufficiently large trials. The preponderance of small pilot studies using convenience samples is consistent with the early state of the science in the emerging field of XR interventions for pain care.

XR can be a means of delivery of a range of clinical interventions and types of therapies. To identify the highest-value contributions of XR to pain care, future research is needed to clarify how VR and AR may improve pain outcomes, including the mechanisms by which XR technologies may enhance the benefits of specific types of pain therapies. For the most part, included studies were not designed to address this question, often because XR interventions were not compared with analogous non-XR intervention types. For example, while several XR psychological skills interventions used fully immersive VR technology, only 1 of these studies used a non-XR psychological skills comparator, so it remains unclear what additional benefits or harms may be attributable to XR technology. In contrast, while many XR physical activity interventions were compared to non-XR physical activity, many of these evaluated less immersive AR devices, and none compared VR and AR interventions to better understand the relative effects of higher levels of immersion. In some cases, it may be more straightforward to envision how immersion may contribute to the key mechanism of a pain therapy. For example, AR embodiment could help participants imagine a movable limb (in place of an amputation) in a real-world setting, leading to less phantom limb pain. Even in this case, however, there is a lack of studies demonstrating added value of XR technology when compared to established interventions using analogous mechanisms (eg, conventional mirror therapy).^97–99^ We found 1 small eligible study comparing AR mirror therapy with conventional mirror therapy for phantom limb pain, which showed that conventional mirror therapy had greater effects on primary outcomes than AR mirror therapy.^79^

One commonly proposed general mechanism for XR benefits is increased patient engagement with varying interventions. To understand whether patient engagement is affected positively or negatively by different forms of XR technology, it would be important to evaluate patient engagement (including adherence and patient experience) in comparing XR interventions with the analogous non-XR interventions. Current evidence also does not address XR technology acceptance across diverse patient populations or evaluate how this may impact intervention effects. Although indicators of patient XR acceptance and experience were beyond the scope of this review, we notably found few studies evaluating XR interventions for older adults with conditions such as chronic low back pain and neck pain that are highly prevalent in older age groups. This is an important gap given potentially greater barriers in technology literacy and acceptance in older adults, although early qualitative studies suggest that barriers to technology use and acceptance may be overestimated among some older adults with chronic pain.^100^ It may also be important to apply conceptual frameworks for assessing technology acceptance for XR interventions to better understand how this contributes to patient experience and uptake of interventions.^101,102^ Future work will need to evaluate acceptance of XR technology among diverse populations, investigate associated intervention engagement and adherence, and examine outcomes and implementation resources for populations that have high prevalence of chronic pain conditions but may face greater barriers—internal or external—to technology adoption.

Included studies rarely evaluated adverse events using rigorous methods that allowed for direct comparisons between XR and non-XR interventions. This is a critical gap to address in future research, as adverse events are an important component of the patient experience and often impact whether someone will start or continue an intervention. At a minimum, adverse events should be assessed systematically and reported for each arm, and involve participant interviews with open-ended questions and/or checklists.^103^ In addition to information on whether the adverse event led to discontinuation of the treatment, studies should report the rates of serious adverse events (usually defined as events that are life-threatening, requiring hospitalization, or resulting in persistent disability). Accurate observation of serious adverse event rates will also require substantially larger studies. Furthermore, it will be important to examine whether adverse events for XR interventions vary for different subgroups of patients, such as by sex or gender. For example, there is some evidence that VR-related nausea and motion sickness are more common among women than men, and that this may be driven by greater incompatibility of many VR devices with the observed range of interpupillary distances among women.^104^

Intervention dose and duration varied widely across included studies, as has also been noted by previous reviews of XR interventions for pain.^105^ Minimal effective dose and duration are likely to vary by intervention type and mechanism. Distraction, for example, may have temporary effects that do not require multiple frequent sessions,^105^ while the benefits of physical activity accumulate over repeated sessions. Overall, XR interventions lasted from several weeks to several months, with studies often not providing the rationale for length, number, frequency, or duration of XR sessions. Studies of some analogous non-XR interventions also have similar limitations; for example, past reviews have found similar dose and duration variability among non-XR physical activity therapies for chronic pain.^106^ Non-XR psychological skills interventions for chronic pain also vary in dose and duration, although there are many examples of effective low-intensity low-cost interventions.^107–109^ Future studies on XR psychological skills interventions should consider applying methods developed for analogous non-XR psychological interventions to provide critical information on minimum effective dose and duration, and the impact of participant adherence on these values.^110–114^

Limited understanding of XR’s impacts on pain therapy mechanisms and intervention adherence also makes it difficult to differentiate when XR is a key active component of the therapeutic intervention versus enhancing the effects of another therapy (eg, by increasing engagement). This distinction between core intervention components and modifiable peripheral components is fundamental to implementation science, making implementation science frameworks potentially helpful even in this early phase of XR pain research.^115,116^ As is often true when incorporating new technologies into various existing interventions, there will likely be situations in which XR technology acts more as a core component of the intervention itself, and cases in which XR technology augments the effects of an intervention as an implementation strategy. Intentionally designing hybrid implementation-effectiveness studies as part of the research continuum may help clarify XR contributions earlier and in more pragmatically applicable ways.

Use of XR interventions in clinical settings is also particularly dependent on implementation contexts, making implementation research key to effective rollout for XR interventions with demonstrated benefits. Existing recommendations for XR research have focused on content development through user centered-design, early testing for feasibility and acceptability, and design of clinical trials to demonstrate efficacy.^117^ Although some recommendations for implementation exist in patient populations such as brain injury,^118^ further work using implementation science frameworks is needed to identify how best to integrate XR technologies into the clinical space and optimize pain outcomes. Clinicians often have a wide range of interest and experience in using XR technologies, as patients do, and substantial facility investment may be required for clinician training. Remote or home use of XR interventions for self-management, particularly with clinician support, may also provide meaningful benefits. Employing an implementation science framework (eg, RE-AIM) during development phases and beyond could speed the translation of XR technologies to the end user. Although cost considerations were beyond the scope of this review, an evaluation of resources needed for XR treatments for pain should consider both the cost of treatments themselves (particularly compared with analogous non-XR therapies) and what is needed for successful implementation (eg, staff training materials and time, logistical support for distributing XR devices to patients). As VHA has begun to pilot XR interventions across different clinical settings, including the use of RelieVRx in outpatient treatment of chronic low back pain,^14^ these implementation and hybrid evaluations should be considered as important next steps for understanding the real-world effectiveness and value of these interventions.

In summary, XR technology has considerable potential as part of a comprehensive plan for pain treatment. Given possibilities for home use and remote monitoring, and the increasing affordability of some XR technologies, XR interventions may address some common patient barriers to access and use of non-drug therapies for pain.^119^ But it remains unclear how and under which circumstances XR adds the most benefit and the least risks for pain treatments. Evaluating benefits and risks in generalizable ways will require larger studies that include more diverse populations (particularly those who may experience more barriers to technology use, such as older adults and rural populations). Additionally, future work should compare XR interventions to analogous non-XR intervention types; investigate mechanisms and added value of XR technology; systematically evaluate adverse events; and examine participant experiences, including attitudes toward XR, as well as barriers and facilitators of access and use.