# RESULTS

## LITERATURE FLOW DIAGRAM

The literature flow diagram summarizes the results of the study selection process. A full list of excluded studies is provided in Appendix B.

Abbreviations. CINAHL=Cumulative Index to Nursing and Allied Health Literature; ISRCTN=International Standard Randomised Controlled Trial Number; US=United States.

## OVERVIEW OF INCLUDED STUDIES

We screened 10,933 unique citations and reviewed the full text for 362. We identified 71 eligible articles reporting 60 unique primary studies: 49 studies (58 articles) that addressed KQ1 and 11 studies (13 articles) for KQ2. Table 1 provides summary characteristics for all eligible studies. Most studies assessed pain-related functioning or interference (k = 43) and pain intensity or severity (k = 53). In contrast, few reported on adverse events (k = 15), and of these, most did not systematically assess adverse effects for all study arms. Half of studies were very small (k = 30 with total n ≤ 50), and only 4 studies had total n > 100. Most studies were conducted outside of the US (k = 54), and most included young and middle-aged adult participants (k = 46). All studies were rated high or some concerns for RoB, with half being high RoB (k = 30). Detailed RoB ratings for all articles are provided in Appendix D. We also identified 47 ongoing or recently completed studies (Appendix C). Four of the ongoing studies have planned n > 250; 3 of these are currently recruiting (NCT04933474, NCT05005026, and NCT049067643), and the fourth has since published results during the drafting of this report (NCT05263037).^23^

Among KQ1 studies evaluating XR interventions for treatment of chronic pain, most addressed low back pain (k = 22), and fewer examined chronic neck pain (k = 6), fibromyalgia (k = 5), and chronic knee pain (k = 5). There were also a variety of other chronic pain conditions with only 1 eligible study (eg, headache or phantom limb pain). Most KQ1 studies evaluated AR interventions (k = 32), and physical activity was the most common type of XR intervention (k = 36; Table 1; Figure 1).

Eleven KQ2 studies examined XR interventions for the prevention of chronic pain, with 7 of these addressing post-surgical pain and rehabilitation. Nearly all post-surgical studies involved XR physical activity interventions (k = 6; Table 1; Figure 1). The remaining 4 studies included 2 RCTs on AR physical activity interventions for post-stroke pain and rehabilitation, 1 RCT on AR physical activity for flight-associated neck pain (both acute and chronic), and 1 cohort study on VR psychological skills intervention for pain from work-related injuries.

Below, we first describe findings for KQ1 studies, grouped by VR and AR interventions within each pain condition. We then briefly present characteristics and findings of single studies for a variety of KQ1 conditions, including those with mixed populations or general chronic pain (eg, chronic pain in ≥2 joints). Next, we describe results for post-surgical pain and rehabilitation (KQ2), grouped similarly by VR and AR interventions. Finally, we present the findings for the 4 KQ2 studies on a variety of conditions. Within sections on chronic low back pain, chronic neck pain, fibromyalgia, chronic knee pain, and post-surgical pain, we also provide COE ratings.

Table 1 Overview of Characteristics for Included Studies

| Characteristics | Chronic Low Back Pain; (k = 22) | Chronic Neck Pain; (k = 6) | Fibromyalgia; (k = 5) | Chronic Knee Pain; (k = 5) | KQ1 Other Conditions^*^; (k = 11) | Post-Surgical; (k = 7) | KQ2 Other Conditions^†^; (k = 4)
XR Technology | Virtual reality (VR) | 6 | 5 | - | 1 | 5 | 2 | 2
XR Technology | Augmented reality (AR) | 16 | 1 | 5 | 4 | 6 | 5 | 2
Type of XR Intervention | Engage & guide in physical activity | 16 | 6 | 4 | 5 | 5 | 6 | 3
Type of XR Intervention | Pain psychology & coping skills | 3 | - | 1 | - | 3 | - | 1
Type of XR Intervention | Embodiment only | 3 | - | - | - | 2 | - | -
Type of XR Intervention | Distraction only | - | - | - | - | 1 | 1 | -
Outcomes Reported | Pain-related functioning or interference | 14 | 5 | 5 | 4 | 8 | 6 | 1
Outcomes Reported | Pain intensity or severity | 21 | 6 | 3 | 5 | 9 | 6 | 3
Outcomes Reported | Adverse events | 3 | 4 | - | 1 | 5 | 1 | 1
Outcomes Reported | Pain catastrophizing & kinesiophobia | 11 | 3 | - | - | 2 | - | -
Outcomes Reported | Pain global change | 2 | 1 | - | - | 2 | - | -
Outcomes Reported | Quality of life | 4 | 1 | 4 | 2 | 4 | 3 | 2
Outcomes Reported | Physical performance | 4 | 6 | 5 | 4 | 3 | 6 | 3
Outcomes Reported | Opioid dose/use | 2 | - | - | - | 1 | - | -
Sample Size | 30-50 | 13 | 5 | 2 | - | 7 | - | 3
Sample Size | 51-100 | 8 | 1 | 3 | 5 | 4 | 4 | 1
Sample Size | 101-200 | 1 | - | - | - | - | 2 | -
Sample Size | >200 | - | - | - | - | - | 1 | -
Country | USA | 2 | - | - | - | 2 | 1 | 1
Country | Europe | 4 | 2 | 3 | 2 | 5 | 3 | 2
Country | Middle East | 5 | 2 | 1 | 2 | - | 1 | 1
Country | Asia | 6 | - | - | 1 | 1 | 2 | -
Country | Australia/New Zealand | 2 | 2 | - | - | 2 | - | -
Country | Others^ǂ^ | 3 | - | 1 | - | 1 | - | -
Follow-Up Duration | 7-30 days | 7 | 1 | - | - | 3 | - | -
Follow-Up Duration | 31-90 days | 7 | 2 | 4 | 4 | 4 | 4 | 2
Follow-Up Duration | >90 days | 8 | 3 | 1 | 1 | 4 | 3 | 2
Mean/Median Age | <30 | 9 | - | - | 1 | 1 | - | 1
Mean/Median Age | 30-64 | 11 | 6 | 4 | 4 | 7 | 1 | 1
Mean/Median Age | 65+ | 1 | - | - | - | 1 | 5 | 2
Mean/Median Age | NR | 1 | - | 1 | - | 2 | 1 | -

* Includes 1 study each on the following conditions: headache/migraine, cancer-related neuropathic pain, musculoskeletal pain in ≥2 joints, pain related to metastatic breast cancer, complex regional pain syndrome, post-polio syndrome, rheumatoid arthritis, phantom limb pain, ankylosing spondylitis, frozen shoulder, & back pain + fibromyalgia

† Includes 2 studies on participants post-stroke, 1 study on flight-related neck pain (acute and chronic), & 1 on those work-related injury

ǂ Includes 3 studies from Brazil and 2 studies from Nigeria

Figure 1 Studies Evaluating Various XR Intervention Types for Pain Conditions

## CHRONIC LOW BACK PAIN (KQ1)

We identified 22 trials evaluating the use of VR (k = 6) or AR (k = 16) interventions for chronic low back pain. VR interventions were either primarily embodiment or psychological skills. In contrast, all AR interventions involved engagement and guidance in physical activity. There was variation in definitions of chronic low back pain, with the minimal duration ranging 2-6 months and not specified in some studies. Below, we first describe findings for VR interventions, and then results for AR studies. Detailed trial characteristics and findings are found in Appendix E.

### VR Intervention Trials

Three studies evaluated VR embodiment,^24–26^ and 3 examined VR psychological skills interventions for chronic low back pain.^27–33^ Study characteristics and findings for VR interventions are summarized in Table 2. The largest study examined the efficacy of a VR psychological skills intervention (RelieVRx); it was conducted in the US and included 188 middle-aged participants (mean age 51 years), mostly women (67-78%). The remaining 5 studies were all small (total n = 30-46), included middle-aged women and men, and occurred outside the US. Below, we first describe results from studies evaluating VR embodiment, and then present findings for the VR psychological skills interventions.

#### VR Embodiment Interventions

The evidence is very uncertain on the effect of VR embodiment on pain-related functioning and pain intensity compared with conventional therapy (very low COE; Table 3), based on results from a single study. Yilmaz Yelvar, 2016^25^ compared VR embodiment in addition to conventional therapy (n = 23) with conventional therapy alone (n = 23). The VR arm used iPods with video glasses for passive viewing of a virtual walking video clip. The study was rated as high RoB due to concerns about randomization, adherence to the intervention, measurement of outcomes, and the selection of reported results. Pain-related functioning was assessed with Oswestry Disability Index (ODI) at baseline and 2-week follow-up, with both groups improving at 2 weeks and little difference between groups (Diff ∆ = 1.2; baseline mean ODI scores were 20.7 in VR group and 26.1 in the control group). Pain intensity was measured using a Visual Analog Scale (VAS) at baseline and 2 weeks, with the VR group having greater improvement at 2 weeks (Diff ∆ = −2.8; baseline mean VAS scores were 6.0 in VR group and 5.6 in the control group). Similarly, there were greater improvements at 2 weeks in the VR group in quality of life, assessed with the Nottingham Health Profile (NHP), with Diff ∆ of −12.5 (baseline mean NHP scores were 226 in VR group and 158 in the control group). VR group also had greater improvements in physical performance tests, including 6-minute walk and timed up and go (TUG). For example, the VR group had greater increases in distance for the 6-minute walk at 2 weeks (Diff ∆ = 91.0 m, baseline mean 414.3 m in VR group and 401.1 m in the control group). Kinesiophobia was measured using the Tampa Scale of Kinesiophobia (TSK), but the authors did not report follow-up scores for the control group. Yilmaz Yelvar, 2016^25^ did not report on adverse events.

Table 2 Summary of Findings for VR Interventions for Chronic Low Back Pain

Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting/Duration | Comparator; N Randomized (N Analyzed); Setting/Duration | Outcomes
Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting/Duration | Comparator; N Randomized (N Analyzed); Setting/Duration | Pain-Related Functioning or Interference | Pain Intensity or Severity | Pain Catastrophizing & Kinesiophobia | Adverse Events & Other Eligible Outcomes
VR Embodiment vs Physical Therapy
Yilmaz Yelvar, 2016^25^; High; Turkey | LBP > 2 mo and no surgical treatments for disc herniation, spina bifida, or spinal stenosis; mean ages 46-53 yr, 46%-82% female | Viewing a virtual walking clip using iPod with video glasses, conventional therapy (hot pack, TENS, deep heat with ultrasound, and therapeutic exercises); N = 23 (22); Clinic; 2 wk | Conventional therapy (hot pack, TENS, deep heat with ultrasound, and therapeutic exercises); N = 23 (22); Clinic; 2 wk | ODI; Baseline means (SD):; Intervention: 20.7 (7.2); Comparator: 26.1 (11.0); Diff ∆ (2 wk): 1.2^*^ | VAS; Baseline means (SD); Intervention: 6.0 (1.1); Comparator: 5.6 (2.4); Diff ∆ (2 wk): −2.8^*^ | TSK; Baseline means (SD); Intervention: 43.7 (4.3); Comparator 1: 40.4 (5.6); Diff ∆ (2 wk): NC | NR; Quality of life (2 wk); Nottingham Health Profile; Physical performance (2 wk); TUG; 6MWT
VR Embodiment vs VR Other
Harvie, 2022^24^; Some concerns; Australia | LBP ≥ 6 mo; mean ages 52-57 yr, 45%-50% female | Games using Oculus Rift S, participants embodied a boxer, superhero, and rock climber; N = 20 (20); Clinic; 1 wk | Relaxing experiences using Oculus Rift S (eg, building a sandcastle, standing at beach); N = 10 (10); Clinic; 1 wk | NR | NRS; Baseline means (CI)^†^:; Intervention: 6.4 (5.8, 7.0); Comparator: 6.6 (4.9, 8.2); Diff ∆ (1 wk): 0.5^*^ | Photograph Series of Daily Activities; Baseline (and follow-up) scores; NR^‡^ | NR; Pain global change (1 wk); PGIC
Kammler-Sücker, 2023^26^; Some concerns; Germany | Back pain > 6 mo, excluding acute causes of back pain, neurological complications, or contraindication to exercise; mean ages 46-52 yr, 56%-71% female | Perform activities, movements guided by virtual doppelganger avatar in immersive environment (projections on 4 walls); N = 17 (17); Clinic; 4-117 days (3 sessions) | Perform activities, movements guided by a videotaped model, 2D projection on only 1 wall of same immersive environment; N = 16 (16); Clinic; 4-117 days (3 sessions) | NRS (limitations due to pain); Baseline means (SD):; Intervention: 2.7 (2.0); Comparator: 1.7 (1.8); Diff ∆ (session 2-session 1, mean 14 days): −0.7^*^; Diff ∆ (session 3-session 1, mean 27 days): −0.4^*^ | NRS (pain intensity); Baseline means (SD):; Intervention: 2.6 (1.1); Comparator: 1.9 (1.6); Diff D (session 2-session 1, mean 14 days): −0.4^*^; Diff ∆ (session 3-session 1, mean 27 days): −0.02^*^ | NR | NR; NR
VR Psychological Skills
Eccleston, 2022^27^; Some concerns; Finland | LBP ≥ 3 mo, with average pain intensity ≥ 4/10 over past week on NRS; mean ages 53-57 yr, 82-100% female | DTxP—using Oculus Quest headsets for program of 24 progressive modules informed by cognitive behavioral therapy; N = 14 (14); Home; 6-8 wk | Using Oculus Quest headsets for seaside virtual environment; N = 17 (17); Home; 6-8 wk | ODI; Baseline means (SD):; DTxP: 36.0 (7.6); VR control: 37.2 (9.4); Usual care: 36.2 (7.6); Diff ∆^*^ (DTxP-VR control):; 8 wk: −8.5^*^; Diff ∆^*^ (DTxP-usual care):; 8 wk: −3.8; PROMIS pain interference; Baseline means (SD):; DTxP: 64.5 (3.7); VR control: 63.1 (3.4); Usual care: 63.1 (2.5); Diff ∆^*^ (DTxP-VR control):; 8 wk: −5.0; Diff ∆^*^ (DTxP-usual care):; 8 wk:−3.3 | NRS; Baseline means (SD); DTxP: 6.0 (1.4); VR control: 6.1 (1.4); Usual care: 5.7 (1.6); Diff ∆^*^ (DTxP-VR control):; 8 wk: −0.6; Diff ∆^*^ (DTxP-usual care):; 8 wk: −0.6^*^; PROMIS pain intensity; Baseline means (SD); DTxP: 66.5 (4.1); VR control: 65.1 (5.4); Usual care: 63.0 (5.5); Diff ∆^*^ (DTxP-VR control):; 8 wk: −3.3; Diff ∆^*^ (DTxP-usual care):; 8 wk: −4.5 | TSK; Baseline means (SD); DTxP: 41.9 (4.4); VR control: 43.2 (6.0); Usual care: 42.5 (5.4); Diff ∆^*^ (DTxP-VR control):; 8-wk: −8.1; Diff ∆^*^ (DTxP-usual care):; 8 wk: −5.5 | Severe AE:; DTxP: 50%; VR control: 29%; Usual care: 36%; Any treatment-related AE:; DTxP: 25%; VR control: 35%; Usual care: 18%; No serious AE in any group; Quality of life (8 wk); EuroQoL-5D-5L; Pain Global Change (8 wk, 5 mo); PGIC
Eccleston, 2022^27^; Some concerns; Finland | LBP ≥ 3 mo, with average pain intensity ≥ 4/10 over past week on NRS; mean ages 53-57 yr, 82-100% female | DTxP—using Oculus Quest headsets for program of 24 progressive modules informed by cognitive behavioral therapy; N = 14 (14); Home; 6-8 wk | Usual care; N = 11 (11); NA; NA | | | TSK; Baseline means (SD); DTxP: 41.9 (4.4); VR control: 43.2 (6.0); Usual care: 42.5 (5.4); Diff ∆^*^ (DTxP-VR control):; 8-wk: −8.1; Diff ∆^*^ (DTxP-usual care):; 8 wk: −5.5
Maddox, 2022^32^; Maddox, 2023^33^; Garcia, 2021^29^; Garcia,2022a^30^; Garcia, 2022b^31^; Some concerns; USA | LBP ≥ 6 mo, average pain intensity ≥4/10 for past month; mean age 51 yr, 67-78% female | RelieVRx—using Pico G2 4K headset for a progressive series of modules to provide pain neuroscience education, mindfulness exercises, and biofeedback; N = 94 (89); Home; 8 wk | Rotation of 20 nature videos, displayed in 2D in Pico G2 4K headset; N = 94 (90); Home; 8 wk | DVPRS-overall interference; Baseline means (SD); Intervention: 4.8 (NR); Comparator: 5.1 (NR); Diff ∆^*^:; 20 mo: −0.7; 26 mo: −0.7 | DVPRS-pain intensity; Baseline means (SD); Intervention: 5.1 (1.2); Comparator: 5.2 (1.1); Diff ∆^*^:; 20 mo: −1.0; 26 mo: −0.5 | NR | NR; NR
Groenveld, 2023^28^; Some concerns; Netherlands | LBP ≥ 3 mo, average pain score ≥ 4/10 scale in the week preceding enrollment, no current treatment other than PT or medications, no invasive treatment in the past year; mean age 51-52 yr, 83% female | Using Oculus Go for pain education program consisting of 5 games based on psychotherapy principles (eg, acceptance and commitment therapy, mindfulness); N = 20 (20); Home; 4 wk | Wait-list control; N = 21 (20); NA; NA | BPI-Interference; Baseline means (SD):; Intervention: 5.9 (1.7); Comparator: 6.3 (2.0); Diff ∆^*^:; 4 wk: −0.3; 4 mo: −0.2; ODI; Baseline means (SD):; Intervention: 40.1 (19.1); Comparator: 42.8 (18.1); Diff D^*^:; 4 wk: −3.7; 4 mo: −0.9 | VAS-worst pain; Baseline means (SD):; Intervention: 6.1 (NR); Comparator: 7.0 (NR); Diff ∆^*^:; 30 days: −0.6; VAS-least pain; Baseline means (SD); Intervention: 3.7 (NR); Comparator: 4.1 (NR); Diff ∆^*^:; 30 days: −0.4 | PCS; Baseline means (SD):; Intervention:21.7 (12.2); Comparator 1: 24.7 (7.8); Diff ∆^*^:; 4 wk: 0.7; 4 mo: −0.2 | Dizziness reported for VR group only: 15%; Quality of life (4 wk, 4 mo); SF-12 physical; SF-12 mental; Opioid use (1, 4 wk); Using at least weekly

Notes.

* Diff ∆ calculated by review team.

† Data abstracted from graphs using Plotdigitizer.

‡ No scores were reported and assessment only completed by 16 of 30 (53%) participants.

Abbreviations. 2D=2 dimensional; 6MWT=6-minute walk test; AE=adverse event; BPI=Brief Pain Inventory; CI=confidence interval; Diff ∆= Difference between groups of mean change scores; DVPRS=Defense and Veterans Pain Rating Scale; LBP=lower back pain; mo=month; NC=not calculable; NR=not reported; NRS=Numeric Rating Scale; ODI=Oswestry Disability Index; PCS=Pain Catastrophizing Scale; PGIC=Pain Global Impression of Change scale; PROMIS=Patient-Reported Outcomes Measurement Information System; PT=physical therapy; SF-12=Short Form Health Survey-12; SD=standard deviation; TENS=transcutaneous electrical nerve stimulation; TSK=Tampa Scale of Kinesiophobia; TUG=timed up and go; VAS=Visual Analogue Scale; wk=week; yr=year.

Table 3 Certainty of Evidence: VR Embodiment versus Conventional Therapy for Chronic Low Back Pain

Outcome; Outcome Measure(s) | Follow-Up; # of Participants and Studies | Anticipated Absolute Effects on Mean Change (∆) | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-Up; # of Participants and Studies | VR Embodiment | Conventional Therapy | Diff. ∆ | Certainty | What Happens
Pain-Related Functioning or Interference; ODI | 2 weeks; N = 46; 1 RCT^25^ | −3.8 | −5.1 | 1.2 | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR-embodiment on pain-related functioning, compared with conventional therapy.
Pain Intensity or Severity; VAS | 2 weeks; N = 46; 1 RCT^25^ | −3.5 | −0.7 | −2.8 | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR-embodiment on pain intensity, compared with conventional therapy.

Notes. GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 2 levels for study limitations (study rated high for risk of bias).

b Downgraded 1 level for indirectness (age in study not generalizable to back pain population).

Abbreviations. CI=confidence interval; Diff. ∆=difference in mean change scores; ODI=Oswestry Disability Index; RCT=randomized controlled trial; VAS=Visual Analog Scale; VR=virtual reality.

The evidence is also very uncertain on the effect of VR embodiment on pain-related functioning and pain intensity, compared with other VR experiences (very low COE; Table 3), based on results from 2 studies.^24,26^ Neither study reported findings on adverse events. The first study, Kammler-Sücker, 2023,^26^ compared the effect of using a virtual doppelganger avatar to guide participants in various activities in a fully immersive environment (n = 17) with a videotaped model performing the same activities and projected on 1 wall of the immersive environment (n = 16). Outcomes were assessed during each of 3 sessions for both groups (occurring over 4-117 days). This study was rated as some concerns for RoB due to concerns about randomization methods and measurement of the outcomes. Pain-related interference was assessed with a Numeric Rating Scale (NRS) 0-10 for how much participants were limited in movements by their pain (10 = “complete incapability”), with both groups having similar reductions comparing session 3 with session 1 (Diff ∆ = −0.4, session 1 mean NRS scores were 2.7 in VR embodiment group and 1.7 in the VR other group). Similarly, there were no differences between groups in pain intensity, as assessed with NRS for pain during movement comparing session 3 with session 1 (Diff ∆ = −0.02, session 1 mean NRS scores were 2.6 in VR embodiment group and 1.9 in the VR other group).

In the second study, Harvie, 2022^24^ used Oculus Rift S to create visual experiences and activities consistent with a boxer, superhero, or rock climber (ie, embodiment, n = 20), and compared this with vacation experiences (eg, standing at a beach) also using Oculus Rift S (n = 10). This study was rated as some concerns for RoB due to concerns about randomization methods and measurement of the outcomes. Harvie, 2022^24^ did not evaluate pain-related functioning or adverse events. Average pain intensity over the past week was assessed using NRS, measured at baseline and 1-week follow-up; both VR groups had very slight improvements in pain intensity (Diff ∆ = 0.5; baseline mean NRS scores were 6.4 in VR group and 6.6 in the control group).^24^ At 1-week follow-up, Pain Global Impression of Change (PGIC) was also assessed, with the VR-embodiment arm having greater proportion reporting at least minimal improvement (37% vs 11% for VR control), but also slightly more with minimal worsening (5% vs 0% for VR control). Fear of movement was assessed using Photograph Series of Daily Activities, which participants rated perceived harmfulness from 0-100; however, these assessments were only completed by 53% of participants and no baseline or follow-up scores were reported.

Table 4 Certainty of Evidence: VR Embodiment versus VR Other for Chronic Low Back Pain

Outcome; Outcome Measure(s) | Follow-Up; # of Participants and Studies | Anticipated Absolute Effects on Mean Change (∆) | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-Up; # of Participants and Studies | VR Embodiment | VR Other | Diff. ∆ | Certainty | What Happens
Pain-Related Functioning or Interference; NRS | 27 days; N = 30; 1 RCT^26^ | −0.4 | 0.0 | −0.4 | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain on the effect of VR embodiment on pain-related functioning compared to VR control.
Pain Intensity or Severity; NRS | 1 wk – 27 days; N = 63; 2 RCTs^24,26^ | −0.1^*^ | −0.1^*^ | −0.02 * | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain on the effect of VR embodiment on pain intensity compared to VR control.

Notes.

* Values for mean change in VR embodiment, VR other, and Diff. ∆ taken from Kammler-Sucker.^26^

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 1 level for study limitations (studies rated some concerns for risk of bias).

b Downgraded 1 level for indirectness (age in study not generalizable to back pain population).

c Downgraded 1 level for imprecision (SDs large relative to means).

Abbreviations. CI=confidence interval; Diff. ∆=difference in mean change scores; NRS=Numeric Rating Scale; RCT=randomized controlled trial; VR=virtual reality; wk=week.

#### VR Psychological Skills Intervention Trials

VR psychological skills, compared to VR control or usual care, may result in better pain-related functioning and greater reductions in pain intensity (low COE), but the evidence on adverse effects is very uncertain (very low COE; Table 5). Three studies (reported in 7 articles^27–33^) evaluated VR psychological skills, compared with either VR control or usual care. VR psychological skills interventions occurred over 4-8 weeks and participants were predominantly middle-aged women. The range of follow-up was 2-26 months. Maddox, 2022^29,31–34^ evaluated a psychological skills program involving progressive modules on pain neuroscience education, mindfulness, and biofeedback (RelieVRx; n = 94) against a VR control of 20 2D nature videos, shown in the same Pico G2 4K headsets (n = 94). Eccleston, 2022^27^ compared a VR program involving 24 modules and 30 unique sessions (n = 14), with a VR control of a relaxing seaside in the same Oculus Quest headsets (n = 17) and usual care (n = 11). Finally, Groenveld, 2023^28^ evaluated a VR psychological skills program of 5 games informed by psychotherapy principles (n = 20) against a wait-list control (n = 21). These studies were all rated some concerns for RoB, due to concerns regarding adherence to the intervention and/or outcome measurement. All studies assessed pain-related functioning and pain intensity, 2 studies examined pain catastrophizing or kinesiophobia, and 2 reported on adverse events.

##### Pain-Related Functioning or Interference

A variety of measures were used to assess pain-related functioning or interference, including the Defense and Veterans Pain Rating Scale (DVPRS), ODI, the Brief Pain Inventory (BPI) interference subscale, and the Patient Reported Outcomes Measurement Information System (PROMIS) pain interference measure. Overall, there was greater improvement in the VR psychological skills group, although some of the between-group differences were quite small (Diff ∆ range = −0.2 to −8.5 on various scales). In the study with the longest follow-up, the Diff ∆ at both 20 and 26 months was −0.7, as assessed with DVPRS-overall interference (baseline mean scores were 4.8 for VR psychological skills and 5.1 for VR control).^32,33^

##### Pain Intensity or Severity

Similarly, the VR psychological skills group had greater improvement in pain intensity, but also with a large range in Diff ∆ (−0.4 to −4.5, on various scales). There appeared to be sustained effects of VR psychological skills, with greater reductions in pain intensity still at 20 and 26 months (Diff ∆ of −1.0 and −0.5 at 20 and 26 months, using the DVPRS-pain intensity subscale; baseline mean scores were 5.1 for VR psychological skills and 5.2 for VR control).^32,33^ Other measures of pain intensity included the NRS and PROMIS pain intensity,^27^ and daily worst and least pain VAS.^28^

##### Adverse Events

Eccleston, 2022^27^ reported a range of adverse events, finding for example that severe adverse events (defined as symptoms leading to inability to perform daily or work activities) were relatively common: 50% of participants experienced any severe events in the VR psychological skills group, 29% in VR control, and 36% in usual care. No serious adverse events (defined as any event leading to death or serious deterioration in health) were reported in any group.^27^ Groenveld, 2023^28^ only assessed for dizziness in the VR psychological skills group, reporting 3 participants (15%) had dizziness but none discontinued the intervention due to symptoms.

##### Pain Catastrophizing and Kinesiophobia

Two studies assessed pain catastrophizing or kinesiophobia, showing inconsistent results. Eccleston, 2022^27^ used TSK to assess kinesiophobia and found that the VR psychological skills group had greater reductions, compared to VR control (Diff ∆ −8.1) or usual care (Diff ∆ −5.5); baseline mean scores were 41.9 for VR psychological skills, 43.2 for VR control, and 42.5 for usual care. In contrast, Groenveld, 2023^28^ used the Pain Catastrophizing Scale (PCS) and found that this worsened for all groups, with slightly greater catastrophizing in the VR psychological skills group at 4 weeks (Diff ∆ 0.7) and slightly worse scores in usual care group at 4 months (Diff ∆ −0.2); baseline mean PCS scores were 21.7 for VR psychological skills and 24.7 for usual care group).

##### Other Outcomes

Eccleston, 2022^27^ assessed the European Quality of Life 5-dimension, 5-level scale (EuroQoL-5D), but only reported domain scores (no index score given). Groenveld, 2023^28^ also evaluated quality of life, using instead the 12-item Short Form Survey (SF-12). SF-12 physical component scores improved somewhat for both groups, with little difference between groups (Diff ∆ −0.3 at 4 months, baseline mean scores were 34.9 for VR psychological skills and 32.9 for usual care), but SF-12 mental component score improved more for the usual care group (Diff ∆ −2.4 at 4 months, baseline mean scores were 45.6 for VR psychological skills and 43.0 for usual care).^28^

Eccleston, 2022^27^ assessed global improvement using PGIC, reporting mean scores at 8 weeks and 5 months (VR psychological skills and VR control only at the later time point). There were no differences between groups at 5 months (mean score 3.0 for both VR psychological skills and VR control), and somewhat worse for the VR psychological skills group at 8 weeks (mean score 2.7 for VR psychological skills, 3.8 for VR control, and 3.9 for usual care).^27^

Groenveld, 2023^28^ evaluated the proportion of participants reporting use of opioids at least weekly, finding that the VR psychological skills group had fewer participants using opioids at 4 weeks compared with at 1 week (28% vs 47%), while no change was found in the usual care group (37% at both time points).

Table 5 Certainty of Evidence: VR Psychological Skills versus VR Control or Usual Care for Chronic Low Back Pain

Outcome; Outcome Measure(s) | Follow-Up; # of Participants and Studies | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-Up; # of Participants and Studies | VR Psychological Skills | Comparator | Difference | Certainty | What Happens
Pain-Related Functioning or Interference; BPI; ODI; DVPRS; PROMIS | 1–26 mo; N = 271; 3 RCTs^27,28,33^ | −2.0^*^ | −1.3^*^ | Diff ∆: −0.7 * | ⨁⨁◯◯; Low^a,b^ | VR psychological skills may result in better pain-related functioning, compared to VR control or usual care.
Pain Intensity or Severity; DVPRS; NRS; PROMIS; VAS; | 1–26 mo; N = 271; 3 RCTs^27,28,33^ | −1.2^*^ | −0.7^*^ | Diff ∆: −0.5 * | ⨁⨁◯◯; Low^a,b^ | VR psychological skills may result in decreased pain intensity, compared to VR control or usual care.
Adverse Events; Severe Adverse Events | 2–8 wk; N = 83; 2 RCTs^27,28^ | 50%^†^ | 32%^†^ | 18 % more ^†^ | ⨁◯◯◯; Very low^a,c^ | The evidence is very uncertain about the effect of VR psychological skills on adverse events, compared to VR control or usual care.

Notes.

* Mean change in DVPRS for each group from baseline to for 26 mo, as reported in Maddox, 2023^32^ and Diff. ∆ calculated by review team.

† Proportion with severe adverse event (symptoms leading to inability to perform daily or work activities) in each group at 8 weeks as reported in Eccleston, 2022^27^ and differences between groups calculated by review team.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded 1 level for study limitations (study rated some concerns for risk of bias).

b Downgraded 1 level for indirectness (women overrepresented in study population, 67-100%).

c Downgraded 2 levels for indirectness (women overrepresented; adverse event data only reported for one arm in 1 study).

Abbreviation. BPI=Brief Pain Inventory; CI=confidence interval; Diff. ∆=difference in mean change scores; DVPRS=Defense and Veterans Pain Rating Scale; mo=month; no.=number; ODI=Oswestry Disability Index; PROMIS=Patient-Reported Outcomes Measurement Information System; RCT=randomized controlled trial; VR=virtual reality; wk=week.

### AR Interventions for Back Pain

Sixteen studies evaluated AR interventions for chronic low back pain and all involved guiding and engagement in physical activity.^35–50^ Study characteristics and findings for AR interventions are summarized in Table 6. Below, we first present results from studies evaluating AR physical activity interventions versus active comparators. Then, we summarize findings from trials comparing AR physical activity with usual care.

#### AR Physical Activity versus Active Comparator

Twelve studies compared AR physical activity to non-AR physical activity^35–39,41–43,46,48,50^ or new medications.^40^ All of these studies were small (n = 30-90). Five AR studies used the Nintendo Wii or Microsoft Kinect,^36,39,40,48,50^ and 7 used other devices for AR physical activity.^35,37,38,41,42,43^ ^,46^ Four studies in this latter group were conducted by the same group (lead author Gopal Nambi) and evaluated the Prokin system (TecnoBody); these were all conducted in Saudi Arabia with young male participants.^35,37,41,42^ Other studies were conducted in Korea (k = 2),^43,48^ Nigeria (k = 2),^36,50^ Brazil,^46^ China,^39^ Japan,^40^ and Pakistan.^38^ These studies included a range of young and middle-aged or older adults, and 1 included only women.^48^ Most studies (k = 9) were rated high for RoB, due to concerns about randomization, deviation from the intended intervention, missing outcome data, and/or selective reporting bias. The remaining 4 studies were rated some concerns for RoB.^35,37,38,45^ Six studies evaluated pain-related functioning and most (k = 11) assessed pain intensity. No study reported adverse events.

##### Pain-Related Functioning or Interference

The evidence is very uncertain on the effect of AR physical activity on pain-related functioning or interference, compared with non-AR physical activity (very low COE; Table 7). Six studies assessed pain-related functioning using the ODI, the Modified ODI (MODI), and/or the Roland-Morris Disability Questionnaire (RMDQ).^36,38,39,43,48,50^ Due to lack of reported results on SD of mean change scores, we were unable to conduct meta-analyses. In general, outcomes were assessed post-intervention (2-8 weeks from baseline) and were inconsistent across studies. Some showed that AR physical activity had greater improvement in pain-related functioning (eg, Diff ∆ −1.73^43^ and −9.46^48^), while others found that that the non-AR physical activity group had greater improvement (eg, Diff ∆ 3.68 and 1.23).^36,39^

##### Pain Intensity or Severity

The evidence is also very uncertain on the effect of AR physical activity on pain intensity or severity, compared with non-AR physical activity or medication (very low COE; Table 7). Eleven studies assessed pain intensity using either VAS or NRS.^35,37–43,46,48,50^ We included results from 10 studies that evaluated AR physical activity interventions lasting 4-8 weeks (Figure 2).^35,37,38,40–43,46,48,50^ The pooled estimate indicated AR physical activity had greater reductions in pain intensity but the CI was quite large (standardized Diff ∆ −0.7 [−1.2, −0.2]). Heterogeneity was also substantial. The only study not included in the meta-analysis was a 3-arm trial comparing AR physical activity with non-AR exercises or thermal magnetic therapy, all lasting only 2 weeks.^39^

Table 6 Summary of Findings for AR Interventions for Chronic Low Back Pain

Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting/Duration | Comparator; N Randomized (N Analyzed); Setting/Duration | Outcomes
Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting/Duration | Comparator; N Randomized (N Analyzed); Setting/Duration | Pain-Related Functioning | Pain Intensity/Severity | Pain Catastrophizing & Kinesiophobia | Adverse Events & Other Eligible Outcomes
AR Physical Activity vs Active Comparator
Afzal, 2022^38^; Some concerns; Pakistan | History of chronic LBP, excluding congenital deformity, history of trauma, fracture of spine or lower extremity, systemic or neurologic disease, on steroids or pregnant; mean age 38 yr, 67% women | Sensor enabled games involving various movements (eg, trunk flexion; jumping, arm, leg, head movements); N = 45 (42); Clinic; 4 wk | Conventional physical therapy; N = 45 (42); Clinic; 4 wk | MODI; Baseline means (SD):; Intervention—69.16 (9.13); Comparator—65.08 (8.94); Diff ∆ (4 wk): −28.6^*^ | VAS; Baseline means (SD):; Intervention—6.50 (1.24); Comparator —6.62 (1.04); Diff ∆ (4 wk): −2.2^*^ | NR | NR; NR
Fatoye, 2022^36^; High; Nigeria | LBP ≥ 3 mo, as determined by McKenzie Institute Lumbar Spine Assessment Algorithm; mean ages 48-49 yr, % women NR | Games using Microsoft Kinect where participants headed virtual balls; N = 29 (22); NR; 8 wk | Conventional physical therapy (McKenzie Protocol); N = 28 (24); NR; 8 wk | ODI; Baseline means (SD); Intervention: 14.23 (9.41); Comparator: 21.12 (10.68); Diff ∆ (8 wk): 3.68^*^ | NR | NR | NR; NR
Kim, 2014^48^; High; Republic of Korea | Chronic LBP; mean ages 44-50 yrs, 100% women | 30-minutes of yoga using Nintendo Wii Fit; N = 15 (15); Clinic; 4 wk | Trunk-stabilizing exercises; N = 15 (15); Clinic; 4 wk | ODI; Baseline means (SD):; Intervention: 34.91 (6.19); Comparator: 36.18 (5.02); Diff ∆ (4 wk): −9.46^*^; RMDQ; Baseline means (SD):; Intervention: 18.64 (2.84); Comparator: 19.09 (2.91); Diff ∆ (4 wk): −4.73^*^ | VAS; Baseline means (SD); Intervention: 7.00 (0.89); Comparator: 6.95 (0.79); Diff ∆ (4 wk): −2.41^*^ | FABQ; Baseline means (SD); Intervention: 65.46 (9.64); Comparator : 70.82 (4.58); Diff ∆ (4 wk): −18.73^*^ | NR; NR
Kim, 2020^43^; High; Korea | LBP ≥ mo and average pain intensity ≥4/11 on tNRS, excluding those with serious medical conditions or physical limitations; mean ages 26-29, 32%-58% women | Simulated horseback riding system, consisting of walking, slow trotting, and fast trotting; N = 24 (16); Clinic; 4 wks | Stabilization exercises using Redcord suspension including supine pelvic lift, supine/prone bridging, and side-lying hip abduction; N = 24 (15); Clinic; 4 wks | ODI; Baseline means (SD):; Intervention: 20.24 (7.69); Comparator: 21.77 (7.11); Diff ∆^*^:; 8 wk: −1.73; 6 mo: 0.58; RMDQ; Baseline means (SD):; Intervention: 7.00 (4.40); Comparator: 5.11 (2.74); Diff ∆^*^:; 8 wk: −1.45; 6 mo: −1.81 | NRS; Baseline means (SD):; Intervention: 4.70 (1.04); Comparator: 4.73 (0.82); Diff ∆^*^:; 8 wk: −0.34; 6 mo: 0.23 | FABQ-physical; Baseline means (SD):; Intervention: 15.35 (4.12); Comparator: 11.93 (5.62); Diff ∆^*^:; 8 wk: −5.72; 6 mo:−8.94; FABQ-work; Baseline means (SD):; Intervention: 17.11 (5.33); Comparator: 20.47 (7.89); Diff ∆^*^:; 8 wk: 0.07; 6 mo: 0.71 | NR; NR
Li, 2021^39^; High; China | LBP > 3 mo, excluding those with specific lumbar pathologies, obesity, or other medical conditions; mean ages 22 – 25 yrs, 64%-83% female | Fruit Ninja using Nintendo Wii or game using Microsoft Kinect Xbox where participants wave their hands without moving their trunk; N = 11 (11); Home, clinic; 2 wk | Motor control exercises (MCE), ultrasound-guided abdominal maneuver; N = 12 (12); Home, clinic; 2 wk | ODI; Baseline means (SD); Intervention: 15.65 (6.39); MCE: 18.42 (9.36); CTMT:12.72 (4.84); Diff ∆^*^ (intervention-MCE):; 2 wk: 1.23; Diff ∆^*^ (intervention-CTMT):; 2 wk: 0.28 | VAS; Baseline means (SD); Intervention: 4.36 (1.36); MCE: 4.58 (1.83); CTMT: 3.64 (1.36); Diff ∆^*^ (intervention-MCE):; 2 wk: 1.25; Diff ∆^*^ (intervention-CTMT):; 2 wk: 0.21 | NR | NR; NR
Li, 2021^39^; High; China | LBP > 3 mo, excluding those with specific lumbar pathologies, obesity, or other medical conditions; mean ages 22 – 25 yrs, 64%-83% female | Fruit Ninja using Nintendo Wii or game using Microsoft Kinect Xbox where participants wave their hands without moving their trunk; N = 11 (11); Home, clinic; 2 wk | Conventional thermal magnetic therapy (CTMT); N = 11 (11); Home, clinic; 2 wk | ODI; Baseline means (SD); Intervention: 15.65 (6.39); MCE: 18.42 (9.36); CTMT:12.72 (4.84); Diff ∆^*^ (intervention-MCE):; 2 wk: 1.23; Diff ∆^*^ (intervention-CTMT):; 2 wk: 0.28 | VAS; Baseline means (SD); Intervention: 4.36 (1.36); MCE: 4.58 (1.83); CTMT: 3.64 (1.36); Diff ∆^*^ (intervention-MCE):; 2 wk: 1.25; Diff ∆^*^ (intervention-CTMT):; 2 wk: 0.21 | NR | NR; NR
Mbada, 2019^50^; High; Nigeria | Long-term mechanical LBP and directional preference for extension; mean ages 33-49 yrs, 49%-79% female | Microsoft Kinect game where patients head balls with feet stationary but moving their head and trunk; N = 28 (22); NR; 8 wk | Physical therapy (McKenzie extension protocol in standing); N = 29 (24); NR; 8 wk | ODI; Baseline means (SD):; Intervention: 18.7 (NR); Comparator: 27.8 (NR); Diff ∆ (8 wk): 4.5^*^; RMDQ; Baseline means (SD):; Intervention: 6.8 (4.9); Comparator: 11.3 (4.6); Diff ∆ (8 wk): 1.3^*^ | VAS; Baseline means (SD):; Intervention: 4.1 (1.8); Comparator: 5.0 (1.9); Diff ∆ (8 wk): 0.9^*^ | TSK; Baseline means (SD); Intervention: 16.5 (NR); Comparator: 29.9 (NR); Diff ∆ (8 wk): 23.5^*^; FABQ-physical; Baseline means (SD); Intervention: 21.0 (NR); Comparator: 25.8 (NR); Diff ∆: NC; FABQ-work; Baseline means (SD); Intervention: 21.2 (NR); Comparator: 25.7 (NR); Diff ∆ (8 wk): 6.4^*^ | NR; Quality of life (8 wk); SF-12 mental and physical; Physical performance (8 wk); Biering-Sorensen test of Statis Muscular Endurance (BSME)
Monteiro-Junior, 2015^46^; High; Brazil | Chronic LBP, not participating in a systematic exercise program; mean age 68 yr, 100% women | 8 exercises using Nintendo Wii and Wii Balance Board (eg, tightrope walk, ski slalom, balance bubble, lunge), and core and strength exercises.; N = 17 (14); Clinic; 8 wks | Core and strength exercises; N = 17 (16); Clinic; 8 wks | NR | NRS; Baseline means (SD); Intervention: 6.5 (1.1); Comparator: 6.6 (1.2); Diff ∆ (8 wk): 0.4^*^ | NR | NR; Physical performance (8 wk); Sit-to-stand test
Nambi, 2020a^37^; Some concerns; Saudi Arabia | Male university soccer players aged 18-25 with chronic LBP and pain intensity 4-8 on the VAS; mean age NR | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 15 (15); Home, clinic; 4 wk | Isokinetic dynamometer to perform extension and flexion exercises, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 15 (15); Home, clinic; 4 wk | NR | VAS; Baseline means (SD); Intervention: 7.1 (0.6); Isokinetic dynamometer: 7.3 (0.5); Balance training: 7.3 (0.6); Diff ∆^*^ (intervention-isokinetic dynamometer):; 4 wk: −0.7; 8 wk: −1.3; 6 mo: −0.9; Diff ∆^*^ (intervention-balance training):; 4 wk: −2.1; 8 wk: −4.0; 6 mo: −3.2 | NR | NR; Physical performance (4 wk, 8 wk, 6 mo); 40 m sprint; 4×5 spring; Submaximal shuttle running; Countermovement jump; Squat jump
Nambi, 2020a^37^; Some concerns; Saudi Arabia | Male university soccer players aged 18-25 with chronic LBP and pain intensity 4-8 on the VAS; mean age NR | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 15 (15); Home, clinic; 4 wk | Conventional balance training, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 15 (15); Home, clinic; 4 wk | NR | | NR | NR; Physical performance (4 wk, 8 wk, 6 mo); 40 m sprint; 4×5 spring; Submaximal shuttle running; Countermovement jump; Squat jump
Nambi, 2020b^42^; High; Saudi Arabia | Male university students with chronic LBP ≥ 3 mo and pain intensity 4-8 on the VAS, excluding serious medical conditions or participation in other weight and balance training programs; mean age 23 yr | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 20 (19); Home; 4 wk | Isokinetic dynamometer to perform extension and flexion exercises, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 20 (20); Home; 4 wk | NR | VAS; Baseline means (SD):; Intervention: 7.5 (0.4); Isokinetic dynamometer: −7.3 (0.3); Conventional training: −7.4 (0.4); Diff ∆^*^ (intervention-isokinetic dynamometer):; 4 wk: −0.5; 6 mo: −0.5; Diff ∆^*^ (intervention-conventional training.):; 4 wk: −2.2; 6 mo: −3.0 | TSK; Baseline means (SD):; Intervention: 57.52 (4.8); Conventional training: 58.11 (4.5); Conventional training: 57.93 (4.3); Diff ∆^*^ (intervention-isokinetic dynamometer):; 4 wk: −0.5; 6 mo: −0.5; Diff ∆^*^ (intervention-conventional training.):; 4 wk: −19.4; 6 mo: −18.1 | NR; NR
Nambi, 2020b^42^; High; Saudi Arabia | Male university students with chronic LBP ≥ 3 mo and pain intensity 4-8 on the VAS, excluding serious medical conditions or participation in other weight and balance training programs; mean age 23 yr | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 20 (19); Home; 4 wk | Conventional balance training, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 20 (19); Home; 4 wk | NR | | | NR; NR
Nambi, 2021^41^; High; Saudi Arabia | Male university American soccer players with chronic LBP ≥ 3 mo and pain intensity 4-8 on the VAS, excluding serious medical conditions or participation in other weight and balance training programs; mean ages 21-22 yr | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 18 (18); Home; 4 wk | Isokinetic dynamometer to perform extension and flexion exercises, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 18 (18); Home; 4 wk | NR | VAS; Baseline means (SD); Intervention: 7.8 (0.6); Isokinetic dynamometer: −7.5 (0.5); Conventional training: −7.6 (0.4); Diff ∆^*^ (intervention-isokinetic dynamometer):; 4-wk: −2.1; 6-mo: −2.6; Diff ∆^*^ (intervention-conventional training.):; 4 wk: −2.2; 6 mo: −2.9 | TSK; Baseline means (SD); Intervention: 56.45 (3.2); Isokinetic dynamometer: 58.02 (3.8); Conventional training: 57.68 (4.1); Diff ∆^*^ (intervention-isokinetic dynamometer):; 4-wk: −8.7; 6-mo: −8.0; Diff ∆^*^ (intervention-conventional training.):; 4 wk: −15.9; 6 mo: −17.8 | NR; NR
Nambi, 2021^41^; High; Saudi Arabia | | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 18 (18); Home; 4 wk | Conventional balance training, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 18 (18); Home; 4 wk | NR | | | NR; NR
Nambi, 2022^35^; Some concerns; Saudi Arabia | Male soccer players with chronic LBP ≥ 3 mo and pain score 4-8 on 10 cm VAS; mean age NR | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 20 (19); Clinic; 3 wk | Isokinetic dynamometer to perform extension and flexion exercises, and home-based exercise protocol, hot pack therapy and ultrasound therapy; 20 (19); Clinic; 3 wk | NR | VAS; Baseline means (SD); Intervention: 7.2 (0.4); IKT: 7.3 (0.3); In-person training: 7.2 (0.3); Diff ∆^*^ (intervention-IKT):; 4 wk: −0.6; Diff ∆^*^ (intervention-in-person training):; 4 wk: −3.0 | NR | NR; NR
Nambi, 2022^35^; Some concerns; Saudi Arabia | Male soccer players with chronic LBP ≥ 3 mo and pain score 4-8 on 10 cm VAS; mean age NR | Using the ProKin system, participants control the game by moving their trunk, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 20 (19); Clinic; 3 wk | Conventional balance training, and home-based exercise protocol, hot pack therapy and ultrasound therapy; N = 20 (20); Clinic; 3 wk | NR | VAS; Baseline means (SD); Intervention: 7.2 (0.4); IKT: 7.3 (0.3); In-person training: 7.2 (0.3); Diff ∆^*^ (intervention-IKT):; 4 wk: −0.6; Diff ∆^*^ (intervention-in-person training):; 4 wk: −3.0 | NR | NR; NR
Sato, 2021^40^; High; Japan | LBP ≥ 3 mo, had not responded to conservative treatment; mean age 49 yr, 55% female | Games on Nintendo Wii Fit where participants control the character by jogging and squatting; N = 20 (20); NR; 8 wk | New medications in order: NSAIDS, tramadol, and duloxetine; N = 20 (20); Clinic; 8 wk | NR | VAS; Baseline means (SD); Intervention: RE (1.99); Comparator: 7.01 (0.93); Diff ∆^*^; 8 wk: −2.21 | PCS; Baseline means (SD); Intervention: 43.50 (7.97); Comparator: 40.77 (RE); Diff ∆^*^; 8 wk: −4.95; TSK; Baseline means (SD); Intervention: 42.50 (5.94); Comparator: 38.92 (5.35); Diff ∆^*^; 8 wk: −0.11 | NR; NR
AR Physical Activity vs Usual Care
Oh, 2014^49^; High; Korea | LBP > 3 mo; mean ages 20-21 yr, 100% men | 10 minutes on horse simulator machine daily (10-min HSM); N=10 (10); Clinic; 8 wk | Usual care; N = 9 (9); Clinic; 8 wk | NR | VAS; Baseline means (SD); 10-min HSM: 3.8 (0.5); 20-min HSM: 4.9 (0.5); 30-min HSM: 5.6 (0.7); Usual care: 3.1 (0.6); Diff ∆^*^ (10-min HSM); 8 wk: −3.0; Diff ∆^*^ (20-min HSM); 8 wk: −4.5; Diff ∆^*^ (30-min HSM); 8 wk: −2.8 | NR | NR; NR
Oh, 2014^49^; High; Korea | LBP > 3 mo; mean ages 20-21 yr, 100% men | 20 minutes horse simulator machine daily (20-min HSM); N = 9 (9); Clinic; 8 wk | Usual care; N = 9 (9); Clinic; 8 wk | NR | | NR | NR; NR
Oh, 2014^49^; High; Korea | LBP > 3 mo; mean ages 20-21 yr, 100% men | 30 minutes horse simulator machine daily (30-min HSM); N = 9 (9); Clinic; 8 wk | Usual care; N = 9 (9); Clinic; 8 wk | NR | | NR | NR; NR
Thomas, 2016^45^; Some concerns; US | LBP category 1-3 (Classification System of the Quebec Task Force on Spinal Disorders), excluding recent LBP onset, low kinesiophobia, or on current treatment for LBP; mean ages 24-27 yr, 46% female | Dodgeball game displayed on 60-inch, high definition 3D-TV; N = 27 (26); Clinic; 3 days | Usual care; N = 26 (26); NR; 3 days | RMDQ; Baseline means SD); Intervention: 4.8 (3.0); Comparator: 5.3 (3.9); Diff ∆^*^; 4 days: NC | VAS; Baseline means (SD); Intervention: 21.1 (10.3); Comparator: 25.2 (16.7); Diff ∆^*^; 4 days: NC | TSK; Baseline means (SD); Intervention: 38.9 (4.1); Comparator: 38.3 (4.6); Diff ∆^*^; 4 days: NC | No adverse events in either group; NR
Yoo, 2014^47^; Some concerns; Korea | Young men with LBP > 3 mo, excluding history of neurological, hypertension, cardiopulmonary diseases, chronic disease or spine surgery; mean ages 20-21 yrs | Exercises using a horse simulator machine consisting of a warm-up, workout, and cool-down; N = 24 (24); Clinic; 8 wk | Usual care; N = 23 (23); NA; 8 wk | NR | VAS; Baseline means (SD); Intervention: 4.37 (2.13); Comparator: 1.50 (0.15); Diff ∆^*^; 8 wk: −1.65 | NR | NR; NR
Zadro, 2019^44^; Some concerns; Australia | Mechanical LBP ≥3 mo, excluding serious pathology in the spine, cognitive limitations, high risk of falls; mean ages 68-69 yr, 52% women | Wii Fit U game consisting of flexibility, bodyweight, and aerobic exercises; N = 30 (28); Home; 8 wk | Usual care; N = 30 (30); Home; 8 wk | RMDQ; Baseline means (SD); Intervention: 6.3 (4.8); Comparator: 7.4 (5.2); Diff ∆ (8 wk): −0.4^*^; PSFS; Baseline means (SD); Intervention: 5.3 (1.4); Comparator: 4.3 (2.1); Diff ∆ (8 wk): 0.7^*^ | NRS; Baseline means (SD); Intervention: 5.2 (1.6); Comparator: 4.8 (1.7); Diff ∆ (8 wk): −1.0^*^ | TSK; Baseline means (SD); Intervention: 33.6 (6.1); Comparator: 34.7 (5.8); Diff ∆ (8 wk): −2.5^*^ | No adverse events in either group; NR

Notes.

* Diff ∆ calculated by review team, unable to calculate standardized Diff ∆.

Abbreviations. 3D-TV=3-dimensional television; AEs=adverse event; CI=confidence interval; CLBP=chronic low back pain; CM=centimeter; CTMT=conventional thermal magnetic therapy; Diff ∆ = difference in change scores; FABQ=Fear Avoidance Belief Questionnaire; HSM=horse simulator machine; IKT=isokinetic training; LBP=low back pain; mo=month; MODI=Modified Oswestry Disability Index; NC=not calculable; NR=not reported; NRS=Numeric Rating Scale; NSAIDS=non-steroidal anti-inflammatory drugs; ODI=Oswestry Disability Index; PCS=Pain Catastrophizing Scale; PSFS=Patient Specific Functional Scale; PT=physical therapy; RMDQ=Roland-Morris Disability Questionnaire; RE=reporting error; RoB=risk of bias; SF-12=12-item Short Form health survey; SD=standard deviation; TSK=Tampa Scale of Kinesiophobia; US=United States of America; VAS=Visual Analogue Scale; wk=week; yr=year.

Figure 2 AR Physical Activity versus Active Comparator: Pain Intensity 4-8 Weeks

Table 7 Certainty of Evidence: AR Physical Activity vs. Active Comparators for Chronic Low Back Pain

Outcome; Outcome Measure(s) | Follow-up; No. of Participants (Studies) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-up; No. of Participants (Studies) | AR Physical Activity | Active Comparator | Difference | Certainty | What Happens
Pain-Related Functioning or Interference; ODI; MODI; RMDQ | 2 –8 wk; N = 316; 6 RCTs^36,38,39,43,48,50^ | −53.1^*^ | −24.5^*^ | Diff. ∆: −28.6 * | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain on the effect of AR physical activity on pain-related interference compared to non-AR physical activity.
Pain Intensity or Severity; VAS; NRS | 2–8 wk; N = 552; 11 RCTs^35,37–43,46,48,50^ | −6.9^†^ | −3.3^†^ | Stand. Diff. ∆: −0.7 (−1.2, −0.2) | ⨁◯◯◯; Very low^a,c,d^ | The evidence is very uncertain on the effect of AR physical activity on pain intensity compared to an active comparator.

Notes.

* Values for mean change in AR physical activity, active comparator and Diff. ∆ taken from Afzal, 2022.^38^

† Mean change for active comparator taken from Afzal, 2022^38^, mean change for AR physical activity calculated using pooled estimate for standardized Diff. ∆.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 2 levels for study limitations (studies rated high for risk of bias).

b Downgraded 1 level for inconsistency (direction of effect varied across studies).

c Downgraded 1 level for indirectness (age in study not generalizable to back pain population).

d Downgraded 1 level for inconsistency (high heterogeneity).

Abbreviations. CI=confidence interval; MODI=Modifided Oswestry Disability Index; NRS=Numeric Rating Scale; ODI=Oswestry Disability Index; RCT=randomized controlled trial; RMDQ=Roland-Morris Disability Questionnaire; VAS=Visual Analog Scale; wk=week.

##### Pain Catastrophizing and Kinesiophobia

Six studies evaluated pain catastrophizing or kinesiophobia using the Pain Catastrophizing Scale (PCS), Tampa Scale of Kinesiophobia (TSK), or the Fear Avoidance Beliefs Questionnaire (FABQ).^40–43,48,50^ We were unable to conduct meta-analyses as no study provided SD for mean change. Most studies found that the AR group showed greater reductions (Diff ∆ −0.1 to −18.7),^40–42,48^ while 1 study showed greater improvement in the comparator group (eg, TSK Diff ∆ 23.5)^50^ and another trial reported inconsistent results between FABQ-physical and FABQ-work subscales.^43^

#### AR Physical Activity versus Usual Care

AR physical activity may result in better pain-related functioning (low COE), but the evidence is very uncertain regarding its effects on pain intensity or severity and adverse events, compared with usual care (very low COE; Table 8). Four studies compared AR physical activity to usual care.^44,45,47,49^ Two studies used simulated equine therapy (both conducted in Korea),^47,49^ 1 used Nintendo Wii,^44^ and 1 used a digital dodgeball game.^45^ The latter 2 were conducted in Australia^44^ and the US.^45^ Three studies^44,45,47^ were rated some concerns for RoB due to concerns about randomization, adherence, measurement of outcomes, and/or selected reporting bias. One was rated high RoB^49^ due to similar concerns as the other study and additionally missing outcomes data.

Zadro, 2019^44^ assessed pain-related functioning using the RMDQ and the Patient Specific Functional Scale (PSFS), finding greater improvement in the AR group at 8 weeks (eg, Diff ∆ −0.4 on RMDQ). Three studies provided data on pain intensity, assessed using either VAS^47,49^ or NRS,^44^ and all showed greater reductions in the AR group at 8 weeks (Diff ∆ −1.0 to −4.5). One study reported data on kinesiophobia, assessed with TSK, demonstrating greater improvement in the AR group at 8 weeks (Diff ∆ −2.5).^44^ The fourth study, Thomas, 2016,^45^ did not report mean scores at follow-up after the 3-day intervention (digital dodgeball) but stated that there were no significant differences between groups on pain-related functioning or pain intensity. Two studies reported that no adverse events were detected in either group.^44,45^

Table 8 Certainty of Evidence: AR Physical Activity versus Usual Care for Low Back Pain

Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | AR Physical Activity | Usual Care | Difference | Certainty | What Happens
Pain-Related Functioning or Interference; RMDQ; PSFS | 8 wk; N = 60; 1 RCT^44^ | −1.4^*^ | −1.0^*^ | Diff. ∆: −0.4 * | ⨁⨁◯◯; Low^a,b^ | AR physical activity may result in better pain-related functioning, compared to usual care.
Pain Intensity or Severity; VAS; NRS | 8 wk; N = 144; 3 RCTs^44,47,49^ | −1.4^*^ | −0.4^*^ | Diff. ∆: −1.0 * | ⨁◯◯◯; Very low^c,d^ | The evidence is very uncertain on the effect of AR physical activity on pain intensity compared to usual care.
Adverse Events | 4 days – 8 wk; N = 113; 2 RCTs^44,45^ | 0^†^ | 0^†^ | 0^†^ | ⨁◯◯◯; Very low^a,e,f^ | The evidence is very uncertain on the effect of AR physical activity on adverse events compared to usual care.

Notes.

* Values for mean change in AR physical activity, usual care, and Diff. ∆ taken from Zadro, 2019^44^ (RMDQ for pain-related functioning).

† In both studies, no events reported in either group.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded 1 level for study limitations (study rated some concerns for risk of bias).

b Downgraded 1 level for indirectness (only older adults included).

c Downgraded 2 levels for study limitations (studies rated some concerns or high for risk of bias).

d Downgraded 1 level for indirectness (only older adults or young men included).

e Downgraded 1 level for indirectness (only young or older adults included).

f Downgraded 1 level for imprecision (sample size too small to detect adverse events).

Abbreviations. AR=augmented reality; CI=confidence interval; No.=number; NRS=Numeric Rating Scale; PSFS=Patient Specific Function Scale; RMDQ=Roland-Morris Disability Questionnaire; VAS=Visual Analog Scale.

## CHRONIC NECK PAIN (KQ1)

We identified 6 trials evaluating the use of VR (k = 5)^51–55^ or AR (k = 1)^56^ interventions for chronic neck pain. All interventions involved engagement and guidance in physical activity for 3-6 weeks. Range for total duration of follow-up was 3 weeks to 4 months. Minimum duration of neck pain was specified as 3-6 months in all but a single study.^53^ Study characteristics and findings are summarized in Table 6, and certainty of evidence for efficacy and harms are presented in Table 10 and Table 11. Detailed trial characteristics and findings are found in Appendix E. Below, we first describe findings for VR studies, and then the single AR study.

### VR Interventions Trials

Five trials compared VR interventions with a variety of non-VR physical activity programs for chronic neck pain.^51–55^ VR interventions and comparator programs all encouraged a range of movements at the neck (flexion, extension, rotation). All studies were small (total n range = 36-92) and involved young to middle-aged (mean or median ages 27-53 years) men and women. Studies were conducted in Australia (k = 2),^54,55^ Europe (k = 2),^52,53^ and Turkey.^51^ Three studies were rated some concerns for RoB, primarily related to the potential bias in patient-reported measures when participants are unmasked to the assignment.^53–55^ The remaining 2 studies were rated high RoB due to substantial dropouts and/or individuals removed from the analyses for unclear reasons.^51,52^

#### Pain-Related Functioning or Interference, and Pain Intensity or Severity

All VR trials assessed pain-related functioning and pain intensity immediately post-intervention (3-6 weeks) and 3 studies also provided data at 3 months after the end of the intervention (3-4 months since baseline).^53,54,56^ VR interventions may result in little to no difference in pain-related functioning at 3-6 weeks (low COE; pooled standardized Diff ∆ −0.2 [−0.5, 0.2], Figure 3) and the evidence is very uncertain for effects at 3-4 months (very low COE; pooled standardized Diff ∆ −0.1 [−0.8, 0.5], Figure 4). VR interventions may result in decreased pain intensity at 3-6 weeks (low COE; pooled standardized Diff ∆ −0.5 [−0.8, −0.1], Figure 5), but lead to little to no difference in pain intensity at 3-4 months (low COE; pooled standardized Diff ∆ −0.2 [−0.9, 0.5], Figure 6).

Table 9 Summary of Findings for Chronic Neck Pain

Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Outcomes
Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Pain-Related Functioning | Pain Intensity/Severity | Adverse Events & Other Eligible Outcomes
VR Intervention Trials
Cetin, 2022^51^; High; Turkey | Neck pain ≥ 6 mo, baseline NDI score ≥10, excluding history of cervical spine surgery, rheumatologic, vestibular, neurological, or cardiopulmonary disease, receiving exercise or physical therapy in past 6 mo; mean ages 40-42 yrs, 56% female | Guided movements while watching relaxing videos using Oculus Go VR glasses; N = 21 (17); Clinic; 6 wk | Motor control exercises; N = 20 (17); Clinic; 6 wk | ProFitMap-Neck; Baseline means (SD):; Intervention—69.3 (11.3); Comparator—65.22 (13.9); Diff ∆ (6 wk): −0.17; Stand Diff ∆ (6 wk): −0.01 | VAS; Baseline means (SD):; Intervention—5.77 (1.39); Comparator—5.98 (1.93); Diff ∆ (6 wk): −1.25; Stand Diff ∆ (6 wk): −0.62 | “No adverse effects were observed in either group.”; Quality of life (6 wk); SF-36 – physical (domain scores only); Physical performance (6 wk); ROM measures (flexion, extension, right lateral flexion, left lateral flexion, right rotation, and left rotation)
Nusser, 2021^52^; High; Germany | Non-traumatic neck pain ≥3 mo, excluding history of cervical fracture/dislocation, operations in cervical spine, damage to inner ear, vertebrobasilar insufficiency, neurological disease, ROM <10° in cervical spine; mean ages 50-53 yrs, 68% women | Neck-specific sensorimotor training using VR headset + standard rehabilitation program; N = 17 (17); Clinic; 3 wk | In-person general sensorimotor (SMC) training and standard rehabilitation program; N = 18 (16); Clinic; 3 wk | NDI; Baseline means (SD):; VR—18.7 (5.2); SMC—21.5 (6.4); Control—18.2 (6.7); Diff ∆ (3 wk):; VR-SMC: 0.5^*^; VR-control: −2.8^*^ | VAS; Baseline means (SD):; VR—4.9 (2.1); Sensorimotor—4.4 (3.1); Control—4.2 (2.6); Diff ∆ (3 wk):; VR-SMC: −1.2^*^; VR-control: −1.7^*^ | “Besides the weight of the helmet, which some patients found unpleasant, no other negative side effects were reported regarding the VR device or in general.”; Physical performance (3 wk); ROM (flexion, extension, left rotation, right rotation)
Nusser, 2021^52^; High; Germany | | Neck-specific sensorimotor training using VR headset + standard rehabilitation program; N = 17 (17); Clinic; 3 wk | Standard rehabilitation program; N = 20 (18); Clinic; 3 wk | NDI; Baseline means (SD):; VR—18.7 (5.2); SMC—21.5 (6.4); Control—18.2 (6.7); Diff ∆ (3 wk):; VR-SMC: 0.5^*^; VR-control: −2.8^*^ | VAS; Baseline means (SD):; VR—4.9 (2.1); Sensorimotor—4.4 (3.1); Control—4.2 (2.6); Diff ∆ (3 wk):; VR-SMC: −1.2^*^; VR-control: −1.7^*^
Sarig Bahat, 2014^55^; Some Concerns; Australia | Neck pain >3 mo, NDI >10%, excluding vestibular pathology, cervical fracture or dislocation, neurologic/cardiovascular/respiratory disorders affecting physical performance, history of traumatic head injury, pregnancy; mean age 41 yr, % women NR | Kinematic training using VR headset; N = 16 (14); Clinic, home; 4 mo | Kinematic training using a head-mounted laser pointer; N = 16 (12); Clinic, home; 4 mo | NDI; Baseline means (SD):; Intervention—20.4 (7.6); Control—20.2 (6.5); Diff ∆^*^:; 4 wk: −2.1; 4 mo: −3.5 | VAS; Baseline means (SD):; Intervention—35.7 (17.7); Control—35.2 (16.7); Diff ∆^*^:; 4 wk: −4.9; 4 mo: −0.7 | Motion sickness in 4 participants (25%) VR group only, no assessment of comparator group; Kinesiophobia (5 wk, 4 mo); TSK; Pain global change (4 mo); GPE on pain; Physical performance (4 mo); Cervical ROM; Head movement velocity & accuracy
Sarig Bahat, 2018^54^; Some Concerns; Australia | ≥18 years of age, neck pain for >3 months, NDI score >12%, VAS score >20 mm in the past week | Kinematic training using VR headset; N = 30 (25); Home; 4 mo | Kinematic training using a head-mounted laser pointer; N = 30 (26); Home; 4 mo | NDI; Baseline means (SD):; VR—32.9 (12.5); KT—32.2 (13.3); Control—24.7 (10.7); Diff ∆ (4 wk)^*^:; VR-KT: −4.0; VR-control: −8.0; Diff ∆ (4 mo)^†^:; VR-KT: −2.7 | VAS; Baseline means (SD):; VR KT—47.8 (20.9); KT—52.5 (19.5); Control—45.8 (21.5); Diff ∆ (4 wk)^*^:; VR-KT: −0.2; VR-control: −10.4; Diff ∆ (4 mo)^†^:; VR-KT: −7.3 | “…few cases of side effects from the VR use. 5 [dropouts] were due to VR-associated sickness and headache.”; Kinesiophobia (4 wk); TSK; Physical performance (4 wk); Velocity; Number of velocity peaks,; Time to peak velocity percentage,; Accuracy error; Cervical ROM
Sarig Bahat, 2018^54^; Some Concerns; Australia | ≥18 years of age, neck pain for >3 months, NDI score >12%, VAS score >20 mm in the past week | Kinematic training using VR headset; N = 30 (25); Home; 4 mo | Waitlist control (re-randomized to VR and head-mounted laser training in phase 2); N = 30 (25); N/A; N/A | NDI; Baseline means (SD):; VR—32.9 (12.5); KT—32.2 (13.3); Control—24.7 (10.7); Diff ∆ (4 wk)^*^:; VR-KT: −4.0; VR-control: −8.0; Diff ∆ (4 mo)^†^:; VR-KT: −2.7 | VAS; Baseline means (SD):; VR KT—47.8 (20.9); KT—52.5 (19.5); Control—45.8 (21.5); Diff ∆ (4 wk)^*^:; VR-KT: −0.2; VR-control: −10.4; Diff ∆ (4 mo)^†^:; VR-KT: −7.3
Tejera, 2020^53^; Some Concerns; Spain | Non-specific chronic neck pain, excluding pregnancy, neck pain caused by cancer, infectious or inflammatory disorders, fracture or trauma, positive neurological signs or symptoms, cervical osteoarthritis, spondylarthritis, vertigo, previous cervical surgery, headaches; mean ages 27-33 yrs, 52% female | Progressive head & neck movements using VR Vox Play glasses and smartphone; N = 22 (22); Clinic; 4 mo | In-person neck exercises; N = 22 (22); Clinic; 4 mo | NDI; Baseline means (SD):; Intervention—13.7 (6.7); Comparator—14.1 (9.3); Diff ∆^*^:; 4 wk: −0.2; 4 mo: 0.5 | VAS; Baseline means (SD):; Intervention—5.0 (1.9); Comparator—4.3 (1.4); Diff ∆^*^:; 4 wk: −1.1^*^; 4 mo: −0.3^*^ | NR; Pain catastrophizing & Kinesiophobia; PCS (4 mo); PASS-20 (4 mo); FABQ (4 mo); TSK (4 wk, 4 mo); Physical performance (4 mo); Flexion/extension; Lateroflexion; Rotation
AR Intervention Trials
Rezaei, 2019^56^; Some Concerns; Iran | Non-traumatic neck pain for >3 mo, 10-14 on NDI, excluding cervical or thoracic trauma in past 6 mo, neurological signs or symptoms in upper extremities, nerve injury, cervical spine injury or pathology or surgery; mean ages 31-36 yrs, 43-52% female | Videogame promoting head movements using Head Mouse Extreme; N = 22 (21); Clinic; 9 wk | Conventional proprioceptive training; N = 22 (21); Clinic; 9 wk | NDI; Baseline means (SD):; Intervention—13.0 (1.3); Control—12.3 (1.4); Diff ∆^*^:; 4 wk: −4.3; 9wk: - 5.6 | VAS; Baseline means (SD):; Intervention—47.1 (10.2); Control—39.0 (10.1); Diff ∆^*^:; 4 wk: −17.0; 9 wk: −18.8 | NR; Physical performance; Dynamic balance Y-balance test

Notes.

* Diff ∆ calculated by review team, unable to calculate standardized Diff ∆.

† 4 months data only available including phase 2 participants, where wait-list control was re-randomized and new participants recruited, N = 18 more for VR group, N = 14 more for KT group.

Abbreviations. AR=augmented reality; CI=confidence interval; Diff ∆= difference between groups of mean change scores; FABQ=Fear Avoidance Belief Questionnaire; GPE=Global Perceived Effect scale; hr=hour; KT=kinematic training; mo=month; N/A=not applicable; NDI=Neck Disability Index; NR=not reported; PASS-20=Pain Anxiety Symptom Scale; PCS=Pain Catastrophizing Scale; RoB=risk of bias; ROM=range of motion; SD=standard deviation; SF-36=36-item Short Form health survey; TSK=Tampa Scale of Kinesiophobia; VAS=Visual Analog Scale; VR=virtual reality; wk=week.

Figure 3 VR Physical Activity versus Non-VR Physical Activity: Pain-Related Functioning 3-6 Weeks

Figure 4 VR Physical Activity versus Non-VR Physical Activity: Pain-Related Functioning 3-4 Months

Figure 5 VR Physical Activity versus Non-VR Physical Activity: Pain Intensity 3-6 Weeks

Figure 6 VR Physical Activity versus Non-VR Physical Activity: Pain Intensity 3-4 Months

#### Adverse Events

Although 4 trials reported some information on adverse events, we were unable to conduct a pooled analysis of this outcome due to inconsistencies in how these were assessed and reported. Overall, the evidence is very uncertain about harms due to VR interventions compared with non-VR physical activity (very low COE). One study reported that no adverse effects were observed in either group,^51^ while 1 noted that the helmet weight was “unpleasant” for some participants without providing any counts.^52^ The other 2 studies noted that VR-related motion sickness or headache contributed to dropouts before and after randomization in the VR group, but it was unclear if the comparator groups were also assessed for potential adverse events.^54,55^

Table 10 Certainty of Evidence: VR Physical Activity for Chronic Neck Pain

Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | Anticipated Absolute Effects (95% CI) | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | VR Physical Activity | Non-VR Physical Activity | Difference | Certainty | What Happens
Pain-Related Functioning or Interference; NDI; ProFitMap-Neck | 3-6 weeks; N = 235; 5 RCTs^51–55^ | −8.6^*^ | −6.6^*^ | Stand. Diff ∆: −0.2 (−0.5, 0.2) | ⨁⨁◯◯; Low^a,b^ | VR physical activity may result in little to no difference in pain-related functioning compared to non-VR physical activity.
Pain-Related Functioning or Interference; NDI | 3-4 months; N = 162; 3 RCTs^53,54,56^ | −9.3^*^ | −8.3^*^ | Stand. Diff ∆: −0.1 (−0.8, −0.1) | ⨁◯◯◯; Very low^b,c^ | The evidence is very uncertain on the effect of VR physical activity on pain-related functioning compared to non-VR physical activity.
Pain Intensity or Severity; VAS | 3-6 weeks; N = 235; 5 RCTs^51–55^ | −2.4^*^ | −1.2^*^ | Stand. Diff ∆: −0.5 (−0.8, −0.1) | ⨁⨁◯◯; Low^c^ | VR physical activity may result in decreased pain intensity compared to non-VR physical activity.
Pain Intensity or Severity; VAS | 3-4 months; N = 162; 3 RCTs^53,54,56^ | −3.1^*^ | −2.6^*^ | Stand. Diff ∆: −0.2 (−0.9, 0.5) | ⨁⨁◯◯; Low^a,b^ | VR physical activity may result in little to no difference in pain intensity compared to non-VR physical activity.
Adverse Events | 4 weeks; N = 159; 4 RCTs^51,52,54,55^ | -^†^ | -^†^ | NC ^†^ | ⨁◯◯◯; Very Low^a,d^ | The evidence is very uncertain on the effect of VR physical activity on adverse events compared to non-VR physical activity.

Notes.

* Mean change values for non-VR physical activity taken from Tejera, 2022^53^, mean change for VR physical activity calculated using pooled estimates for standardized Diff. ∆.

† 1 study reported no adverse events in either group; the others only assessed events in the VR group.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 1 level for study limitations (studies rated some concerns for risk of bias).

b Downgraded 1 level for imprecision (PI crosses 0).

c Downgraded 2 levels for study limitations (studies with some concerns and high risk of bias).

d Downgraded 1 level for indirectness (authors only describe events in VR arm, not the control arm).

Abbreviations. CI=confidence interval; Diff ∆=between-group difference in mean change scores (Intervention-Comparator); NC=not calculable; NDI=Neck Disability Index; No.=number; RCT=randomized controlled trial; SD=standard deviation; VAS=Visual Analog Scale; VR=virtual reality.

#### Pain Catastrophizing and Kinesiophobia

Three studies evaluated kinesiophobia, all using TSK.^53–55^ At 3-6 weeks, the pooled standardized Diff ∆ was −0.1 (−0.8, 0.5), indicating little to no difference compared with the non-VR physical activity programs (Figure 7). Similarly, the pooled standardized Diff ∆ at 3-4 months was −0.3 (−1.1, 0.6), indicating little to no difference (Figure 8).

Figure 7 VR Physical Activity versus Non-VR Physical Activity: Kinesiophobia 3-6 Weeks

A Standardized Difference in Change (Stand. Diff ∆)

B Difference in Change (Diff ∆) of Tampa Scale of Kinesiophobia (TSK) Scores

Figure 8 VR Physical Activity versus Non-VR Physical Activity: Kinesiophobia 3-4 Months

A Standardized Difference in Change (Diff ∆)

B Difference in Change (Diff ∆) of Tampa Scale of Kinesiophobia (TSK) Scores

#### Other Eligible Outcomes

Quality of life was evaluated by 1 study using the 36-item Short Form Health Survey (SF-36) but authors did not report the physical and mental component scores (PCS and MCS, respectively).^51^ Scores for the individual domains are provided in the detailed results in Appendix tables. Global perceived effect (GPE) on change was only reported by 1 study,^55^ while physical performance was assessed by all 5 studies using a variety of different measures, including ROM and velocity and accuracy in making certain movements.

### AR Interventions Trials

One trial compared an AR physical activity intervention (n = 21) with conventional exercises (n = 21) for chronic neck pain.^56^ Both physical activity programs lasted 4 weeks. This study was conducted in Iran and included young men and women (mean ages 31-36 years, 43-52% women). This study was rated high RoB due to concerns about allocation concealment, amount and treatment of missing data, and bias in self-reported measures when participants are unmasked to assignment.

Pain-related functioning was assessed using NDI at baseline, 4 weeks (immediately post-intervention), and 9 weeks (5 weeks after completion of the intervention). There was greater improvement in pain-related functioning in the AR group (Diff ∆ −4.3 at 4 weeks, and −5.6 at 9 weeks). Pain intensity was assessed at the same time points using VAS 0-100 mm. The AR group also had greater reductions in pain intensity (Diff ∆ −17.1 at 4 weeks, and −18.7 at 9 weeks). For physical performance, multiple measures from a dynamic Y-balance test were reported at baseline, 4 weeks, and 9 weeks. This study did not evaluate adverse events, quality of life, pain catastrophizing or kinesiophobia, global change in pain, or any of the secondary outcomes.

Table 11 Certainty of Evidence: AR Physical Activity for Chronic Neck Pain

Outcome; Outcome Measure | Follow-up; No. of Participants (Studies) | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure | Follow-up; No. of Participants (Studies) | AR Physical Activity | Non-AR Physical Activity | Diff. ∆ | Certainty | What Happens
Pain-Related Functioning or Interference; NDI | 4-9 weeks; N = 42; 1 RCT^56^ | −8.6 | −3.1 | −5.6 * | ⨁⨁◯◯; Low^a^ | AR physical activity may improve pain-related functioning compared to non-AR physical activity.
Pain Intensity or Severity; VAS | 4-9 weeks; N = 42; 1 RCT^56^ | −37.5 | −18.8 | −18.8 * | ⨁⨁◯◯; Low^a^ | AR physical activity may reduce pain intensity compared to non-AR physical activity.

Notes.

* Calculated by review team.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 2 levels for study limitations (study rated high risk of bias).

Abbreviations. AR=augmented reality; CI=confidence interval; Diff ∆=difference in change scores; NDI=Neck Disability Index; no.=number; RCT=randomized controlled trial; VAS=visual analogue scale.

## FIBROMYALGIA (KQ1)

We identified 5 trials (reported in 8 articles) evaluating the use of XR interventions for fibromyalgia. All were AR interventions: 4 studies compared AR physical activity interventions using Microsoft Kinect or Nintendo Wii with either conventional exercises or usual care,^57–63^ and 1 trial^64^ evaluated AR-enhanced cognitive behavioral therapy (CBT). All trials included only female participants with a confirmed diagnosis of fibromyalgia (according to American College of Rheumatology criteria). All studies reported results for pain-related functioning,^57,58,60,64^ 3 reported findings for pain intensity,^57,59,64^ and no trials addressed adverse events. Study characteristics and findings are summarized in Table 12, and detailed trial characteristics and findings are found in Appendix G. Below, we first describe findings for AR physical activity trials, and then discuss the single trial of AR-enhanced CBT.

### AR Physical Activity Interventions

Of 4 trials on AR physical activity interventions for fibromyalgia, 3 involved exercise programs over 7-8 weeks,^57,58,60,61^ and the fourth lasted 6 months.^59,62,63^ Studies were conducted in Spain (k = 2)^59–63^, Brazil,^58^ and Turkey.^57^ All studies were small with total n range 35-83. Two studies were rated high for RoB,^57,58^ and 2 as some concerns,^59–63^ due to a variety of factors, including concerns about randomization, missing outcomes data, and bias in measurement of outcomes.

#### Pain-Related Functioning or Interference, and Pain Intensity or Severity

The evidence is very uncertain on the effects of AR physical activity on pain-related functioning and pain intensity, compared with conventional therapy or usual care (very low COE; Table 13). For the meta-analysis on pain-related functioning, we included data from the 3 trials evaluating AR physical activity interventions lasting 7-8 weeks, all of which used the Fibromyalgia Impact Questionnaire (FIQ).^57,58,60,61^ One of these trials did not include the work-related items of FIQ.^57^ The pooled estimate for standardized Diff ∆ was −0.6 (−1.4, 0.2; Figure 9). The fourth trial used the revised version of FIQ (FIQR) to assess pain-related functioning at baseline and post-intervention (6 months), finding greater improvement in the AR group (Diff ∆ −2.8).^63^

Both trials reporting pain intensity used the VAS, but on different scales. Polat, 2021^57^ used 0-10 VAS and found greater reductions in the AR group during and immediately after the intervention (Diff ∆ - 0.6 at 4 weeks and −0.9 at 8 weeks). Villafaina, 2019^59^ used 0-100 VAS and showed greater improvement in the AR group immediately post-intervention at 6 months (Diff ∆ −11.1).

Figure 9 AR Physical Activity versus Control: Pain-Related Functioning 7-8 Weeks

Table 12 Summary of Findings for Fibromyalgia

Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Outcomes
Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Pain-Related Functioning or Interference | Pain Intensity or Severity | Adverse Events & Other Eligible Outcomes
AR Physical Activity Interventions
Collado-Mateo, 2017a^60^; Collado-Mateo, 2017b^61^; Some concerns; Spain | Women diagnosed with fibromyalgia by ACR criteria, excluding pregnancy, any changes in therapies in past 8 mo, and had contraindications to exercise; mean ages 52-53 yrs | Games using Microsoft Kinect that involved dance, walking, etc.; N = 42 (41); Clinic; 8 wk | Usual care; N=41 (35); Clinic; 8 wk | FIQ; Baseline (SD):; Intervention—50.6 (12.9); Comparator—49.2 (15.3); Diff ∆ (8 wk): −8.3^*^ | NR | NR; Quality of life (8 wk); EuroQoL-5D; Physical performance (8 wk); TUG; Functional reach; Balance tests
De Carvalho, 2019^58^; High; Brazil | Women diagnosed with fibromyalgia by ACR criteria, excluding cardiovascular, pulmonary, orthopedic, neurologic, or dermatologic conditions affecting strength and physical capabilities, and pregnancy; mean ages 48-56 yrs | Games using Nintendo Wii Fit that involve variety of lower limb, upper limb and trunk exercises; N = 16 (11); Clinic; 7 wk | Chain muscle stretching; N = 19 (10); Clinic; 7 wk | FIQ; Baseline (SD):; Intervention—64.5 (16.1); Comparator—72.0 (9.1); Diff ∆^*^:; 4 wk: −14.3; 7 wk: −5.6 | NR | NR; Physical performance (4 wk, 7 wk); Number of Steps up/down (25 cm height)
Polat, 2021^57^; High; Turkey | Women diagnosed with fibromyalgia by ACR criteria, ≥ 8 years of formal education and same medications for fibromyalgia ≥3 mo; mean ages 43-47 yrs | Beach volleyball games using Microsoft Kinect; N = 20 (20); Home, clinic; 8 wk | Conventional strength training; N = 20 (20); Home, clinic; 8 wk | FIQ (no work domain); Baseline (SD):; Intervention—54.7 (13.3); Comparator—58.5 (9.2); Diff ∆^*^:; 4 wk: −5.2; 8 wk: −6.8 | VAS; Baseline (SD):; Intervention—6.40 (1.4); Comparator—6.45 (1.3); Diff ∆^*^:; 4 wk: −0.6; 8 wk: −0.9 | NR; Quality of life (4 wk, 8 wk); EuroQoL-5D; Physical performance (4, 8 wk); 6-minute walk
Villafaina, 2019^59^; Martin-Martinez, 2019^62^; Villafina, 2020^63^; Some concerns; Spain | Women diagnosed with fibromyalgia by ACR criteria; mean ages 53-54 yrs | Games using Microsoft Kinect that involved dance, walking, etc; N = 28 (25); Clinic; 24 wk | Usual care; N = 27 (25); Clinic; 24 wk | FIQR; Baseline (SD):; Intervention—52.6 (17.1); Comparator—55.0 (20.3); Diff ∆ (24 wk): −2.8^*^ | VAS; Baseline (SD):; Intervention—62.1 (19.3); Comparator—60.4 (19.3); Diff ∆ (24 wk): −11.1^*^ | NR; Quality of life (24 wk); EuroQoL-5D-5L; Physical performance (24 wk); 6-minute walk; Sit-to-stand; TUG; 10 stairs (timed); Sit and reach; Arm curl; Back scratch
AR-Enhanced Cognitive Behavioral Therapy
Garcia-Palacios, 2015^64^; High; Spain | Women 18-70 years old, diagnosed with fibromyalgia by ACR criteria, excluding severe mental disorders, mental retardation, substance abuse, physical disease “that could interfere with receiving…treatment,” and not requesting disability; mean age NR | Cognitive behavioral therapy sessions with projected images of meadow or beach environments alongside environment sounds, music, or narratives.; N = 31 (30); Clinic; 6 wk | Usual care; N = 30 (29); Clinic; 6 wk | FIQ; Baseline (SD):; Intervention—61.6 (19.9); Comparator—60.6 (21.4); Diff ∆ (6 wk): −15.7^*^; BPI-Interference; Baseline (SD):; Intervention—32.2 (14.8); Comparator—32.3 (16.7); Diff ∆ (6 wk): −5.7^*^ | BPI-Intensity; Baseline (SD):; Intervention—23.6 (5.1); Comparator—22.4 (7.97); Diff ∆ (6 wk): 0.7^*^ | NR; Quality of life (8 wk); Quality of Life Index

Notes.

* Diff ∆ calculated by review team, unable to calculate standardized Diff ∆.

Abbreviations. ACR=American College of Rheumatology; BPI=Brief Pain Inventory; Diff=difference in differences; EuroQoL-5D=European Quality of Life 5 dimensions; FIQ=Fibromyalgia Impact Questionnaire; FIQR=revised version of Fibromyalgia Impact Questionnaire; NR=not reported; RoB=risk of bias; SD=standard deviation; TUG=timed up and go; wk=week; yrs=years.

Table 13 Certainty of Evidence: AR Physical Activity for Fibromyalgia

Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | AR Physical Activity | Comparator | Difference | Certainty | What Happens
Pain-Related Functioning or Interference; FIQ; FIQR | 7-8 weeks; N = 158; 3 RCTs)^57,58,60^ | −4.6^*^ | 2.5^*^ | Stand. Diff ∆: −0.6 (−1.4, 0.2) | ⨁◯◯◯; Very low^a,b,c^ | The evidence is very uncertain about the effect of AR physical activity on pain-related functioning, compared with conventional therapy or usual care.
Pain Intensity or Severity; VAS | 2-4 months; N = 95; 2 RCTs^57,59^ | −2.5^†^ | −1.7^†^ | Diff ∆: −0.9 ^†^ | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of AR physical activity on pain intensity compared with conventional therapy or usual care.

Notes.

* Mean change for active comparator taken from Collado-Mateo, 2017a^60^, mean change for AR physical activity calculated using pooled estimate for standardized Diff. ∆.

† Values for mean change in AR physical activity, active comparator, and Diff. ∆ taken from Polat, 2021.^57^

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 2 levels for study limitations (studies rated high for risk of bias).

b Downgraded 1 level for indirectness (all studies included only female participants).

c Downgraded 1 level for imprecision (CI crosses 0).

Abbreviations. AR=augmented reality; CI=confidence interval; Diff ∆=difference in change scores; FIQ=Fibromyalgia Impact Questionnaire; FIQR=Revised version of Fibromyalgia Impact Questionnaire; No.=number; RCT=randomized controlled trial; VAS=Visual Analogue Scale.

#### Other Outcomes

Three AR physical activity studies reported findings on health-related quality of life, all using the European Quality of Life-5 (EuroQoL-5D).^57,59,60^ All 3 found no substantial differences between groups, with both groups showing slight improvements or none (Diff ∆ 0.1 across all studies and time points). These same 3 studies also provided results on a range of physical performance assessments, including 6-minute walk, TUG, and sit-to-stand. In general, the AR group demonstrated greater improvements, compared with either usual care or conventional exercises. For example, both Collado-Mateo, 2017b^61^ and Martin-Martinez, 2019^62^ showed greater reductions in time on the TUG (Diff ∆ −0.7 s and −1.8 s, respectively). Similarly, the AR group had larger increases in distance on the 6-minute walk (Diff ∆ 26.9 m^57^ and 34.6 m^63^).

### AR-Enhanced CBT Intervention

The evidence is also very uncertain on the effects of AR-enhanced CBT on pain-related functioning and pain intensity, compared with usual care (very low COE; Table 14). Garcia-Palacios, 2015^64^ was conducted in Spain, and compared AR-enhanced CBT for 6 weeks (n = 31) with usual care (n = 30).^64^ The AR arm involved group CBT sessions that provided coaching on activity management while a landscape image was projected on a large screen and specific music, sounds, or narratives were playing. Pain-related functioning was assessed with FIQ and BPI-Interference. The AR group showed greater improvements on both measures at 6 weeks (Diff ∆ −15.7 for FIQ and −5.7 on BPI-Interference). Pain intensity was measured with BPI-Intensity and although both groups had reductions at 6 weeks, the control group had a greater improvement (Diff ∆ 0.7). Finally, quality of life was assessed with the Quality of Life Index, and the AR group showed greater improvement at 6 weeks (Diff ∆ 1.4).

Table 14 Certainty of Evidence: AR-Enhanced CBT for Fibromyalgia

Outcome; Outcome Measure | Follow-Up; No. of Participants (Studies) | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure | Follow-Up; No. of Participants (Studies) | AR-CBT | Usual Care | Diff ∆ | Certainty | What Happens
Pain-Related Functioning or Interference; FIQ; BPI-Interference | 6 weeks; N = 59; 1 RCT^64^ | −19.2 | −3.6 | −15.7 | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of AR-enhanced CBT on pain-related functioning, compared with usual care.
Pain Intensity or Severity; BPI-Intensity | 6 weeks; N = 59; 1 RCT^64^ | −0.9 | −1.7 | 0.7 | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain about the effect of AR-enhanced CBT on pain-related functioning, compared with usual care.

Notes. GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded 2 levels for study limitations (rated high for risk of bias).

b Downgraded 1 level for indirectness (trials included only female participants.

Abbreviations. AR=augmented reality; BPI=Brief Pain Inventory; CBT=cognitive behavioral therapy; Diff ∆=difference in change scores; FIQ=Fibromyalgia Impact Questionnaire; No.=number; RCT=randomized controlled trial.

## CHRONIC KNEE PAIN (KQ1)

We identified 5 trials evaluating XR interventions for chronic knee pain, all of which included only participants with knee osteoarthritis. All studies involved VR (k = 1) and AR (k = 4) interventions with physical activity, compared to conventional therapy. Summary characteristics and findings are summarized in Table 15, and detailed trial characteristics and results are found in Appendix H. Below, we first present findings from the single VR trial, and then describe results from the 4 AR studies.

Table 15 Summary of Findings for Chronic Knee Pain

Author, Year; RoB; Country | Key Participant Characteristics | XR Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator(s); N Randomized (N Analyzed); Setting; Duration | Outcomes
Author, Year; RoB; Country | Key Participant Characteristics | XR Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator(s); N Randomized (N Analyzed); Setting; Duration | Pain-Related Functioning | Pain Intensity/Severity | Adverse Events & Other Eligible Outcomes
VR Intervention Trials
Ozlu, 2023^65^; High; Turkey | Knee OA stages 2-3 (ACR criteria), MMSE≥ 22; mean ages 53-54 yr, 49-68% women | Games using Oculus headset that focus on lateral movement and trunk flexion to interact with virtual targets, in addition to ultrasound and TENS treatment; N = 41 (35); Clinic; 3 wk | Conventional treatment with ultrasound and TENS; N = 41 (38); Clinic; 3 wk | WOMAC (total); Baseline means (SD):; Intervention—31.7 (6.8); Comparator—33.0 (7.9); Diff ∆^*^:; 3 wk: −8.7; 7 wk: −5.1 | VAS; Baseline means (SD):; Intervention—5.6 (0.9); Comparator—5.8 (0.7); Diff ∆^*^:; 3 wk: −0.7; 7 wk: −1.1 | NR; Physical performance (3 wk, 7 wk); 6-minute walk; Berg Balance Scale
AR Intervention Trials
Elshazly, 2016^66^; Some concerns; Saudi Arabia | ≥3 months of OA, able to walk ≥30 ft without assistance, and not in any sports or physical therapy; mean ages 58-60, sex/gender NR | Game involving standing and taking steps on virtual platform (device NR); N = 20 (20); NR; 8 weeks | Sensorimotor training (SMT); N = 20 (20); NR; 8 weeks | WOMAC (total); Baseline means (SD):; Intervention—71.7 (3.4); SMT—71.7 (2.8); Control—71.9 (3.1); Diff ∆ (Intervention-SMT)^*^:; 4 wk: −13.5; 8 wk: −19.5; Diff ∆ (Intervention-control)^*^:; 4 wk: −14.1; 8 wk: −29.9 | VAS; Baseline means (SD):; Intervention—6.8 (0.9); SMT—6.6 (1.2); Control—6.68 (0.84); Diff ∆ (Intervention-SMT)^*^:; 4 wk: −1.9; 8 wk: −1.8; Diff ∆ (Intervention-control)^*^:; 4 wk: −1.8; 8 wk: −2.0 | NR; Quality of Life (4 wk, 8 wk); CDC Health Related Quality of Life; Physical Performance (4 wk, 8 wk); Position sense
Elshazly, 2016^66^; Some concerns; Saudi Arabia | ≥3 months of OA, able to walk ≥30 ft without assistance, and not in any sports or physical therapy; mean ages 58-60, sex/gender NR | Game involving standing and taking steps on virtual platform (device NR); N = 20 (20); NR; 8 weeks | Conventional walking program (control); N = 20 (20); NR; 8 weeks | | VAS; Baseline means (SD):; Intervention—6.8 (0.9); SMT—6.6 (1.2); Control—6.68 (0.84); Diff ∆ (Intervention-SMT)^*^:; 4 wk: −1.9; 8 wk: −1.8; Diff ∆ (Intervention-control)^*^:; 4 wk: −1.8; 8 wk: −2.0 | NR; Quality of Life (4 wk, 8 wk); CDC Health Related Quality of Life; Physical Performance (4 wk, 8 wk); Position sense
Lin, 2020^67^; Some concerns; Taiwan | Knee OA (ACR criteria), Kellgren and Lawrence score ≥ 2, able to walk > 15 m, and not needing NSAIDS; mean ages 56-58 yr, 43-60% female | Games involving interaction with virtual targets through lower limb and trunk movements (via sensor pad for feet), in addition to temperature therapy and TENS; N = 40 (40); Clinic; 4 weeks | Temperature therapy, TENS, and conventional exercise program (stretching, stabilization exercises, etc.); N = 40 (40); Clinic; 4 weeks | WOMAC-physical function ^‡^; Baseline means (SD):; Intervention—505.1 (328.4); Comparator—581.0 (383.8); Diff ∆^*^:; 2 wk: 39.1; 4 wk: 60.3; 8 wk: 90.0; 16 wk: 82.8 | WOMAC-pain; Baseline means (SD):; Intervention—161.2 (114.7); Comparator—170.2 (121.3); Diff ∆^*^:; 2 wk: 0.7; 4 wk: 3.9; 8 wk: −19.9; 16 wk: 4.9 | No adverse effects observed in either group; Quality of Life (2-16 wk); WHOQOL-BREF; Physical Performance (2-16 wk); Biodex stability system; 10 m walk time; Stair ascent, descent time
Mete, 2022^68^; High; Turkey | Knee OA, Kellgren and Lawrence stages 2-3; median ages 57-60 yr, 77-88% women | Games involving control of on-screen avatars through knee flexion and extension, via special device (MarVAJED) with sensors for joint positions and provided auditory and visual feedback, in addition to comparator treatment; N = 32 (30); Clinic; 6 wk | Conventional treatment with ultrasound, TENS, temperature therapy, and muscle strengthening exercises; N = 32 (30); Clinic; 6 wk | WOMAC (total); Baseline medians (IQR):; Intervention—19.7 (18.2, 21); Comparator—15.1 (9.3, 18); Diff ∆ NC^†^ | WOMAC–pain; Baseline medians (IQR):; Intervention—6 (5.37, 7.12); Comparator—4.5 (4.3, 6); Diff ∆ NC^†^; VAS (at rest); Baseline medians (IQR):; Intervention—32.2 (20.8, 40.0); Comparator—36.3 (30.0, 40.0); Diff ∆ NC^†^ | NR; Kinesiophobia (6 wk); TSK; Physical performance (6 wk); Pedalo Balance Score; Knee flexion & extension ROM; Knee proprioception at 30, 60°; Peak torque of knee flexion & extension at 120, 240°
Nambi, 2020c^69^; Some concerns; Saudi Arabia | Male soccer players with post-traumatic OA ≥ 3 mo following ACL injury (verified by orthopedic surgeon) and pain rating 4-8; mean ages 22-23 yr | Games using ProKin system that required knee movements to interact with visual targets; N = 20 (18-20); Clinic; 4 wk | Sensorimotor training (SMT); N = 20 (18-20); Clinic; 4 wk | WOMAC (total); Baseline means (SD):; Intervention—72.3 (4.2); SMT—72.5 (4.5); Control—71.2 (3.8); Diff ∆ (Intervention-SMT)^*^:; 4 wk: −22.1; 8 wk: −9.8; 3 mo: −14.0; Diff ∆ (Intervention-control)^*^:; 4 wk: −29.3; 8 wk: −31.0; 3 mo: −25.1 | VAS; Baseline means (SD):; Intervention—7.2 (0.5); SMT—7.4 (0.4); Control—7.3 (0.4); Diff ∆ (Intervention-SMT)^*^:; 4 wk: −2.3; 8 wk: −0.8; 3 mo: −0.8; Diff ∆ (Intervention-control)^*^:; 4 wk: −3.1; 8 wk: −1.6; 3 mo: −3.2 | NR; NR
Nambi, 2020c^69^; Some concerns; Saudi Arabia | Male soccer players with post-traumatic OA ≥ 3 mo following ACL injury (verified by orthopedic surgeon) and pain rating 4-8; mean ages 22-23 yr | Games using ProKin system that required knee movements to interact with visual targets; N = 20 (18-20); Clinic; 4 wk | Standard exercise program (control); N=20 (19-20); Clinic; 4 wk | | | NR; NR

Notes.

* Diff ∆ calculated by review team, unable to standardize as no SD for change reported.

† Diff ∆ not reported and cannot be calculated using provided results.

‡ WOMAC total scores NR.

Abbreviations. ACL=anterior cruciate ligament; ACR=American College of Rheumatology; CDC=Center for Disease Control and Prevention; Diff ∆=difference in change scores; IQR=interquartile range; mo=months; NC=not calculable; NR=not reported; NSAIDS=non-steroidal anti-inflammatory drugs; OA=osteoarthritis; RoB=risk of bias; ROM=range of motion; SD=standard deviation; SMT=sensorimotor training; TENS=transcutaneous electrical nerve stimulation; TSK=Tampa Scale of Kinesiophobia; VAS=Visual Analog Scale; wk=weeks; WOMAC=Western Ontario and McMaster Universities Arthritis Index; WHOQOL-BREF=World Health Organization Quality of Life Brief Version; yr=years.

### VR Intervention Trial

VR physical activity may result in better pain-related functioning, and greater decreases in pain intensity, compared with conventional therapy (low COE, Table 16). Ozlu, 2023^65^ was conducted in Turkey and compared 3 weeks of games (using Oculus glasses) that required lateral trunk movements (ie, catching fish or bananas) plus conventional therapy (n = 41) with conventional therapy only (n = 41). Conventional therapy involved ultrasound imaging as well as transcutaneous electrical nerve stimulation (TENS). Participants were middle-aged men and women who had no cognitive impairments. This trial was rated high for RoB due to concerns in every domain, including randomization, deviations from the intended intervention, missing data, and selective reporting bias.

For pain-related functioning, WOMAC was assessed at baseline, 3 weeks, and 7 weeks, showing greater improvement in the VR group at both timepoints (Diff ∆ −8.7 at 3 weeks and −5.1 at 7 weeks). Regarding pain intensity, VAS scores were measured at the same time points and demonstrated similarly greater reductions in the VR group (Diff ∆ −0.7 at 3 weeks and −1.1 at 7 weeks). This study also assessed physical performance, finding essentially no differences between groups on the 6-minute walk test (Diff ∆ −0.9 m at both time points) but greater improvement in the VR group on the Berg Balance Scale (Diff ∆ 1.9 at 3 weeks and 2.9 at 7 weeks).

Table 16 Certainty of Evidence: VR Physical Activity for Chronic Knee Pain

Outcome; Outcome Measure | Follow-Up; No. of Participants (Studies) | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure | Follow-Up; No. of Participants (Studies) | VR Physical Activity | Ultrasound & TENS | Diff ∆ | Certainty | What Happens
Pain-Related Functioning or Interference; WOMAC | 7 weeks; N = 82; 1 RCT^65^ | −5.2 | −0.2 | −5.0 | ⨁⨁◯◯; Low^a^ | VR physical activity may result in better pain-related functioning, compared to ultrasound and TENS.
Pain Intensity or Severity; VAS | 7 weeks; N = 82; 1 RCT^65^ | −1.5 | −0.4 | −1.1 | ⨁⨁◯◯; Low^a^ | VR physical activity may result in decreased pain intensity compared to ultrasound and TENS.

Notes.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded 2 levels for study limitations (study rated high for risk of bias).

Abbreviations. CI=confidence interval; Diff ∆=difference in change scores; No.=number; RCT=randomized controlled trial; TENS=transcutaneous electrical nerve stimulation; VAS=Visual Analogue Scale; VR=virtual reality; WOMAC=Western Ontario and McMaster Universities Arthritis Index.

### AR Intervention Trials

The evidence is very uncertain on the effects of AR physical activity on pain-related functioning, pain intensity, and adverse events, compared with conventional therapy (very low COE; Table 17). Four studies evaluated AR physical activity for chronic knee pain due to osteoarthritis. AR exercise programs lasted 4-8 weeks and were all compared with conventional therapy involving exercise and other techniques.^66–69^ All studies were very small (total n = 40-80). Studies were conducted in the Middle East (k = 3)^66,68,69^ and Taiwan.^67^ Three trials included middle-aged and older men and women,^66–68^ while the fourth included only young male soccer players.^68^ This latter study also specified that these athletes had post-traumatic osteoarthritis after an injury to the anterior cruciate ligament.^68^ Three studies were rated some concerns for RoB^66,67,69^ and 1 was rated high RoB.^68^ There were methodological concerns in most domains, including randomization, deviations from the intended intervention, missing data, and selective reporting bias. All studies assessed pain-related functioning and pain intensity, but only 1 study reported on adverse events.^67^

#### Pain-Related Functioning or Interference, and Pain Intensity or Severity

All 4 studies used WOMAC to evaluate pain-related functioning. Three trials^66,68,69^ reported total WOMAC scores (though 1 study only reported medians [IQR]), and the fourth study^67^ provided domain scores only. In general, all the groups improved over time, with the AR group having greater improvement in WOMAC total scores (eg, Diff ∆ −13.5 at 4 weeks and −19.5 at 8 weeks, compared with sensorimotor training).^66^ All studies also assessed pain intensity, using either VAS or WOMAC-pain subscale. Two trials showed greater reductions in VAS for the AR group (Diff ∆ −0.8 to −3.1),^66,69^ and 1 trial found inconsistent results over time using WOMAC-pain scale (Diff ∆ −19.9 to 4.9).^67^ The fourth trial reported only medians (IQR) for pain intensity.^68^

#### Adverse Events

Only 1 study evaluated adverse events; none were detected in either group during the 4-week duration of the intervention.^67^

#### Other Outcomes

Two studies examined quality of life: 1 used the Centers for Disease Control and Prevention (CDC) Health Related Quality of Life scale,^66^ and the other used the World Health Organization Quality of Life Brief Version (WHOQOL-BREF).^67^ There were generally small improvements in all the groups and no clear differences between groups (eg, Diff ∆ 0.5-1.9 for WHOQOL-BREF physical domain scores).^67^ One study assessed kinesiophobia using TSK but only provided medians (IQR).^68^ Three trials evaluated physical performance using a variety of measures, including 10-meter walk, balance and position sense, and ROM.^66–68^ All groups generally improved in these measures but there were inconsistent results in terms of which group did better. For example, Lin, 2020^67^ showed that the control group had greater reduction in time for 10-meter walk at 2 weeks (Diff ∆ 1.1 s), no substantial differences between groups at 4 and 8 weeks (Diff ∆ −0.1 s at both time points), and the AR group had better times at 16 weeks (Diff ∆ −0.9 s).

Table 17 Certainty of Evidence: AR Physical Activity for Chronic Knee Pain

Outcome; Outcome Measure | Follow-Up; No. of Participants (Studies) | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure | Follow-Up; No. of Participants (Studies) | AR Physical Activity | Conventional Therapy | Difference | Certainty | What Happens
Pain-Related Functioning or Interference; WOMAC | 2-4 months; N = 180; 3 RCTs^66,67,69^ | −57.0^*^ | −27.2 to −37.6^*^ | Diff ∆: −19.5 to −29.9 * | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of AR physical activity compared to conventional therapy.
Pain Intensity or Severity; VAS; WOMAC-pain | 2-4 months; N = 180; 3 RCTs^66,67,69^ | −3.9^*^ | −1.9 to −2.1^*^ | Diff ∆: −1.8 to −2.0 * | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of AR physical activity on pain intensity compared to conventional therapy.
Adverse Events | Mean 4 weeks; N = 80; 1 RCT^67^ | 0 | 0 | 0 | ⨁◯◯◯; Very low^c,d,e^ | The evidence is very uncertain on the effect of AR physical activity on adverse events compared to conventional therapy.

Notes.

* Values for mean change in AR physical activity, conventional therapy (2 groups: sensorimotor training and walking program), and Diff. ∆ taken from Elshazly et al^66^ at 8 weeks.

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded 2 level for study limitations (studies rated some concerns and high for risk of bias).

b Downgraded 2 levels for indirectness (high prevalence of women in some studies; one trial with only young male athletes).

c Downgraded 1 level for study limitations (study rated some concerns for risk of bias).

d Downgraded 1 level for indirectness (authors do not describe how they measured adverse events).

e Downgraded 1 level for imprecision (no events were detected in either arm).

Abbreviations. AR=augmented reality; CI=confidence interval; Diff ∆=difference in change scores; no.=number; RCT=randomized controlled trial; VAS=Visual Analogue Scale; WOMAC=Western Ontario and McMaster Universities Arthritis Index.

## KQ1 OTHER CONDITIONS

We identified 11 trials that were single studies evaluating the use of VR (k = 5) or AR (k = 6) interventions for a variety of chronic pain conditions. Trial characteristics and main findings are summarized in Table 18. Detailed characteristics and results are provided in Appendix I. Below, we first describe the trials evaluating VR interventions. Then we provide the results from trials of AR interventions.

Table 18 Summary of Findings for KQ1 Other Conditions

Author, Year; RoB; Country | Pain Condition; Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Outcomes
Author, Year; RoB; Country | Pain Condition; Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Pain-Related Functioning or Interference | Pain Intensity or Severity | Adverse Events & Other Eligible Outcomes
VR Psychological Skills Trials
Cueno, 2023^70^; High; USA | Chronic migraine; Severe psychiatric comorbidities were excluded; mean ages 42-43 yr, 83% women | Biofeedback training using Oculus Go mobile headset and heartrate monitor; N = 25 (14); Home; 12 wk | Wait-list control; N = 25 (22); N/A; 12 wk | MIDAS; Baseline means (SD):; Intervention—100.4 (72.6); Comparator—77.6 (64.7); Diff ∆ (3 mo): −9.7^*^ | Headache days/month; Baseline means (SD):; Intervention—23.7 (5.6); Comparator—25.4 (5.8); Diff ∆ (3 mo): −0.4^*^ | VR group: Nausea 29%, dizziness 22% (comparator group NR); Pain catastrophizing (12 wk); - CAP
Chuan, 2023^71^; Some Concerns; Australia | Cancer-related neuropathic pain; Independent in most ADLs; psychiatric comorbidities (not stabilized with treatment) were excluded; mean ages 56-63 yr, 64% women | Progressive muscle relaxation and guided pain visualization using Oculus Rift S; N = 19 (19); Clinic; 3 mo | Short nature videos viewed on Oculus Rift S; N = 20 (20); Clinic; 3 mo | BPI-interference; Baseline means (SD):; Intervention—4.7 (2.4); Comparator—4.1 (2.7); Diff ∆:; 1 mo: −1.0^*^; 3 mo: −1.6^*^ | BPI-intensity; Baseline means (SD):; Intervention—4.9 (1.1); Comparator—4.4 (1.9); Diff ∆:; 1 mo: −0.5^*^; 3 mo: −0.2^*^ | Intervention: 21% nausea, 21% dizziness, 21% eyestrain; Control: 25% nausea, 20% dizziness, 40% eyestrain; Quality of life (1 mo, 3 mo); - QLQ-C30 (all domains); Opioid use; - Average MME in previous week
Darnall, 2020^72^; High; USA | Back pain & fibromyalgia; Adults with self-reported chronic, nonmalignant low back pain or fibromyalgia for ≥ 6 months with average pain intensity >4 (scale NR) over past month; mean ages NR; 26-33% female | Pain self-management strategies using Oculus Go VR headset; N = 35 (25); Home; 22 days | Pain self-management strategies through audio recordings; N = 39(29); Home; 22 days | DVPRS (item scores only – Pain Stress, Pain Mood, Sleep, and Activity Interference) | DVPRS – Pain; Baseline means (SD):; VR—8.4 (3.5); Audio only—4.5 (1.8); Diff ∆ (3 wk): −4.5 | 24% of VR group had any nausea or motion sickness (comparator group not assessed); Pain global change (3 wk); - PGIC
VR Other Trials
Reynolds, 2022^73^; Some Concerns; New Zealand | Metastatic breast cancer related pain, anxiety, and/or fatigue; Experiencing pain, fatigue, and/or anxiety in the past week; mean ages 51-53 yr, 100% women | Sequence of 2 pleasant distracting experiences using Pico Goblin VR headset:; 1^st^—Ripple; 2^nd^—Happy Place; N = 20 (38); Home; 9 days, 1-wk washout, 9 days | Inverse sequence of 2 experiences using Pico Goblin VR headset:; 1^st^—Happy Place; 2^nd^—Ripple; N = 18 (38); Home, 9 days, 1-wk washout, 9 days | BPI (total score) ^ǂ^; Baseline means (95% CI):; Happy Place—37.7 (31.2, 44.2); Ripple—42.1 (35.5, 48.6); 9-day mean difference: −2.2^*^ | NR | Some participants reported feeling “claustrophobic” or “a bit dizzy/nauseous.” (text comments from acceptability survey, rates NR); Quality of life (9 days); - EuroQoL-5D-5L (index and VAS general health)
Wankhade, 2022^74^; High; India | Frozen shoulder; Stage 2-3 primary or idiopathic frozen shoulder, excluded any post-operative history of shoulder injuries, diabetes, and/or rheumatoid arthritis; mean age & % women NR | Physical therapy using Oculus Rift; N = 25 (25); Clinic; 2 wk | Conventional physical therapy; N = 25 (25); Clinic; 2 wk | Shoulder Pain and Disability Index; Baseline mean (SD) NR; Diff ∆: 16.3^*^ | NRS; Baseline mean (SD) NR; Diff ∆: 1.0^*^ | NR; Physical performance (2 wk); - ROM shoulder flexion, extension, abduction, adduction, internal & external rotation
AR Physical Activity Trials
Ambrosino, 2020^75^; High; Italy | Rheumatoid arthritis; Enrolled for 4 wk intensive orthopedic and rheumatologic rehabilitation, excluded malignancy, intolerance to exercise, and pregnancy; mean ages 27-28 yrs, 35-40% male | Exercises with Nintendo Wii-Fit; N = 20 (20); Clinic & Home; 12 wk | Conventional rehabilitation; N = 20 (20); Clinic & Home; 12 wk | Health Assessment Questionnaire (HAQ); Baseline mean (SD):; Intervention:1.8 (0.2); Comparator: 1.8 (0.3); Diff ∆ (12 wk): −0.6^*^ | NR | NR; NR
Ditchburn, 2020^76^; High; United Kingdom | Musculoskeletal pain in ≥ 2 locations; Able to walk unassisted for at least 0.5 miles, musculoskeletal pain in ≥2 joints for >12 weeks, excluding systemic conditions that may cause pain or self-reported injuries that contra-indicate exercise; mean ages 70-72 yr, 65-82% female | Games using the IREX system (volleyball, sharkbait, formula racing, snowboard, and bird & balls); N = 27 (27); Clinic; 6 wk | Exercises matched to games; N = 27 (27); Clinic; 6 wk | NR | NRS; Baseline mean (SD):; Intervention: 3.0 (1.9); Control: 3.3 (2.8); Diff ∆ (6 wk): −1.0^*^ | “There were no adverse events, reactions, or reports of motion sickness amongst participants…”; Quality of life (6 wk); - MAPS questionnaire; Physical performance (6 wk); - Postural sway with eyes open & closed
Gouveia e Silva, 2020^76^; Some concerns; Brazil | Post-polio syndrome; Diagnosis by consensus of Halstead and Rossi, no other rehabilitation or physical exercise during intervention; mean ages 55-56 yr; 50% female | Nintendo Wii games (bowling, boxing, golf, tennis); N = 19 (19); Clinic; 7 wk | Movement that mimics that of the Wii games; N = 20 (20); Clinic; 7 wk | NR | VAS; Baseline means (SD):; Intervention: 6.2 (3.0); Control: 6.9 (1.6); Diff ∆:; 7 wk: 0.0; 11 wk: −0.1 | Later upper limb muscle pain (after 1^st^ session): AR group 15%, control group 10%; Physical performance (7 wk, 11 wk); - Box and Block (dexterity); - Functional Reach Assessment (balance)
Karahan, 2016^77^; Some Concerns; Turkey | Ankylosing spondylitis; Lack of regular exercise during the previous 6 months, excluded cardiopulmonary or other serious comorbidities; mean ages 36-37 yrs, 14-21% female | Games using Microsoft Kinect; N = 28 (28); Clinic; 8 wk | Usual care; N = 29 (29); Clinic; 8 wk | Bath Ankylosing Spondylitis Functional Index (BASFI); Baseline means (SD):; Intervention—3.7 (1.5); Control—3.9 (1.6); 8-week Diff ∆:; Intervention: −0.8; Control: 0.0 | VAS; Baseline means (SD):; Intervention—4.9; Control—5.1; 8-week Diff ∆:; Intervention: −1.3; Control: −0.1 | NR; Quality of life (8 wk); - Ankylosing Spondylitis Quality of Life (ASQOL) questionnaire
AR Embodiment Trials
Lewis, 2021^78^; High; UK | Complex Regional Pain Syndrome (CRPS); Identified from the CRPS UK network registry, excluded co-morbidity that might influence CRPS symptoms (ie, stroke, diabetes, fibromyalgia); mean age 52 yr, 65% female | Mediated virtual reality (MVR). (MIRAGE system); N = 23 (21 analyzed); Clinic; 6 wk | Sham; N = 22 (18 analyzed); Clinic; 6 wk | NR | NRS; Baseline mean (SD); Intervention: 5.6 (3.3); Comparator: 5.7 (3.4); Diff ∆: −0.05^*^ | NR; NR
Rothgangel, 2018^79^; Some concerns; Germany | Phantom limb pain; Unilateral amputation with average PLP intensity 3/11 and ≥1 episode of PLP in past week; sufficient cognition, motor and cognitive skills; excluded stroke, severe mental disorders; mean ages 60-63 yr, 56-80% male | Mirror therapy with iPad; N = 26 (22); Home, clinic; 6 mo | No additional therapy; N = 24 (19); Home, clinic; 6 mo | PDI; Baseline means (SD):; iPad: 30.5 (16.5); Mirror therapy: 23.6 (18.2); Control: 32 (20.1); 10-week Diff ∆:; iPad vs mirror therapy: 5.1^*^; iPad vs control: 3.9^*^; 6 mo:; iPad vs mirror therapy: 3.6^*^; iPad vs control: 0.9^*^ | NRS; Baseline means (SD):; iPad: 5.9 (1.9); Mirror therapy: 5.4 (2.4); Control: 5.8 (2.1); Diff ∆:; 10 wk:; iPad vs mirror therapy: 0.5^*^; iPad vs control: 0.4^*^; 6 mo:; iPad vs mirror therapy: 0.9^*^; iPad vs control: −0.5^*^ | NR; Quality of life (10 wk, 6 mo); - EuroQoL-5D-5L; Pain global change (10 wk, 6 mo); - GPE
Rothgangel, 2018^79^; Some concerns; Germany | | Mirror therapy with iPad; N = 26 (22); Home, clinic; 6 mo | Traditional mirror therapy; N = 26 (21); Home, clinic; 6 mo | | | NR; Quality of life (10 wk, 6 mo); - EuroQoL-5D-5L; Pain global change (10 wk, 6 mo); - GPE

Notes.

* Difference in mean change calculated by review team, unable to calculate SMD

ǂ Data abstracted from graphs using Plotdigitizer

Abbreviations. AR=augmented reality; BPI=Brief Pain Inventory; CRPS=Complex Regional Pain Syndrome; DASS-SF=Depression Anxiety Stress Scales – Short Form; Diff ∆ =difference in mean change; EuroQoL-5D-5L=European Quality of Life-5 questionnaire; FACIT=Functional Assessment of Chronic Illness Therapy; GPE=global perceived effect; HAQ=Health Assessment Questionnaire; IREX=Interactive Rehabilitation and Exercise; MIDAS=Migraine Disability Assessment Test; MME=morphine milligram equivalent; N/A=not applicable; NR=not reported; NRS=Numeric Rating Scale; oMEDD=oral morphine equivalent daily dose; PDI=Pain Disability Index; PGIC=Pain Global Impression of Change scale; QLQ-C30= The European Organisation for Research and Treatment of Cancer (EORTC) Quality of Life Questionnaire Core 30; RoB=risk of bias; SD=standard deviation; USA=United States of America; VAS=Visual Analog Scale; VR=virtual reality; yr=year.

### VR Intervention Trials

Three trials evaluated VR psychological skills interventions for migraine,^70^ cancer-related neuropathic pain,^71^ and self-report chronic back pain or fibromyalgia.^72^ A fourth trial examined VR distraction for pain, anxiety, and/or fatigue due to metastatic breast cancer,^73^ and the last trial used VR physical activity intervention for frozen shoulder.^74^

#### VR Psychological Skills

Cueno, 2023^70^ was conducted in the US and compared biofeedback training using an Oculus Go mobile VR headset (paired with a Polar H10 heart rate monitor, n = 25) to wait-list control (n = 25). VR group participants experienced a beach or hilltop setting with accompanying music to help cue breathing and attain individualized optimal respiratory rate. Participants were primarily young and middle-aged women (mean ages 42-43 years, 83% women). This study was rated high RoB, primarily due to the high attrition disproportionately affecting the VR group. For pain-related functioning, Migraine Disability Assessment (MIDAS) was assessed at baseline and 12 weeks. MIDAS scores improved in both arms with somewhat greater reduction in the VR group (Diff ∆ −9.7). The number of headache days per month also decreased for both groups, with little difference between groups (Diff ∆ −0.4). Adverse events were only assessed for the VR group: 29% experienced nausea and 22% experienced dizziness. Pain catastrophizing was also assessed with the Concerns about Pain Scale (CAP).

The second VR psychological skills study, Chuan, 2023,^71^ examined VR psychological skills for cancer-related neuropathic pain. The study was conducted in Australia and compared a program teaching progressive muscle relaxation and pain visualization techniques (using Oculus Rift S headsets; n = 19) with a VR control consisting of short nature videos viewed through the same VR headsets (n = 20). Participants were functionally independent in most daily activities. Pain-related functioning was assessed with BPI-Interference at baseline, 1 month, and 3 months, showing slightly greater reduction in the VR psychological skills group (Diff ∆ −1.0 at 1 month and −1.6 at 3 months). Similar results were seen for pain intensity, measured using BPI-Intensity. Adverse events were assessed through reported symptoms of cybersickness as well as the tolerability of the interventions. There were no significant differences in the rates of nausea (21% vs 25%, p = 1.00), dizziness (21% vs 20%, p = 1.00), or eyestrain (21% vs 40%, p = 0.30) between the VR psychological skills and control groups. One participant from the control group withdrew from the study due to severe headaches. Quality of life was assessed with European Organization for the Research and Treatment of Cancer Core Quality of Life questionnaire (EORTC QLQ-C30) and median dose of opioids (average in the past week) was 0 morphine milligram equivalents per day at baseline and follow-up in both groups.

In the third VR psychological skills study, Darnall, 2020^72^ compared a pain education and self-management training (delivered using Oculus Go headset; n = 35) to similar skills training via audio recordings (n = 39) for participants with self-reported chronic low back pain or fibromyalgia. This trial was conducted in the US and was rated as high RoB due to concerns with the randomization process, deviations from the intended intervention, missing outcome data, and selective reporting bias. At baseline and 21 days, DVPRS was used to assess pain intensity and pain-related interference in a variety of domains. Greater reductions were seen in the VR psychological skills group (eg, DVPRS pain intensity Diff ∆ −4.5 and activity interference Diff ∆ −1.33). Adverse events were assessed through a survey on day 22. A quarter of participants (6 of 25) in the VR group experienced any nausea or motion sickness. Using the PGIC, 84% of VR group and 62% in the control group reported improvement; 0% in the VR group and 3% in the control group reported worsening pain.

#### VR Other

Reynolds, 2022^73^ examined VR distraction intervention for middle-aged women with fatigue and/or anxiety related to metastatic breast cancer. This crossover trial was conducted in New Zealand and compared 2 randomization schedules for the Happy Place application (a relaxing, animated camping scene with soothing music) and Ripple application (3 VR 360° nature scenes) using the Pico Goblin VR headset. Group 1 (n = 20) was randomized to Ripple, then Happy Place and Group 2 (n = 18) was randomized to Happy Place, then Ripple. There was a 1-week washout period in between interventions in both groups. This trial was assessed as some concerns RoB due to concerns of deviations from the intervention and missing outcome data. Pain-related functioning was assessed with BPI at baseline, day 7, and day 9. There was a slightly greater reduction in BPI for the Ripple application (Diff ∆ −2.2). Adverse events were measured throughout with an open-ended survey question, with some participants reporting feelings of claustrophobia and/or nausea while using the headset. Authors measured quality of life through the EuroQoL-5D-5L Index, and there were similar improvements in both groups.

In the second study, Wankhade, 2022^80^ compared VR physical activity (using Oculus Quest; n = 25) with conventional physical therapy (n = 25) for participants with frozen shoulder patients (mean age and sex NR). This trial was rated as high RoB due to concerns with the randomization process, deviations from the intended intervention, missing outcome data, and selective reporting bias. Pain-related functioning was assessed with the Shoulder Pain and Disability Index (SPADI) at baseline and 2 weeks, and only within-group differences were reported. SPADI increased for both groups, with greater change in the VR group (Diff ∆ 16.3). Pain intensity was measured with the NRS, and the VR group had greater increases in pain (Diff ∆ 1.1). Physical performance was assessed through various ROM measures.

### AR Intervention Trials

We identified 6 trials examining AR interventions, 4 of which were physical activity programs for musculoskeletal pain,^81^ rheumatoid arthritis,^75^ ankylosing spondylitis,^77^ and post-polio syndrome.^76^ The remaining 2 both evaluated AR embodiment interventions, 1 for complex regional pain syndrome (CRPS),^78^ and the other for phantom limb pain (PLP).^79^

#### AR Physical Activity

Ambrosino, 2020^75^ compared in-home exergaming using Nintendo Wii-Fit (n = 20) with conventional rehabilitation (n = 20) for rheumatoid arthritis. AR group participants were asked to play each of 5 games for 10 minutes each day at home over 8 weeks, after an intensive 4-week rehabilitation in clinic. The control group were advised to continue the rehabilitation exercises at home after the same 4-week in-clinic program. The study was conducted in Italy and included young men and women. This trial was rated as some concerns for RoB due to concerns about the randomization process, outcome measurement, and selective reporting bias. Pain-related functioning was assessed with the Health Assessment Questionnaire (HAQ), with greater improvement in the AR group post-intervention (Diff ∆ −0.6).

The second trial, Ditchburn, 2020,^81^ evaluated AR physical therapy using the IREX system (n = 27) versus traditional gym-based exercises (n = 27) for musculoskeletal pain in multiple locations. In the AR group, participants played each of 5 games 3 times per session, twice weekly for 6 weeks. The control group performed gym-based exercises that were similar, also twice weekly for 6 weeks. This study was conducted in the UK and included predominantly older women. This trial was rated high RoB due to concerns with the randomization process, deviations from the intended intervention, missing outcome data, and selective reporting bias. Authors measured current pain intensity and pain experienced within the past 30 days using the NRS. For current pain intensity, the AR group had greater reductions post-intervention (Diff ∆ −1.0). Authors stated, “There were no adverse events, adverse reactions, or reports of motion sickness…” Additionally, physical performance was assessed as postural control, measured as Center of Pressure displacement and velocity.

In the third trial, Gouveia e Silva, 2020^76^ examined the effect of games using Nintendo Wii for post-polio syndrome. The AR group played Nintendo Wii games (boxing, bowling, tennis, and golf; n = 19) and the control group were asked to perform exercises that mimicked the movements of Nintendo games, but without the interactive video game interface (n = 20). Both groups exercised for a total of 7 weeks, with 4 additional weeks follow-up afterwards. This study was conducted in Brazil and included middle-aged men and women with post-polio syndrome who were not undergoing other rehabilitation or exercising regularly. This trial was rated some concerns RoB due to concerns about adherence to the intervention and missing outcome data. Authors reported that both groups showed similar improvements in pain, measured by the VAS (Diff ∆ 0.0 at 7 weeks and −0.1 at 11 weeks). Authors evaluated late upper limb muscle pain after the first session only, reporting that 15% of the AR group and 10% of the control group experienced this. Physical performance was assessed with the Functional Reach Assessment (FRA) and Box and Block (BB) tests. Both groups improved on these assessments, with the AR group showing greater improvement on both tests (eg, Diff ∆ 1.0 for FRA and 5.3 for BB at 7 weeks).

The fourth study, Karahan, 2016,^77^ compared exercises using Microsoft Kinect 360 (n = 28) to usual care (n = 29) for ankylosing spondylitis. The AR group performed exercises 5 times per week for 8 weeks. This study was conducted in Turkey and included mostly young men. Eight (29%) participants in the AR group and 7 (24%) participants in the control group were taking anti-TNF α medication. This study was rated as some concerns RoB due to concerns about missing outcome data and selective reporting bias. Pain-related functioning was assessed with the Bath Ankylosing Spondylitis Functional Index (BASFI) and pain intensity with the VAS, both at baseline and 8 weeks. The AR group showed improvements in both BASFI and VAS at 8 weeks, whereas the control group did not change from baseline (Diff ∆ −0.8 for BASFI and −1.2 for VAS). Quality of life was measured with the Ankylosing Spondylitis Quality of Life (ASQOL), and similarly, only the AR group showed any improvement (Diff ∆ −2.8).

#### AR Embodiment

Lewis, 2020^78^ compared the impact of manipulated (n = 23) versus non-manipulated (n = 21) images of the affected hand in participants with CRPS. This trial was conducted in the UK and recruited participants from CPRS network registry and clinics. This trial was rated high RoB, in large part due to concerns regarding missingness of outcome data and deviations from the intervention. Authors used the MIRAGE system and required that participants place both hands resting palm down into the 2 apertures of the system. With their hands resting on the flat surface, the participants viewed a real-time digital image of their hands through a ‘window-like’ surface above and perpendicular to the apertures. Participants in both groups viewed their hand images during 1-minute sessions for a maximum of 5 sessions, with 4 occurring over 4 weeks and a final session during the sixth week. In the intervention group sessions, study personnel manipulated the appearance of the hand based on how participants desired their hand to appear. Pain intensity was assessed using NRS at baseline and before and after each session. There were no clear differences between groups (Diff ∆ −0.05).

In the second study, Rothgangel, 2018^79^ examined the effect of mirror therapy using an iPad (n = 26), compared with traditional mirror therapy (n = 26) and no therapy (n = 24) on phantom limb pain. This study was conducted in Germany. Participants were predominantly older men. This trial was assessed as some concerns RoB due to concerns about the randomization process, adherence to the intervention, and missing outcome data. During the first 4 weeks, both iPad and mirror therapy groups performed exercises with the intact limb in front of a mirror and were instructed to also perform the exercises with the phantom limb as soon as they perceived voluntary, pain-free movement. At the last session, participants in the iPad group (n = 26) were given the tablet, instructions, and training materials, and encouraged to use it as often as they wished. In the traditional mirror therapy group (n = 25), participants were encouraged to perform mirror therapy as often as they wished. In the comparator group (n = 24), participants performed the same exercises during the first 4 weeks without a mirror and instructed not to do exercises with their phantom limb. Afterwards, they were encouraged to perform self-delivered exercises with the intact limb as often as they wished. Pain-related functioning was measured with the Pain Disability Index at 10 weeks and 6 months, with the traditional mirror therapy group and control group having greater reductions than the iPad group at both time points (eg, Diff ∆ 5.1 and 3.6 at 10 weeks and 6 months, comparing iPad with mirror therapy). Similar results were seen for pain intensity, as measured with NRS at the same time points. Quality of life was assessed with the EuroQoL-5D, and pain global change was measured by the Global Perceived Effect (GPE); these were similar between groups and did not change substantially on follow-up.

## POST-SURGICAL PAIN & REHABILITATION (KQ2)

We identified 7 trials evaluating XR interventions for rehabilitation after knee or hip replacement surgery. Two trials examined VR interventions^82,83^ and 5 studies used AR interventions^84–88^ for rehabilitation after knee replacement (1 of these also included participants with hip replacements). All AR interventions involved physical activity. Trial characteristics and main findings are summarized in Table 19. Detailed trial characteristics and findings are found in Appendix K. Below, we first describe findings for VR intervention trials and then present findings for AR studies.

Table 19 Summary of Findings for Post-Surgical XR Interventions

Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Outcomes
Author, Year; RoB; Country | Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Pain-Related Functioning | Pain Intensity/Severity | Adverse Events & Other Eligible Outcomes
VR Intervention Trials
Fuchs, 2022^82^; High; Israel | Patients with osteoarthritis undergoing unilateral TKA; mean age 70 yrs, 52-63% women | Nature or music film watched on Oculus, while undergoing continuous passive motion therapy; N = 30 (30); Hospital; 2 days | Continuous passive motion therapy; N = 25 (25); Hospital; 2 days | WOMAC; Baseline means (SD):; Intervention—36.4 (15.1); Comparator—34.5 (17.0); Diff ∆ (6 mo)^*^: 1.1 | VAS; Baseline medians (IQR):; Intervention—6 (5-8); Comparator—6 (6-8); Diff ∆ NR^†^ | NR; NR
Jin, 2018^83^; High; China | Patients with osteoarthritis undergoing TKA; mean age 66 yrs, 55-61% women | Game using Oculus headset, rowing a boat using knee flexion; N = 33 (33); Hospital; NR | Passive flexion of knee using arms; N = 33 (33); Hospital; NR | WOMAC; Baseline (SD):; Intervention—45.0 (5.1); Comparator—44.2 (5.7); Diff ∆^*^:; 1 mo: −3.9; 3 mo: −4.7; 6 mo: −5.6 | VAS; Baseline (SD):; Intervention—7.4 (1.1); Comparator—7.4 (1.3); Diff ∆^*^:; 3 days: −0.3; 5 days: −0.5; 7 days: −0.5 | NR; Physical performance (3, 7, 14 days); - ROM
AR Intervention Trials
Eichler, 2019^84^; High; Germany | Patients with osteoarthritis after TKA or THA; mean ages 53-57 yrs, 49-54% women | Exercises using Microsoft Kinect sensor, as demonstrated by an avatar; N = 56 (48); Home; 3 months (after 3 wk inpatient rehab) | Usual care; N = 55 (39); Home; NR (after 3 wk inpatient rehab) | WOMAC; Baseline (SD); Intervention—26.4 (18.5); Comparator—24.8 (16.4); Standardized Diff ∆ (3 mo)^‡^: −0.29 | NR | NR; Quality of life (3 mo); - SF-36; Physical performance (3 mo); - 6-minute walk; - Stair Ascend test; - Five Times Chair Rise test
Janhunen, 2023^85^; Some concerns; Finland | After first primary TKA; mean ages 66-67 yrs; 63-64% women | Games using Microsoft Kinect, involved similar movements as home PT; N = 25 (21); Home; 16 wk | Standard PT; N = 27 (25); Home; 16 wk | OKS; Baseline (SD); Intervention—26.7 (6.7); Comparator—26.9 (6.5); Standardized Diff ∆ (4 mo)^‡^: 0.32, p=0.27 | VAS; Baseline (SD); Intervention—57.1 (18,3); Comparator—54.2 (21.6); Standardized Diff ∆ (4 mo)^‡^: −0.39, p=0.18 | NR; Physical performance (2, 4 mo); - TUG; - Short Physical Performance Battery; - Muscle force flexion, extension; - ROM flexion, extension
Piqueras, 2013^86^; High; Spain | After primary TKA, with active ROM flexion 80° and extension −10°, without signs of stiffness, and able to walk (walking aid ok); mean age 73 yrs, 72% women | Screen and leg movement sensors to instruct and monitor knee exercises; N = 90 (68); Home; 2 wk | Conventional PT; N = 91 (65); Clinic; 2 wk | NR | VAS; Baseline (SD):; Intervention—3.8 (2.01); Comparator—4.3 (1.93); Standardized Diff ∆^‡^:; 2-wk: −0.05, p=0.804; 3-mo: 0.22, p=0.28 | NR; Physical performance (2 wk, 3 mo); - TUG; - Quadriceps, hamstring strength; - ROM flexion, extension
Prvu Bettger, 2020^87^; Some concerns; USA | TKA for non-traumatic conditions and expected to discharge home; mean age 65 yrs, 60-65% women | Virtual telehealth system (VERA) to demonstrate exercises (with avatar) and monitor performance; N = 153 (140); Home; NR | Conventional PT care; N = 153 (140); Home; NR | KOOS; Baseline (SD):; Intervention—37.0 (12.0); Comparator—36.0 (13.0); Diff ∆^*^:; 6 wk: −1.8; 12 wk: 1.4 | NRS; Baseline (SD):; Intervention—5.2 (2.1); Comparator—5.7 (2.0); Diff ∆ (12 wk)^*^: 0.2 | Number of falls (12 wk):; Intervention—19.4%; Comparator—14.6%; Difference 4.8% (−2.6, 12.3); Physical performance (6 wk); - ROM extension, flexion
Shim, 2023^88^; Some concerns; Korea | Post-TKA and discharged home; mean ages 68-72 yrs; 75-82% women | Exercises using Microsoft Kinect; N = 28 (27); Home; 12 wk | Conventional rehabilitation; N = 28 (27); Home; 12 wk | WOMAC; Baseline (SD):; Intervention—83.1 (13.0); Comparator—81.1 (14.4); Diff ∆ NC^†^ | NRS; Baseline (SD):; Intervention—5.7 (2.1); Comparator—5.5 (2.2); Diff ∆ NC^†^ | NR; Quality of life (3 mo); - EuroQoL-5D; Physical performance (3, 12, 24 wk); - 4-meter gait speed; - Berg balance scale; - Quadriceps strength; - Hamstring strength; - ROM

Notes.

* Diff ∆ calculated by review team, unable to standardize as no SD for change reported.

† Diff ∆ not reported and cannot be calculated using provided results.

‡ Standardized Diff ∆ calculated by review team.

Abbreviations. Diff ∆=difference in change scores; EuroQoL-5D=European Quality of Life-5 dimensions KOOS=Knee Injury and Osteoarthritis Outcome Score; mo=month; NC=not calculable; NRS=Numeric Rating Scale; OKS=Oxford Knee Score; PT=physical therapy; RoB=risk of bias; ROM=range of motion; SD=standard deviation; SF-36=36-item Short Form health survey; TKA=total knee arthroplasty; THA=total hip arthroplasty; TUG=timed up and go; VAS=Visual Analog Scale; VR=virtual reality; wk=week; WOMAC=Western Ontario and McMaster Universities Arthritis Index.

### VR Intervention Trials

Both VR trials evaluated short-term interventions in the immediate post-surgical period while participants were still hospitalized, comparing these with standard physical therapy for rehabilitation after primary total knee replacement.^82,83^ Both studies included older men and women (mean ages 66-70 years, 53-58% women) previously diagnosed with osteoarthritis. Fuchs, 2022^82^ was conducted in Israel and compared watching a nature or music film on Samsung Gear VR headsets while undergoing continuous passive motion (CPM), physiotherapy (n = 30), or the same CPM physiotherapy without VR (n = 25) on post-operative days 1-2. Jin, 2018^83^ was conducted in China and compared daily boat-rowing exercises requiring knee flexion via VR headset (Mide Technology Inc.) (n = 33) with conventional physical therapy, also involving knee flexion (n =33). These exercises began on post-operative day 1 but total duration of therapy was not reported. Both trials were rated high RoB due to concerns in randomization and allocation procedures, appropriateness of statistical analyses, and missing data.

The evidence is very uncertain on the effects of VR for pain-related functioning or pain intensity when compared with non-VR rehabilitation (low COE, Table 20). Neither trial reported on adverse events. Both VR studies evaluated change in WOMAC as the measure of pain-related functioning. Fuchs, 2022^82^ found that WOMAC scores similarly worsened for both groups at 6 months (Diff ∆=1.1), while Jin, 2018^83^ reported improvement in WOMAC scores in both groups at 1, 3, and 6 months, with greater reductions in WOMAC in the VR group (eg, Diff ∆ = −5.6 at 6 months). Both VR studies also assessed pain intensity using the VAS. Fuchs, 2022^82^ measured VAS before and after therapy sessions on post-operative days 1 and 2, but only reported medians (IQR). Jin, 2018^83^ assessed VAS on post-operative days 1, 3, 5, and 7, with slightly greater reductions in the VR group (eg, Diff ∆ = −0.5 at day 7, compared with day 1). Jin, 2018^83^ also evaluated knee ROM before surgery and on post-operative days 3, 7, and 14.

Table 20 Certainty of Evidence: VR for Post-Surgical Pain & Rehabilitation

Outcome; Outcome Measure | Follow-up; No. of Participants (Studies) | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure | Follow-up; No. of Participants (Studies) | VR | Comparator | Diff ∆ | Certainty | What Happens
Pain-Related Functioning or Interference; WOMAC | 6 months; N = 121; 2 RCTs^83,89^ | −23.5^*^ | −17.9^*^ | −5.6^*^ | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of VR on pain-related functioning when compared to non-VR rehabilitation.
Pain Intensity or Severity; VAS | 2-7 days; N = 121; 2 RCTs^83,89^ | −3.5^*^ | −3.0^*^ | −0.5^*^ | ⨁◯◯◯; Very low^a,c^ | The evidence is very uncertain on the effect of VR on pain intensity when compared to non-VR rehabilitation.

Notes.

* Values for mean change in VR and comparator groups, and Diff. ∆ calculated from data reported in Jin, 2018.^83^

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations

a Downgraded 2 levels for study limitations (study rated high risk of bias).

b Downgraded 1 level for inconsistency (direction of effects inconsistent across studies).

c Downgraded 1 level for indirectness (pain only measured at 1 week post-surgery in 1 study; other study only reported medians).

Abbreviations. CI=confidence interval; Diff ∆=difference between groups in mean change scores; RCT=randomized controlled trial; VAS=Visual Analog Scale; VR=virtual reality; WOMAC=Western Ontario and McMaster Universities Arthritis Index.

### AR Interventions

Three trials evaluated AR physical activity interventions using Microsoft Kinect,^84,85,88^ while the other 2 trials used other AR sensor technologies that also monitored participant movements and displayed these in digital environments.^86,87^ AR intervention duration was 2 weeks to 4 months, and all 5 trials compared AR physical activity against usual care or standard rehabilitation. One study was conducted in the US,^85^ 1 in Asia,^88^ and the others in Europe.^84,86,87^ Studies included 52-306 middle-aged and older men and women (mean ages 53-73 years, 49-82% women). Three studies were rated some concerns for RoB due to a range of issues, including potential bias in outcomes assessment, concerns about adherence, and missing data.^85,87,88^ The other 2 were rated high RoB due to high drop-out and missing data.^84,86^

The evidence is very uncertain on the effects of AR physical activity interventions on pain-related functioning, pain intensity, and adverse events, compared with standard rehabilitation (very low COE, Table 21). Pain-related functioning was evaluated in 4 studies, using WOMAC, Oxford Knee Score (OKS), and Knee Injury and Osteoarthritis Outcome Score (KOOS).^84,85,87,88^ Outcomes at 3-4 months were inconsistent across studies. For example, Eichler, 2019^84^ found improvement in both groups at 3 months, with slightly greater reduction in WOMAC in the AR group (standardized Diff ∆ −0.29), but Prvu-Bettger, 2020^87^ showed slightly greater reduction in KOOS in the control group at 3 months (Diff ∆ −1.4).

Similarly, pain intensity was assessed in 4 trials using VAS or NRS, and there were inconsistent results across studies.^85–88^ While Janhunen, 2023^85^ and Shim, 2023^88^ reported greater reductions in pain intensity in the AR group (eg, standardized Diff ∆ −0.39 at 4 months),^85^ Piqueras, 2013^86^ showed greater reductions in the control arm at 3 months (standardized Diff ∆ 0.22). Prvu-Bettger, 2020^87^ found very similar improvements in both groups at 3 months using NRS (Diff ∆ 0.2) and using the VAS, assessed at baseline, 2 months, and 4 months. Both groups improved in VAS a similar amount (standardized Diff ∆ −0.39, p = 0.18). The Kinect group had a baseline mean score of 57.1 (SD 18.3) with mean reduction of 36.3 at 4 months, while the control group baseline mean was 54.2 (SD 21.6) and decreased by 26.7 over this time.

Only 1 trial reported on adverse events. Prvu-Bettger, 2020^87^ assessed the proportion of participants who experienced any falls during the 12 weeks post-discharge, finding 19% (27/139) of AR group and 15% (20/137) of the control group had this event. However, they did not attempt to determine if these falls were related to the treatment or another health condition. No other types of events or symptoms were assessed.

Two studies assessed quality of life. Shim, 2023^88^ reported EuroQoL-5D index scores at baseline, 3, 12 and 24 weeks. Both groups showed some improvement at follow-up, with no clear difference between groups. Eichler, 2019^84^ reported 36-item Short Form Survey (SF-36) physical and mental component scores (PCS and MCS, respectively) at baseline and 3-month follow-up. In both groups, PCS improved at 3 months but similarly there were no clear differences between groups (standardized Diff ∆ −0.04). The AR group mean baseline PCS was 33.8 (SD 7.6) with mean improvement of 10.7 at 3 months, while the control group baseline PCS was 33.3 (SD 7.9) with a mean improvement of 11.1 (SD 7.2). In both groups, MCS did not change at 3 months and there were no clear differences between groups (standardized Diff D ∆ −0.24). The AR group mean baseline MCS was 54.8 (SD 10.6) with a change of −2.5 (SD 12.4) at 3 months, while the control group baseline MCS was 53.9 (SD 11.8) with a change of 0.1 (SD 8.5).

All 5 trials evaluated physical performance using a variety of measures, including TUG, 6-minute walk, Short Physical Performance Battery (SPPB), and ROM at knee, among others. In general, there were either no differences in improvements between groups or slightly greater improvement in the AR groups, but there were also some inconsistent results. For example, Eichler, 2019^84^ found slightly greater distances for 6-minute walk in the AR group at 3 months (standardized Diff ∆ 0.16). However, while Janhunen, 2023^85^ showed greater reduction in times for TUG in the AR group at 4 months (standardized Diff ∆ −0.71, p = 0.04), Piqueras, 2013^86^ reported a greater improvement in the control group at 3 months (standardized Diff ∆ 0.51, p = 0.020).

Table 21 Certainty of Evidence: AR Physical Activity for Post-Surgical Pain and Rehabilitation

Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | Anticipated Absolute Effects | | | Certainty | What Happens
Outcome; Outcome Measure(s) | Follow-Up; No. of Participants (Studies) | AR Physical Activity | Comparator | Difference | Certainty | What Happens
Pain-Related Functioning or Interference; WOMAC; OKS; KOOS | 3-4 months; N = 525; 4 RCTs^84,85,87,88^ | 12.1^*^ | 9.8^*^ | Stand. Diff ∆: −0.32 SD^*^ | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of AR on pain-related functioning when compared to standard rehabilitation.
Pain Intensity or Severity; VAS; NRS | 4 months; N = 595; 4 RCT^84,85,87,88^ | −36.3^*^ | −26.7^*^ | Stand. Diff ∆: −0.39 SD^*^ | ⨁◯◯◯; Very low^a,b^ | The evidence is very uncertain on the effect of AR on pain intensity when compared to standard rehabilitation.
Adverse Events | 3 months; N = 276; 1 RCT^87^ | 19.4%^†^ | 14.6%^†^ | 4.8% more (2.6 fewer to 12.3 more)^†^ | ⨁◯◯◯; Very low^c,d,e^ | The evidence is very uncertain on the effect of AR on falls risk compared with standard rehabilitation.

Notes.

* Values for mean change in VR and comparator groups, and Stand Diff. ∆ from data reported in Janhunen, 2023.^85^ Pain-related functioning was assessed by OKS and pain intensity with VAS.

† Values are proportion with any falls for VR and comparator groups, and difference between groups from Prvu Bettger, 2020.^87^

GRADE Working Group grades of evidence

High certainty: We are very confident that the true effect lies close to that of the estimate of the effect.

Moderate certainty: We are moderately confident in the effect estimate: the true effect is likely to be close to the estimate of the effect, but there is a possibility that it is substantially different.

Low certainty: Our confidence in the effect estimate is limited: the true effect may be substantially different from the estimate of the effect.

Very low certainty: We have very little confidence in the effect estimate: the true effect is likely to be substantially different from the estimate of effect.

Explanations:

a Downgraded 2 levels for study limitations (studies rated some concerns and high RoB).

b Downgraded for inconsistent results across studies.

c Downgraded 1 level for study limitations (studies rated some concerns RoB).

d Downgraded 1 level for indirectness (authors only reported falls without assessment of cause, and no other adverse events).

e Downgraded 1 level for imprecision (confidence interval includes fewer events and substantially more events).

Abbreviations. CI=confidence interval; Diff ∆=Between-group difference in mean change scores (Intervention-Comparator); KOOS=Knee Injury and Osteoarthritis Outcome Score; NRS=numeric rating scale; OKS=Oxford Knee Score; VAS=visual analogue score; WOMAC=Western Ontario and McMaster Universities Arthritis Index.

## KQ2 OTHER CONDITIONS

Four studies (6 articles) evaluated XR interventions for a variety of pain conditions; these included 2 VR studies for neck pain^90^ and work-related injuries,^91^ and 2 AR studies, both for post-stroke rehabilitation.^92–95^ Trial characteristics and main findings are summarized in Table 22. Detailed characteristics and results are provided in Appendix K.

### VR Interventions

Sarig Bahat, 2020^90^ compared VR physical activity (Oculus Rift with a built-in 3D tracker, n = 22) to conventional physical therapy (n = 23) for flight-associated neck pain in Israeli pilots (mean ages 28-30, 95% men). Three different VR modules (ROM, velocity, and accuracy) were used to improve head control. Participants were asked to use the VR at least 5 minutes per day, 4 times per week for 4 weeks. This study was rated as some concerns RoB due to concerns with adherence to the intervention and missing outcome data. Pain-related functioning was assessed at baseline, post-intervention (4 weeks), and 7 months, but only medians (IQR) were reported. The NDI at 7 months was 9 (6, 18) for VR physical activity group and 18 (6, 26) for control group; baseline medians (IQR) were similar. VAS was used to assess average pain intensity during the past week at baseline, 4 weeks, and 7 months. The control group had greater reductions in pain (Diff ∆ 11.9 at 4 weeks, 11.6 at 7 months). Additionally, authors reported mean scores of various physical performance measures at baseline and 4 weeks (eg, ROM flexion and extension, isometric strength flexion and extension, global peak velocity).

Abd-Elsayed, 2021^91^ was a retrospective cohort study conducted in the US and included participants who used a VR psychological skills program for work-related injuries (and who were receiving workers’ compensation, n = 36). This study was rated as critical risk of bias due to presenting only uncontrolled pre-post results. This study also assessed self-reported use of opioids by participants.

### AR Interventions

Both AR studies evaluated AR physical activity interventions for post-stroke rehabilitation of upper limb functioning. The first study, Rodriguez-Hernandez, 2021a (and other articles),^92,93,96^ was conducted in Spain and compared exercises enabled by a variety of AR devices (Microsoft Kinect, Hand-Tutor glove, and 3D Tutor; n = 23) with conventional rehabilitation (n = 23). Both groups completed 150 minutes of therapy per day, for 5 consecutive days per week for 3 weeks. This study was rated high RoB due to concerns about deviations from intended interventions and missing outcome data. Quality of life was assessed with EuroQoL-5D (only domain scores reported) at baseline and 3 months. This study also assessed several physical performance measures, including the Fugl-Meyer Assessment-Upper Extremity and Action Research Arm Test.^93,96^ The AR physical activity group showed greater improvement on both physical performance tests, for example Diff ∆ 10.1 at 3 weeks and 8.9 at 3 months on the Fugl-Meyer Assessment.

The second study, Taveggia, 2016,^94^ was conducted in Italy and compared an AR physical activity program using Armeo Spring exoskeleton device (Hocoma Inc., Zurich, Switzerland) for sensing movements around the shoulder, elbow, and wrist joints and displaying these movements in a digital virtual environment (n = 27) with conventional rehabilitation (n = 27). Both groups received therapy for 1 hour per day, 5 days per week for 6 weeks. This study was rated some concerns for ROB due to concerns about deviations from intended interventions and missing outcome data. Pain-related functioning was not assessed. Pain intensity was measured using VAS at baseline, 6 weeks, and 12 weeks, showing that the AR physical activity group had greater reductions in pain intensity (Diff ∆ −1.1 at 6 weeks, −1.9 at 12 weeks). This study reported that no adverse events were detected in either group. Physical performance was measured with the Motricity Index, and the AR group showed greater improvements at follow-up (Diff ∆ 6.3 at 4 weeks, 37.9 at 7 months).

Table 22 Summary of Findings for KQ2 Other Conditions

Author, Year; Study Design; RoB; Country | Pain Condition; Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Outcomes
Author, Year; Study Design; RoB; Country | Pain Condition; Key Participant Characteristics | Intervention; N Randomized (N Analyzed); Setting; Duration | Comparator; N Randomized (N Analyzed); Setting; Duration | Pain-Related Functioning or Interference | Pain Intensity or Severity | Adverse Events & Other Eligible Outcomes
VR Intervention Studies
Sarig Bahat, 2020^90^; RCT; Some Concerns; Israel | Flight-associated neck pain; Air force pilots with average neck pain ≥20/100 on VAS during past week; mean ages 28-30 yr, 91% men | Exercises aimed at improving ROM, velocity, and accuracy using Oculus Rift; N = 22 (18); Home; 4 wk | Conventional physical therapy; N = 23 (17); NA; NA | NDI; Median (IQR):; Intervention:; Baseline—15 (12,22); 4 wk—10 (6,26); 7 mo—9 (6,18); Comparator:; Baseline—16 (10,20); 4 wk—16 (8,20); 7 mo—18 (6,26) | VAS; Baseline means (SD):; Intervention—36.4 (22.9); Comparator—49.5 (21.1); Diff ∆:; 4 wk: 11.9; 7 mo: 11.6^*^ | NR; Physical performance (4 wk); - ROM flexion, extension, rotation bilaterally; - Isometric strength flexors, extensors; - Global peak velocity, mean velocity, time to peak velocity, & accuracy
Abd-Elsayed, 2021^91^; Cohort; Critical; USA | Acute or chronic workplace and injuries receiving workers’ compensation; mean age 45 yrs, 56% female | Using PICO headset for modules on coping skills and pain education, and telephone consultations with range of clinicians; N = N/A (36); Home; 90 days | N/A | NR | VAS; Baseline mean: 6.0^†^; 12 wk mean: 5.4^†^; ∆: −0.6 | NR; Opioid use (90 day); - Proportion with increase or decrease in opioids, or cessation
AR Intervention Trials
Rodriguez-Hernandez, 2021a^92^; Rodriguez-Hernandez, 2021b^96^;Rodriguez-Hernandez, 2023^93^; RCT; High; Spain | Post-stroke rehabilitation; ≤ 6 mo since stroke, upper limb involvement, dependence in ADLs, absence of other serious and disabling pathologies; mean age 63 yr, 19% women | Microsoft Kinect, Hand-Tutor glove, and 3D Tutor devices for sensing and displaying movements to participants and therapists; N = 23 (23); Clinic; 3 weeks | Conventional rehabilitation; N = 23 (20); Clinic; 3 weeks | NR | NR | NR; Quality of life (3 mo); - European Quality of Life-5 dimensions (EuroQoL-5D) domain scores (mobility, selfcare, daily activities, pain/discomfort, anxiety/depression); Physical performance (3 mo); - Fugl-Meyer Assessment Upper Extremity; - Action Research Arm Test
Taveggia, 2016^94^; RCT; Some concerns; Italy | Post-stroke rehabilitation; 0.5-12 mo post-stroke (1^st^ episode), with self-reported functional impairments of upper extremity, no peripheral nerve injury or MSK condition of affected limb, no contracture or invasive treatment for spasticity in past 6 mo | Armeo Spring exoskeleton device for sensing arm and hand movements, displays movements in digital environment; N = 7 (27); Clinic; 6 weeks | Conventional rehabilitation; N = 27 (27); Clinic; 6 weeks | NR | VAS; Baseline means (SD):; Intervention: 4.5 (1.5); Comparator: 4.2 (2.0); Diff ∆:; 6 wk: −1.1^*^; 12 wk: −1.9^*^ | No adverse events reported in either group; Physical performance (3 mo); - Motricity Index

Notes.

* Diff ∆ calculated by review team, unable to standardize as no SD for change reported.

† No SD reported; these are means before using VR headset (article also reported post-use means and those were lower but had the similar change from baseline to 12 weeks, ∆ =−0.7).

Abbreviations. ADL=activities of daily living; AR=augmented reality; Diff ∆=difference in mean change scores; IQR=interquartile range; mo=month; MSK=musculoskeletal; N/A=not applicable; NDI=Neck Disability Index; NR=not reported; RCT=randomized controlled trial; RoB=risk of bias; ROM=range of motion; SD=standard deviation; VAS=Visual Analog Scale; VR=virtual reality; wk=week.