# METHODS

## TOPIC DEVELOPMENT

Collaboratively with representatives from VHA XR Network, VA PMOP, VA HSR, and our Technical Expert Panel, we defined the scope, formulated key questions (KQs), and determined eligibility criteria. We included a wide variety of technologies and types of XR interventions that may be used to treat various pain conditions.

## REGISTRATION AND REVIEW

A preregistered protocol for this review can be found on the PROSPERO international prospective register of systematic reviews (CRD42023439903 (https://www.crd.york.ac.uk/prospero/display_record.php?RecordID=439903)). A draft version of this report was reviewed by external peer reviewers; their comments and author responses are in Appendix L.

## KEY QUESTIONS AND ELIGIBILITY CRITERIA

The following key questions were the focus of this review: For adults, what are the benefits and harms of XR interventions for 1) treating chronic pain and 2) preventing the development of chronic pain? Study eligibility criteria are shown in the table below.

| Inclusion Criteria | Exclusion Criteria
Population | Key Question 1 (KQ1): Adults (≥18 years) with chronic pain, defined as a condition that has chronic pain as a major symptom (eg, arthritis, fibromyalgia, phantom limb pain, diabetic neuropathy) AND/OR assessed pain of ≥90 days duration; Key Question 2 (KQ2): Adults (≥18 years) with any pain | Children (<18 years)
Intervention | Extended reality (ie, augmented, mixed or fully immersive virtual reality) treatments with a primary aim of treating or preventing chronic pain | XR tools for providers; telehealth or virtual care that does not involve XR (only videoconferencing, etc); KQ1 only: XR interventions solely during surgery or other medical procedures
Comparator | Any | —
Outcomes | [underlined: Primary outcomes] *; Pain-related functioning or interference (PRO); Pain intensity or severity (PRO); Pain global change (PRO); Pain catastrophizing and kinesiophobia (PRO); Quality of life (PRO); Adverse events; [underlined: Secondary outcomes]; Opioid dose or use; Physical performance; Completion of medical treatments or adherence | —
Setting | KQ1: Non-acute care settings (eg, outpatient clinic, home); KQ2: Any | KQ1 only: Hospitalizations or emergency room visits
Study Design | KQ1: RCTs with N ≥ 30 and follow-up ≥ 1 day post-treatment; KQ2: Observational cohorts and RCTs with N ≥ 30 and follow-up ≥ 90 days | Commentary, case series, case reports, reviews; N < 30; KQ1 only: observational studies

Notes.

* To be eligible, study had to address at least 1 primary outcome.

Abbreviations. PRO=patient-reported outcomes; RCT=randomized controlled trial; XR=extended reality.

## SEARCHING AND SCREENING

We searched MEDLINE, Embase, CINHAL, PsycINFO, and Scopus databases from inception to May 2023, using key words and subject headings for virtual and augmented reality, exergaming, pain, and a variety of pain-related conditions (eg, neuralgia and fibromyalgia). See Appendix A for complete search strategies. We also hand-searched included studies of relevant systematic reviews identified via the database searches. We searched clinical trial registries (clinicaltrials.gov, Australian and New Zealand Trials Registry, European Union Trials Register, and www.isrctn.com) for recently completed and ongoing trials. For completed trials, we looked for publications associated with these trials using the protocol title, investigator names, and locations. Ongoing trials (without identified publications) are noted in Appendix C.

Duplicate search results were removed, and abstracts were screened using DistillerSR version 2.35 (Evidence Partners, Ottawa, Canada).^15^ Exclusion of abstracts required agreement of 2 reviewers. Included abstracts underwent full-text review by 2 individuals, with eligibility decisions requiring consensus of both reviewers.

## DATA ABSTRACTION AND RISK OF BIAS ASSESSMENT

Data abstraction was completed by 1 reviewer and verified by a second reviewer. Abstracted data included participant characteristics and inclusion/exclusion criteria, intervention characteristics (technology and devices used, content and goals of intervention), study design and settings, and findings for primary and secondary outcomes, as noted above. If findings were only reported in figures, we used PlotDigitizer (https://plotdigitizer.com/app) to derive numbers from figure images, per recommended practices.^16^

Using reported intervention characteristics, we classified interventions as VR or AR according to the proposed framework by Rauschnabel et al.^10^ Additionally, we coded the type of XR intervention into 4 categories based on intervention content and goals:

1) Pain psychology and coping skills (referred to as “psychological skills” hereafter)
2) Guide and engage in physical activity
3) Embodiment only
4) Distraction only.

Risk of bias (RoB) assessments were conducted independently by 2 researchers, and discrepancies were resolved by consensus or with a third reviewer. RCTs were assessed with Cochrane Risk of Bias 2.0^17^ and observational studies with the Cochrane Risk Of Bias In Non-randomised Studies - of Interventions (ROBINS-I).^18^ RoB ratings (including domain ratings) are provided in Appendix D.

## SYNTHESIS

We first grouped studies by pain condition (eg, chronic back pain, knee pain) and then by intervention characteristics. We separately examined studies of VR and AR interventions and then by type of intervention (eg, pain psychology and coping skills, or guiding and engaging in physical activity). We conducted meta-analyses when there were ≥3 studies for a given pain condition that evaluated sufficiently similar interventions and reported the same outcome (eg, comparable measures of pain-related functioning or interference). Otherwise, we provided narrative syntheses of study characteristics and findings. For meta-analyses, we used random-effects models (with Hartung–Knapp-Sidik–Jonkman estimator) due to the anticipated heterogeneity in effects arising from variation in patient populations, clinical settings, and other study characteristics. We focused on between-group comparisons of the mean change in continuous outcomes (ie, difference in change scores [Diff ∆]), preferentially as standardized effect sizes (Diff ∆/standard deviation [SD] of change). To calculate Diff ∆, we subtracted the mean change in the comparator group from the mean change in the XR intervention group (∆_XR_ - ∆_C_); thus, for outcome measures where lower scores are better (eg, pain intensity or severity), a negative value for Diff ∆ indicates that there were greater improvements in the XR intervention group. When SDs of change scores were not reported, we used imputation techniques to estimate SD using data from other sufficiently similar studies, when these were available. As described in the Cochrane Handbook for Systematic Reviews of Interventions,^16^ we calculated the correlation coefficients for mean change and SD of change scores using data from studies that provided all data, and used these correlation coefficients to impute the SD of change scores from the reported mean change (or calculated mean change, using baseline and follow-up mean scores). We evaluated for statistical heterogeneity using visual inspection, τ^2^, and 95% prediction intervals (PI). We planned to assess publication bias using funnel plots if there were ≥10 sufficiently similar studies (according to considerations described above). We used meta and metafor packages and R version 4.3.1 (R Foundation for Statistical Computing, Vienna, Austria)^19^ to conduct meta-analyses and generate forest plots.

### Certainty of Evidence

For certainty of evidence (COE) assessments, we prioritized 3 primary outcomes with input from Operational Partners and Technical Expert Panel members. Before analysis and synthesis of eligible study findings, we met with partners and the expert panel to discuss prioritization of outcomes for COE assessments and then conducted an online survey requesting feedback on the top 3 outcomes in importance (ie, indicate which primary outcome is first, second, or third, from among the 6 eligible primary outcomes). The top 3 prioritized outcomes were pain-related functioning or interference, pain intensity or severity, and adverse events. We rated COE for each prioritized outcome separately for types of VR and AR interventions for the following pain conditions: chronic low back pain, chronic neck pain, fibromyalgia, chronic knee pain, and post-surgical pain and rehabilitation (KQ2). We used Grading of Recommendations, Assessment, Development, and Evaluation (GRADE) methodology to rate overall COE as high, moderate, low, or very low.^20,21^ Briefly, for each prioritized outcome, we used GRADEpro Guideline Development Tool (GDT)^22^ to systematically evaluate 5 domains: study limitations (risk of bias), imprecision (limitations in precision of effect estimates), inconsistency (in direction and magnitude of effects across studies), indirectness (applicability of the results), and other considerations (including publication bias).