# BACKGROUND

Chronic pain is prevalent among United States (US) Veterans. In 2021, the age-adjusted prevalence of chronic pain among US adults was 27.5% for Veterans and 19.2% for non-Veterans, with 11.6% of Veterans and 6.5% of non-Veterans reporting that their pain resulted in frequent functional limitations in daily life or work activities.^1^ Non-drug therapies (eg, exercise and psychological interventions) are first-line treatments for common pain conditions due to their evident benefits and low risks, particularly as compared to opioids and invasive procedures.^2–5^ Accordingly, Veterans Health Administration (VHA) initiatives have emphasized use of non-drug therapies to improve chronic pain management and decrease inappropriate opioid prescribing. The VHA Directive on Pain Management (#2009-053)^6^ also mandated national implementation of a multimodal stepped care model that would enable timely access to evidence-based non-drug therapies, among other features. Effects of non-drug therapies may vary across common pain conditions and patient characteristics. For example, while targeted exercise is generally effective for chronic low back pain,^7^ integration of psychotherapy techniques with exercise may be needed for maximal benefit in those with high fear of movement (ie, kinesiophobia).^8^ Outcomes of non-drug therapies may also differ depending on whether they are used to treat established chronic pain (eg, chronic low back pain) or to prevent the development of persistent or chronic symptoms from acute pain (eg, post-surgical pain management and rehabilitation). Additionally, non-drug treatments often require long-term adherence to yield maximum benefit, making patient engagement a key factor in effectiveness over time.

Extended reality (XR) is a spectrum of digital technologies and software that serve as modalities for delivering different types of interventions for pain, such as teaching pain self-management psychological skills or guiding engagement in physical activity.^9,10^ A user’s level of immersion in the XR digital environment is used to define categories within the XR spectrum.^10^ Virtual reality (VR) has the highest level of immersion in an interactive, fully digital environment: for example, relaxation training in a digitally created peaceful forest that is separate from the user’s real-world physical environment. Augmented reality (AR) provides partially immersive user experiences by augmenting depictions of real-world physical environments with digital elements or translating user activities into the digital world. For example, an AR intervention may involve visualizing a simulated digital leg on real-time video of the user’s physical body to facilitate rehabilitation after amputation. Like VR, AR can also incorporate sensors to monitor participant movements and translate these into actions in digitally created worlds, as in gaming systems such as Microsoft Kinect and Nintendo Wii. With the increased availability of low-cost XR devices and widespread popularity of these technologies, interest in a broad range of XR clinical applications has also grown.

Although XR interventions have been implemented in clinical settings for a range of health conditions, including acute and chronic pain treatment,^11^ the ways in which XR contributes to therapeutic change remain under investigation and likely vary by type of intervention (eg, building mindfulness skills vs performing targeted exercises). The use of XR to decrease acute pain through distraction is well documented (eg, during dental treatment or other procedures that cause pain).^12^ For treatment of chronic pain and rehabilitation, distraction may enable participation in recommended exercises, leading to better engagement and adherence. Some have also proposed that XR technology can specifically facilitate embodiment (the perception of one’s body as comprising both digital and real-world elements), a potentially important mechanism for addressing conditions like phantom limb pain.^13^ However, it remains unclear whether XR interventions can improve outcomes across different common chronic pain conditions, and if so, how they should be integrated into a comprehensive plan for pain treatment. As the field continues to expand and diverse XR interventions are developed, understanding the current evidence for effects of XR pain therapies is critically needed to guide future implementation efforts and further research to address knowledge gaps.

The VHA’s XR Network is a nationwide resource hub for dissemination and pilot testing of XR technologies across VHA facilities; current pilots of XR interventions for pain are occurring in post-operative care, Community Living Centers, and various outpatient settings.^14^ To inform future research on XR interventions for pain and implementation of XR treatments at VA facilities, the VHA XR Network, in collaboration with VA Health Systems Research (HSR) and VA National Pain Management, Opioid Safety, and Prescription Drug Monitoring Program (PMOP) Office, requested this evidence review on the benefits and harms of XR interventions for chronic pain.

In this systematic review, we synthesized evidence on benefits and harms of XR interventions for treatment of chronic pain or to prevent development of chronic pain (if treating acute pain). We present findings by pain condition, beginning with chronic low back pain and chronic neck pain, followed by other conditions. Within each condition, we provide results separately for VR and AR interventions, and then types of XR interventions (and comparators) within these categories. We conducted meta-analyses where feasible and provide qualitative summaries otherwise.