# APPENDIX L PEER REVIEW COMMENTS AND RESPONSES

Comment # | Reviewer # | Comment | Author Response
Are the objectives, scope, and methods for this review clearly described?
1 | 2 | Yes | Thank you.
2 | 3 | Yes | Thank you.
3 | 4 | Yes | Thank you.
4 | 6 | Yes | Thank you.
5 | 7 | Yes | Thank you.
6 | 13 | Yes | Thank you.
Is there any indication of bias in our synthesis of the evidence?
7 | 2 | No | Thank you.
8 | 3 | No | Thank you.
9 | 4 | No | Thank you.
10 | 6 | No | Thank you.
11 | 7 | No | Thank you.
12 | 13 | No | Thank you.
Are there any published or unpublished studies that we may have overlooked?
13 | 2 | No | Thank you.
14 | 3 | Yes - Garcia et al., 2021 (doi:10.2196/26292); Garcia et al., 2022a (doi: 10.1016/j.jpain.2021.12.002); Garcia et al., 2022b (doi:10.2196/37480); Maddox et al., 2023 (doi: 10.1016/j.mcpdig.2023.09.003; Perhaps outside of the scope of the review, but interesting study on VR Cybersickness: https://doi.org/10.3389/frobt.2020.00004 | The 3 articles by Garcia et al. report results of the RelieVRx trial for low back pain and are already included in the report (see Results on Chronic Low Back Pain, eg, Table 2). The fourth article by Maddox et al. was published in December 2023, about 6 months after our search date. We added a reference to this newly published study in Appendix C (Ongoing Studies) and also refer to it in the Discussion (Evidence Gaps & Future Research).; We appreciate reviewer’s suggestion of the article on etiology of gender differences in VR Cybersickness. Although it is not eligible (as it is not evaluating effects of XR interventions for an eligible pain condition), it provides important information about evaluation of VR side effects and potentially how to mitigate some of these in future interventions. We have added the results from this reference to the Discussion (Evidence Gaps & Future Research).
15 | 4 | No | Thank you.
16 | 6 | No | Thank you.
17 | 7 | No | Thank you.
18 | 13 | No | Thank you.
Additional suggestions or comments can be provided below.
19 | 2 | Overall this is every good and I’m sure a reflection of what is available given the rigor of the review. A couple of comments for consideration. I would ensure that citations are used in the intro to support claims made (think I only saw 1 in the exec summary and number of statements made that should have been cited). I would also consider not making a positive statement about possible benefit and then in the same sentence seemingly de-qualifying it with “but there was limited info on adverse events.” I understand this was a significant miss across studies, but it would also be helpful to be clear about the potential good that was seen. | The Executive Summary usually does not contain citations, to help keep the content concise and to avoid complications with reference management (eg, references in the Discussion may then precede those for the eligible studies, which may not be individually named in the Summary). The Executive Summary content is a high-level summary of statements and findings in the full report, where all appropriate citations are included. We have also carefully reviewed the Introduction and Discussion sections of the main report for adequate citation of references.; We organized the Key Findings using the same structure as the Results sections in the main report. Thus, we briefly summarize the evidence addressing various XR interventions and the findings for different outcomes for each pain condition. Within this structure, the findings for adverse events are generally in close proximity to the benefits of each intervention type (per pain condition). Additionally, we emphasize the lack of evidence on adverse events across all the pain conditions and interventions in the Key Findings because this is an important consideration for clinicians and patients when selecting treatments: side effects are often the reason that treatments are declined or stopped. In the rest of the Executive Summary, as well as in the main report, the findings for each outcome (per intervention and comparator pairing for each pain condition) are laid out in greater detail, and these sections are much more focused on the benefits. This was largely due to eligible studies infrequently reporting adverse events.
20 | 3 | Page IX, Lines 15-16; - How were the prioritized primary outcomes of interest determined (e.g., a priori, ad hoc)? | Prioritization of the primary outcomes for GRADE assessments was discussed with Operational Partners and Technical Expert Panel members, and additional information was collected via an online ranking exercise. We clarified in the Executive Summary the stage at which this prioritization occurred (p. viii) and have added more information about this process to the Methods section in the main report (p.11).
21 | 3 | Page X, Lines 35-37, 42-44; - In lines 35-36, when discussing the direction of the effects the authors state “AR physical activity v. any active comparator”.; ○ To me, this could leave the reader to assume the standardized mean difference (SMD) = MAR – MControl / SD of change.; ○ Thus, SMD = −.7 (−1.2, −.2) indicated that mean reduction in pain intensity is larger in comparator groups is than AR (before accounting for uncertainty).; - Then in lines 42-44, the authors state that “AR physical activity may result in better pain-related functioning (eg, Diff ∆ −0.4 on Roland-Morris Disability Questionnaire), when compared with usual care…”; ○ To me, this now indicates that the standardized mean difference (SMD) = MControl – MAR / SD of change.; ○ To orient the reader, I think that the general equation posted in page 6 (line 12 = Diff ∆ /standard deviation [SD] of change) should be expanded upon to orient the reader whether positive/negative effects size point estimates and confidence intervals reflect the AR/VR or control conditions. | We have clarified the calculation of the Diff ∆ (and standardized Diff ∆) in both the Executive Summary (p. viii) and the main report Methods (p.11). The reviewer is correct in the direction of the comparison; however, improvement is reflected by lower scores for most of the outcome measures (including NRS, VAS, and Roland-Morris Disability). For outcome measures where lower scores reflect an improvement (eg, less pain or less disability), the negative value for Diff ∆ indicates a greater improvement in the XR intervention group. The reverse would be true for measures where higher scores are better but this was uncommon; we have described in greater detail when there are such findings in the main report. Additionally, the direction of comparison in pooled analyses are also indicated on the forest plots in the main report (when meta-analyses were conducted for that outcome).
22 | 3 | Page XI, Lines 19-26; “Five trials evaluated XR interventions for chronic knee pain due to osteoarthritis, and all compared XR physical activity programs (1 VR, 4 AR) with conventional exercises and rehabilitation. The single trial on VR physical activity showed greater improvement in pain-related functioning and pain intensity in the VR group (eg, Diff ∆ −5.1 on the Western Ontario and McMaster Universities Arthritis Index [WOMAC] and −1.1 on VAS 0-10 at 7 weeks). This trial did not address adverse events. The evidence is very uncertain on the effects of AR physical activity on pain-related functioning, pain intensity, and adverse events.”; - No mention of the AR studies or aggregate XR effects? | We have added a summary of AR study results to the Executive Summary (p. x).
23 | 3 | Page 9, Lines 33-37; - Were studies inly specified if they had a specified population (e.g., chronic low back pain, fibromyalgia) versus chronic pain in general regardless of type? If studies were chosen with non-specific chronic pain populations, how please describe how the data from participants were handled in the study. | For KQ1 eligible studies, the included population could comprise individuals with an eligible condition with pain as a primary symptom (eg, fibromyalgia), individuals with a mixture of these eligible conditions, and/or individuals with chronic pain symptoms directly assessed in the study (eg, pain in 2 or more joints for at least 3 months). In the KQ1 Other Conditions subsection, we report results for those pain conditions (or other chronic pain) with only 1 identified eligible study (pp. 54-62). For example, this subsection includes 1 study evaluating AR intervention for participants with chronic pain in multiple joints, as well as 1 study examining VR intervention for individuals with either chronic low back pain or fibromyalgia. Since this latter study did not provide results broken down by each condition, we were not able to include its findings under the sections for low back pain and fibromyalgia, respectively. We clarified these groupings in the Results Overview (p. 2).
24 | 3 | Page 11, Lines 17-19; - Please provide additional detail KQ1 to describe imputation methodology used to estimate missing standard deviations of change scores. | We added to the Methods a description of the imputation method we used, which was recommended by the Cochrane Handbook for Systematic Reviews (p. 11).
25 | 3 | Page 12, Lines 11-52; - Why are n’s in the flow diagram blank? | The literature flow diagram was not produced for the draft report. It has been completed for the final report.
26 | 3 | Page 13, Lines 5-8; - It was stated that 70 eligible articles reported 59 primary studies. Given the very specific methodology (e.g., RCTs for KQ1), please explain how there more eligible articles than primary studies? | Eligible studies could have multiple articles reporting the findings and this is described in greater detail within each Results subsection. For example, the 5 articles reporting results for RelieVRx for chronic low back pain are described in the Results subsection on chronic low back pain (pp. 21-23) and also cited in Table 2 (pp. 17-19).
27 | 3 | Page 16, Lines 17-18; - Table 2 is repeated twice: “Study characteristics and findings for VR interventions are summarized in Table 2Table 2.” | This has been fixed.
28 | 3 | Page 16, Lines 33-35; - This may be beyond the scope of the review, but in the description of single studies comments such as below read as very vague without further details which were also not provided in the cited appendix (E):; - “The study was rated as high RoB due to concerns about randomization, adherence to the intervention, measurement of outcomes, and the selection of reported results”. | We rated RoB using the Cochrane RoB2 (for RCTs) or ROBINS-I (for observational studies). In the text and Appendix E, we summarize and provide detailed ratings for each domain addressed by these standardized assessments. Each domain is evaluated through several items, and the number of items may vary depending on the response to preceding items. As the RoB assessment involves answering a potentially large number of questions, we do not customarily report all the response to these items for each study rating. For example, the study cited here (Yilmaz Yelvar 2017) was rated high risk of bias for the domain of randomization because neither the randomization nor the allocation procedures were described, and there were substantial differences between intervention and control groups in baseline characteristics. Overall, the RoB assessment for Yilmaz Yelvar, 2017 involved 20 items.
29 | 3 | Page 20, Lines 33-36; - Error with referencing software?; “The evidence is also very uncertain on the effect of VR embodiment on pain-related functioning and pain intensity, compared with other VR experiences (very low COE; Error! Not a valid bookmark self-reference.)” | This has been fixed.
30 | 3 | Page 22, Lines 30-33; - The statement below reads as if many severe events were reported across conditions, and that no serious adverse events were reported across conditions. Please clarify.; “Eccleston, 202225 reported a range of adverse events, finding for example that severe adverse events (symptoms leading to inability to perform daily or work activities) were relatively common: 50% of participants experiencing any severe events in the VR psychological skills group, 29% in VR control, and 36% in usual care. No serious adverse event was reported in any group.” | We have added the definition of “serious adverse events” (any event leading to death or serious deterioration in health) to clarify that these are actually more severe than the AE described as “severe” in these studies (p. 22).
31 | 3 | Page 23, Lines 8-10; - The AR for back pain section begins by introducing a comparison to active physical activity interventions then a comparison to usual care. Why is the VR for back pain not aligned with similar comparisons (in the previous section)? | For eligible studies examining the same pain condition (eg, for chronic low back pain or fibromyalgia), we grouped VR and AR interventions first by intervention type, and then within each intervention type, by comparators, when these were thought to be substantially different. Studies of VR interventions for low back pain evaluated different intervention types (embodiment and psychological skills). Within each of these 2 intervention types, there were a range of comparators, which are described in greater detail in the VR results subsection. Similarly, the AR section is broken down first by intervention type (in this case, all AR studies evaluated physical activity interventions) and then by comparators. The VR and AR subsections are different because the studies evaluated different interventions and comparators.
32 | 3 | Page 41, Lines 23-26; Page 52, Lines 46-47; - When discussing the effects of VR v. non-VR physical activity on pain catastrophizing the authors state that all 3 studies used the Tampa Scale of Kinesiophobia. This is puzzling given the noted distinction between these construction in the empirical literature.; ○ Sullivan et al. (2001) often cited definition describes pain catastrophizing as an ‘exaggerated negative mental set brought to bear during actual or anticipated experience of pain’.; ○ Influential papers by Kori et al. (1990) and Vlaeyen et al. (1995) define kinesiophobia (or fear of movement) as “an excessive, irrational, and debilitating fear of physical movement and activity resulting from a feeling of vulnerability to painful injury or re-injury”.; - The influential Fear-Avoidance Model for Chronic Pain identifies pain catastrophizing as an important predictor of precursor factor in pain-related fear and avoidance. Studies often report a fair to moderate correlation between these two constructs. I am curious to the rationale of the authors decisions. | We agree that kinesiophobia and pain catastrophizing are distinct, though related, concepts that are variably correlated. Our goal was to evaluate the impact of XR interventions on negative perceptions (of potential pain triggers) that contribute to poor outcomes -- particularly fear of movement, pain catastrophizing, or both. To ensure we accurately represent the full scope of XR effects on pain-related outcomes, we intended to be inclusive in selecting eligible outcomes. We have revised the description of this outcome to “pain catastrophizing and kinesiophobia” and have clarified the naming of specific findings regarding these concepts throughout the Results.
33 l | 3 | Page 44, Lines 43-44; - Typo: “Villafaina, 201957) used 0-100 scale and showed greater improvement in the AR group immediately post-intervention at 6 months (Diff ∆ −11.1).” | This has been fixed.
34 | 3 | Page 55, Lines 26-28; - Typo: “Pain-related functioning was assessed with BPI-Interference at baseline, 1 month and 3 months, showing slightly greater reduction in the VR psychological skills group (Diff ∆ −1.0 at 1 month and −1.6 at 3 monhts). | This has been fixed.
35 | 3 | Page 66, Lines 25-27; - Formatting error: “Prvu-Bettger, 202085 found very similar improvements in both groups at 3 months, using NRS (Diff ∆ 0.2). and using the VAS assessed at baseline, 2 and 4 months.” | This has been fixed.
36 | 3 | Page 72, Lines 32-33; Page 73, Lines 24-26; - The authors state that “VR psychological skills may have some benefit for chronic low back pain, but this was not compared with an active treatment.” I found this to be an inaccurate statement. Specifically, in the Darnall et al. (2020) paper the authors cite, they comparison group is an audio only version of the same psychological skills intervention. To me, this can be interpreted as an active control group, albeit non-XR (as noted on page 73, lines 21-24). Furthermore, in a follow-up RCT by the same group (see Appendix L for recommendation), they compared 3D VR to sham VR (2D) versions of the same program.; ○ The authors claim “For XR physical activity and psychological skills interventions, a proposed mechanism for enhanced benefits is increased patient engagement, so it would be important to compare to the non-XR versions, and also directly compare measures of engagement and adherence.” Again, in the Darnall trial, the authors report the number of VR sessions completed by the intervention group compared to the audio-only (non-XR) control group. This can be taken as a measure of adherence in interpreting these findings. | The Darnall 2020 study included individuals with self-reported low back pain or fibromyalgia, but did not provide results separately for each condition. This study also did not report the number of individuals with each condition by treatment arm. We were thus unable to include this study’s results in either the low back pain or fibromyalgia section. Of the 7 studies evaluating an XR psychological skill intervention (for any condition), the Darnall 2020 study was also the only one to use an active comparator. We have revised the Discussion paragraph describing the importance of comparing XR interventions with analogous non-XR treatments, to highlight that this is a particular gap for XR psychological skills interventions (XR physical activity interventions typically were compared with non-XR physical activity). In this paragraph, we also added a sentence highlighting there was 1 study (ie, Darnall 2020) that did this for VR psychological skills (p. 74).
37 | 3 | Page 74, Lines 34-35; - Given the limited reporting of adverse events noted by the authors, any specific recommendations for reporting adverse events, measuring, or comparing adverse effect across interventions in VR trials? | We have added recommendations for evaluation and reporting of adverse events to the Discussion (pp. 74-75).
38 | 4 | First and foremost, the report is very exhaustive and comprehensive. It takes a lot of effort to put this kind of analyses together and present them in a meaningful and compelling manner. The report is both educative and forward looking, addressing the research and evidence gap and future directions for research. The structure of the report is another aspect to be appreciated: providing an overview, detailed analyses, and following it up with the Appendices that provide the information for the curious ones.; With that being said loud and clear, I have to raise an important aspect. While XR in its different avatars as VR and AR has been around for a while, but the wide spread adoption is not really at the same level as a cell phone or laptop. This (the lack of widespread adoption) could lead to a “digital divide” in the population experiencing pain, not necessarily due to economic background, but due to technology acceptance.; In this context, I should say I am disappointed about Appendix D on Risk of Bias Assessments in the sense that the biases listed are mostly on the processes used for study design and outcome ana analyses. There is no report (in Appendix D) that can throw light whether the conducted studies have identified the technology literacy level nor the technology acceptance level. Did the studies collect data and report for:; 1. What was the level of the participants’ knowledge and comfort in using XR: high/medium/low/poor?; 2. What was the level of technology acceptance in using XR: high/medium/low/poor?; 3. Do the studies attempt to correlate the outcomes with respect to the answers for (1) and (2)?; To me, the answers to the above questions are really important, perhaps even more important than the outcome of XR interventions for chronic pain. Simply because, the outcomes *might* heavily depend on answers for (1) and (2). Unlike other psychotherapy interventions where the level of technology might be less intrusive or “low”. The only factor in the report that I could see closely related is the tracking of “adverse events” pertaining to motion / VR sickness - which in my opinion is not really the same as (1) and (2).; Another disappointment was that these factors (1) and (2) are NOT highlighted in the “EVIDENCE GAPS & FUTURE RESEARCH” section (Page 72, from Line 53). Of course, there is a passing mention of “barriers to technology adoption” in Page 74, Line 27. But this is mentioned only with respect to older adults - for future research.; To make my view clear, the point I want to convey is that reluctance to “accept” a technology - as a means for intervention - can *potentially* have a significant impact on the outcomes - and this needs to be studied along with other factors. The acceptance - or lack of it - of technology need not be due to economic or literacy factors alone, in my view. Another important thing is that this “acceptance” could change during the study period: one could be highly enthusiastic initially and might get bored quickly, and vice versa. A systematic study on technology acceptance and its impact on the outcomes is therefore needed. | Thank you.; We agree that technology literacy and acceptance are distinct, and it is likely that both are key components of patients’ experience (and uptake) of XR interventions. These factors also likely impact commonly proposed XR mechanisms of action, such as increased patient engagement with exercise. As with other proposed XR mechanisms of action, however, the relationship of XR to patient engagement appears understudied, and evaluation of relevant mechanistic indicators was beyond the scope of this review. We also agree that a systematic review of technology acceptance and its influence on XR outcomes would be useful – although our experience with the current review suggests that there are likely few studies that have rigorously addressed technology literacy and acceptance using a randomized design. We have revised the Discussion to highlight the need for improved understanding of these factors (p. 74).
39 | 6 | The draft review is a very nicely organized review that follows a clear and standard method to describe the current state of the evidence base. It provides a rationale for not including case studies and similar types of reports that are of the type that are commonly found in a relatively new intervention. It points out the VHA XR Network which is an important resource for readers of this review. It notes the important limitations in research quality that limits the ability to determine the effectiveness of these novel interventions. It describes possible mechanisms and gives guidance for improved research methods to help determine if these mechanism are present and to what degree XR could be a useful adjunct or alternative to more standard treatments. This is careful and helpful review. Its primary benefit is noting current limitation and providing guidance on what will improve the evidence base. Also appreciate the authors wish to be inclusive and the acknowledgement that it can be difficult to categorize XR, i.e., AR vs VR. These issues and the rationale were stated nicely. The appendices are also excellent resources for understanding the reviewed studies. | Thank you.
40 | 6 | The authors are encouraged to be cautious in statements like “XR has great potential as part of a comprehensive plan for pain treatment.” page 74, line 18. I share this enthusiasm but am also informed by the draft review which indicates that the current research does not provide reliable guidance on the potential for XR. It may have great potential but the limitations in CoE that are the primary theme of this review do not support the word great. Similarly, stating that XR may be helpful for some conditions but not others, page 74, lines 36-38, should be restated with more care since the problems noted in Page 74, lines 34-35 suggest that such comparisons probably should not be made at this point. | We have changed this sentence to state “considerable potential”. Regarding the statements in the Conclusion, the use of “may” is consistent with the low CoE assessments for XR physical activity interventions for neck pain, which takes into consideration the methodological concerns noted in the beginning of the Conclusion. However, we have corrected the statement for low back pain to “the evidence is very uncertain,” which is more consistent for the very low COE for low back pain (p. 76).
41 | 6 | Pain Catastrophizing: For the most part, in the draft manuscript Pain Catastrophizing is used to refer to both catastrophizing and kinesiophobia. Table 2 Page 17 lines 22-24 has Outcomes column label Pain Catastrophizing & Kinesiophobia (both the TSK and FABQ can be considered measures of kinesiophobia. This table label is correct in that the two are related but not perfectly correlated and can have independent predictions and treatment indications. It would be helpful to note early in the main text that Pain Catastrophizing is being used as a general term to cover both related concepts as indicated in the Table 2. | We have further clarified the inclusion of these 2 related concepts and revised the report accordingly, as noted above in our response to comment #32.
42 | 6 | The reviewed copy is a draft. Recommend further proofing to correct some typos, grammar and similar issues. | We have carefully copyedited the final draft.
43 | 13 | This is an interesting and well-conducted review on an important topic. The limited evidence and paucity of robust studies on XR interventions for chronic pain is for me admittedly rather surprising and somewhat disappointing. Given what appear to be fundamental gaps related to the efficacy, effectiveness and adverse events associated with XR, I was also a bit surprised by some of the discussion about implementation as part of future research. Nonetheless, while some aspects related to implementation may be premature, I don’t disagree that it is important to consider implementation, including user-centered design approaches and implementation context, while establishing the efficacy/effectiveness of XR interventions for chronic pain. | We agree that implementation of XR interventions for several pain conditions may be premature given the state of the evidence. However, implementation science frameworks may still be helpful by clarifying the role of XR as core intervention component vs. means of intervention delivery and engagement. Additionally, implementation science can help with evaluating real-world effectiveness and costs of XR interventions, when health systems (such as the VA) have begun to offer these interventions. We have revised the Discussion to reflect these points (pp.75-76).
44 | 13 | Minor issues, mostly typos that may have already been identified; Page vii, Key Findings section. Use of the phrase “effects on adverse events” is a bit awkward and potentially confusing. While perhaps technically correct, the issue is whether these interventions might cause or lead to adverse events, which based on the findings of this review appear to be very uncertain or in many cases unreported and it would be helpful if this were more clearly stated, at least in presenting the key findings. | We have revised this phrase in the first Key Finding to “the evidence for adverse effects is very uncertain” (p. vi).
45 | 13 | Page x, line 49 would suggest rephrasing “but the evidence about adverse events is very uncertain …” | We have revised this phrase to “the evidence for adverse effects is very uncertain” (p. x).
46 | 13 | Page 16, line 18, Table 2 is repeated | This has been fixed.
47 | 13 | Page 17, Table 2, line 49, for Kammler-Sucker outcomes it would be helpful to the reader if the two NRS measures had more distinct labels, e.g., pain-interference NRS and pain intensity NRS | We have clarified the labeling of NRS for these 2 outcomes in Table 2.
48 | 13 | Page 20, line 35, flagging error and line 41 I believe the word environment is missing after immersive | This has been added.
49 | 13 | Page 22, line 34, should be assessed rather than assess and lines 55-56 quality of life is repeated | These have been updated.
50 | 13 | Page 24, line 32, word activity is missing after physical | This has been added.
51 | 13 | Page 26, Table 6, line 61 typo for percentage in the second column (496%), perhaps 46% or 49% | This typo has been corrected.
52 | 13 | Page 28, Table 6, line 33, word aged in second column (describing male university student sample) should be deleted | This has been fixed.
53 | 13 | Page 34, several minor typos, line 18 missing period, line 23 missing word to after due and line 30 the word these can be deleted and the sentence start with “All showed …” | These have been updated.
54 | 13 | Page 53, line 28, capitalize VAS | This has been fixed.
55 | 13 | Page 66, line 26 there appears to be in advertent period and extra space | This has been fixed.
56 | 13 | Page 67, section on KQ2 Other Conditions, the citations are not suprascript | This has been fixed.