# APPENDIX K KQ2 OTHER CONDITIONS

Appendix Table K1 Detailed Characteristics for Included Trials on KQ2 Other Conditions

Author, Year; Risk of Bias; Follow-Up Duration; Site(s); Funding Source | Inclusion/Exclusion Criteria | Intervention: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Intervention Characteristics | Comparator(s): Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Comparator Characteristics | Primary Outcome; Eligible Outcomes & Measures Reported (Time Points); Other Non-Eligible Outcomes Reported
VR Intervention
Abd-Elsayed, 2021^91^; Critical; 12 weeks; Harvard MedTech Vx Pain Relief Program; N/A | Inclusion: “All adult patients aged 18 to 65 treated from April 2019 to April 2020 for acute or chronic workplace injuries and were on workers’ compensation were retrospectively identified for inclusion. All patients were referred to and overseen by a prescribing physician and referred to the Harvard MedTech Vx Pain Relief Program by orthopedic specialists, pain specialists, primary care physicians, and occupational health providers. All types of workplace injuries were considered…”; Exclusion: “…patients were excluded if their attorney required them to discontinue therapy. Patients were also excluded if they attended less than five in-person behavioral therapy sessions with their behavioral health clinician, as this would indicate possible poor compliance with the Harvard MedTech Vx Pain Relief Program.” | N=36; Age, mean (range): 45 (20-65); Female: 56%; Home; At least 1 to 2 times daily for 45 min each, over 90 days (~12 weeks); “During headset use, patients selected specialized categories, or experiences, pre-loaded onto the headset to target either the knowledge of pain, meditation techniques, escape from pain, or distraction from pain. The choice to view a specific category of VRT was based on weekly phone calls between the physician and patient. For the tailored behavioral therapy component of the program, patients and clinicians discussed their progress with headset use (all outcomes re-reassessed) and the goals of therapy for 30–60 min each week and set three specific goals for the patients care. The goals could be related to pain reduction, sleep improvement, behavioral health, or social well-being. Any adjustments in therapy were also made at this meeting (as previously discussed). The patient’s clinician directed the program, ensured compliance, and also provided further education on how to generalize the skills acquired by the virtual reality headset.” | -- | Primary: Average pain relief, measured through the VAS (0-10); Pain intensity/severity; - VAS; Opioid use; - Self-reported opioid use; Non-eligible: Anxiety awareness and level of immersion in therapy, patients’ perception of set goals being achieved, sleep improvement, average time thinking about pain
Bahat, 2020^90^; Some concerns; 7 months; Israeli Air Force; IDF-Medical Corps’ research grant | Inclusion: “…fighter and helicopter pilots from the Israeli Air Force with acute, subacute, or chronic neck pain; with or without referral to the upper limbs; and with an average neck pain intensity (during the past week) of at least 20% [on a Visual Analog Scale (VAS)/100 mm].”; Exclusion: “Participants were excluded if they reported suffering from neurological disorders, systemic disease, history of spinal surgery, or any disorders that may have limited the ability to complete the study’s procedure.” | N=22; Age, mean (SD): 30 (5.8); Female: 5%; Home; 5 min/session (1 exercise each for 1-2 mins, 1 min break between modules), 4 sessions per week (total 20 min/wk) for 4 weeks; “The individualized VR training software programs were installed on personal laptops for independent use by the subjects… During the interactive VR sessions, the subject’s head was visualized as an animated image of a pilot flying a small airplane…The subject’s head movements controlled interactions within the virtual environment and the various tasks stimulated different therapeutic aims. The VR software included three modules aimed at stimulating: 1) increased ROM, 2) faster motion with a quick response, and 3) increased neck motion accuracy…” | N=23; Age, mean (SD): 28 (5.1); Female: 13%; Usual care; NR; “…both groups (control and intervention) continued physical therapy, if receiving any, and this was the control intervention.” | Primary: NDI, mean velocity; Pain-related functioning (4 wk, 7 mo); - NDI; Pain intensity (4 wk, 7 mo); - VAS; Quality of life (7 mo); - EQ5D-VAS general health; Physical performance (7 mo); - Isometric strength flexion/extension; - Global peak velocity; - Global mean velocity; - Global time to peak velocity; - Global accuracy; - Global # of velocity peaks
AR Interventions
Rodriguez-Hernandez, 2021^92,96,122^; High; 15 weeks; University General Hospital of Talavera de la Reina, Spain; University of Castilla La Mancha (grant # 2020-GRIN-29192) | Inclusion: “…attended the hospital rehabilitation unit…. who had been diagnosed with stroke…age: 18 to 85 years… maximum evolution time of six months…upper limb motor involvement…dependence in activities of daily living (Stroke Impact Scale; version 3.0)… life expectancy greater than six months (absence of life-threatening diagnoses such as end-stage cancer)…absence of other serious and disabling pathologies.”; Exclusion: “…presence of other neurological diagnoses, severe hemineglect, psychiatric pathologies” | N=23; Age, mean (SD): 62.6 (13.5); Female: 21.7%; Clinic; 150 mins per daily session, 5 consecutive days per week × 3 weeks; “…conventional upper and lower limb strength and motor training (100 min; guided by the hospital’s physiotherapy and occupational therapy team with the use of virtual reality devices (50 min) …Motor training with virtual reality devices consisted of several systems: First, the Hand-Tutor© glove (Figure 1a) for hand rehabilitation and 3DTutor© for upper extremities. Both systems are based on intensive and repetitive practice through movement and feedback instructions provided by the software with virtual environments and task that stimulate movements that stroke survivors require for daily life.” | N=23; Age, mean (SD): 63.6 (12.2); Female: 15%; Clinic; 150 min per daily session, 5 consecutive days per week × 3 weeks; “The conventional intervention protocol consisted of receiving manual therapy techniques (massage); passive and active assisted mobilization of the upper and lower limbs; walking in parallel, on slope and stairs; exercises with and without resistance with balls, elastic bands, and dumbbells in therapeutic cage and trellises; active-assisted mobility exercises of the upper limb and fingers in a sitting position; moving objects horizontally on a table; elevation and superposition of objects in vertical plane; biomechanical tasks that simulate flexion–extension and abduction–adduction of the shoulder and flexion–extension of the wrist and fingers.” | Primary: EQ-5D-5L; Quality of life (15 wk); - EQ-5D-5L; Physical performance (3 wk, 15 wk); - Fugl-Meyer Assessment – Upper Extremity; - Action Research Arm Test (ARAT); Non-eligible: Modified Ashworth Scale; Stroke Impact Scale
Taveggia, 2016^94^; Some concerns; 12 weeks; 3 hospitals (2 owned by Habilita), Italy; NR | Inclusion: “… aged 18 to 80 years old…patients in the acute phase of stroke (between 0.5 and 12 months post-onset)…self-reported functional impairments of their upper extremities after stroke… first stroke episode; no history of peripheral nerve injury or musculoskeletal disease (e.g., arthritis, musculotendinous injury or bone fracture) in the affected upper extremity; no contracture of the affected wrist or fingers (Modified Ashworth <3); and no history of any invasive procedure (botulinum toxin type A) for the treatment of spasticity for at least 6 months prior to the start of this study.”; Exclusion: “…unstable medical disorders, aphasia, or cognitive problems (MMSE≤21).” | N=27; Age, mean (SD): 73 (10); Female: 66.7%; Clinic; 1 hr/day, 5 days per week, for 6 weeks; Armeo Spring device “allows the reinforcement and facilitation of movement by means of a visual feedback with a three-dimensional virtual environment in which the patient is asked to perform various tasks…In the first session the device was adjusted for patient’s arms. The physiotherapist controlled functional space of upper limb movement and correct position of working station. Each training session consisted of two parts with 30 minutes per session with Armeo Spring and 30 minutes per session with conventional treatment…” | N=27; Age, mean (SD): 68 (13); Female: 48.1%; Clinic; 1 hr/day, 5 days per week, for 6 weeks; “…traditional rehabilitation…such as passive and active assisted mobilization of the upper limbs traditional training based on the Bobath concept (neuromuscular facilitation, postural control and proprioception exercises, verticalization and gait training).” | Primary: Functional Independence Measure (FIM), clinician-reported measure of functional ability; Motricity Index (MI) for motor strength; Pain intensity/severity (6 wk, 12 wk); - VAS; Adverse events (6 wk); Physical performance (6 wk, 12 wk); - Motricity Index (MI); Non-eligible: FIM; Modified Ashworth Scale for Grading Spasticity (MAS)

Abbreviations. AR=augmented reality; EQ-5D-5L=European Quality of Life scale; EQ5D-VAS=European Quality of Life-Visual Analog Scale; mm=millimeters; MMSE=Mini Mental State Examination; NDI=Neck Disability Index; NR=not reported; SD=standard deviation; VAS=Visual Analog Scale; VR=virtual reality.

Appendix Table K2 Detailed Results for KQ2 Other Conditions Studies

Author, Year; VR or AR; Risk of Bias | Effect Measure | Intervention; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparator; Baseline Man (SD); Follow-Up Mean (SD), Mean Change | Comparison
Pain-Related Functioning or Interference
Bahat, 2020^90^; VR; Some concerns | NDI | 17.6 (8.9); 4 wk median (IQR): 10 (6, 26); 7 mo median (IQR): 9 (6, 18) | 17.9 (10.4); 4 wk median (IQR): 16 (8, 20); 7 mo median (IQR): 18 (6, 26) | Diff ∆: NC
Pain Intensity
Abd-Elsayed, 2021^91^; VR; Critical | VAS | Baseline pre: 6.0 (NR); Baseline post: 5.4 (NR); 12 wk pre: 3.8 (NR); 12 wk post: 3.1 (NR) | NR | NA
Bahat, 2020^90^; VR; Some concerns | VAS | 36.4 (22.9); 4 wk: 25.7 (24.0), −10.7^*^; 7 mo: 23.0 (22.2), −13.4^*^ | 49.5 (21.1); 4 wk: 26.9 (22.3), −22.6^*^; 7 mo: 24.5 (22.3), −25.0 | Diff ∆^*^:; 4 wk: 11.9; 7 mo: 11.6
Taveggia, 2016^94^; AR; Some concerns | VAS | 4.5 (1.5); 6 wk:1.7 (1.2), −2.8 (1.4); 12 wk: 1.0 (1.1), −3.5 (1.3) | 4.2 (2.0); 6 wk: 2.5 (1.6), −1.7 (1.8); 12 wk: 2.6 (1.6), −1.6 (1.8) | Diff ∆^*^:; 6 wk: −1.1; 12 wk: −1.9
Adverse Events
Taveggia, 2016^94^; AR; Some concerns | Participants who experienced an AE | No AE | No AE | Diff ∆^*^:; 0
Quality of Life
Rodriguez-Hernandez, 2021^92^; AR; High | EuroQoL −5DL - Mobility | n (%); No problems: 0; Mild/moderate problems: 5 (22); Severe/extreme problems: 18 (78); 15 wk:; No problems: 9 (39); Mild/moderate problems: 14 (61); Severe/extreme problems: 2 (10) | n (%); No problems: 0; Mild/moderate problems: 12 (60); Severe/extreme problems: 8 (40); 15 wk:; No problems: 0; Mild/moderate problems: 18 (90); Severe/extreme problems: 2 (10) | --
| EuroQoL −5DL - Selfcare | n (%); No problems: 0; Mild/moderate problems: 5 (22); Severe/extreme problems: 18 (78); 15 wk:; No problems: 15 (65); Mild/moderate problems: 8 (35); Severe/extreme problems: 0 | n (%); No problems: 0; Mild/moderate problems: 12 (60); Severe/extreme problems: 8 (40); 15 wk:; No problems: 5 (25); Mild/moderate problems: 15 (75); Severe/extreme problems: 0 | --
| EuroQoL −5DL – Daily activities | n (%); No problems: 0; Mild/moderate problems: 5 (22); Severe/extreme problems: 18 (78); 15 wk:; No problems: 8 (35); Mild/moderate problems: 15 (65); Severe/extreme problems: 0 | n (%); No problems: 0; Mild/moderate problems: 4 (20); Severe/extreme problems: 16 (80); 15 wk:; No problems: 0; Mild/moderate problems: 20 (100); Severe/extreme problems: 0 | --
| EuroQoL −5DL – Pain/discomfort | n (%); No problems: 13 (56); Mild/moderate problems: 6 (26); Severe/extreme problems: 4 (17); 15 wk:; No problems: 4 (17); Mild/moderate problems: 19 (83); Severe/extreme problems: 0 | n (%); No problems: 10 (50); Mild/moderate problems: 9 (45); Severe/extreme problems: 1 (5); 15 wk:; No problems: 0; Mild/moderate problems: 19 (95); Severe/extreme problems: 1 (5) | --
| EuroQoL −5DL – Anxiety/depression | n (%); No problems: 0 (0); Mild/moderate problems: 18 (78.3); Severe/extreme problems: 5 (22); 15 wk:; No problems: 7 (30); Mild/moderate problems: 15 (65); Severe/extreme problems: 1 (4) | n (%); No problems: 0; Mild/moderate problems: 17 (85); Severe/extreme problems: 3 (15); 15 wk:; No problems: 0; Mild/moderate problems: 13 (65); Severe/extreme problems: 7 (35) | --
Opioid Use
Abd-Elsayed, 2021^91^; VR; Critical | Self-reported opioid use | Cessation: 38%; Decrease: 31%; Increase: 6%; No Change: 25% | NR | NA
Physical Performance
Rodriguez-Hernandez, 2021^93,96^; AR; High | Fugl-Meyer Assessment Upper Extremity | 23.3 (6.9); 3 wk: 57.7 (4.7), 34.4^*^; 15 wk: 58.8 (5.9), 35.5 | 22.7 (5.4); 3 wk: 47.0 (6.1), 24.3^*^; 15 wk: 49.3 (6.3), 26.6 | Diff ∆^*^:; 3 wk: 10.1; 15 wk: 8.9
Rodriguez-Hernandez, 2021^93,96^; AR; High | Action Research Arm Test | 13.2 (11.7); 3 wk: 46.0 (9.0), 32.8^*^; 15 wk: 46.0 (9.0), 32.8 | 11.5 (10.6); 3 wk: 29.3 (10.5), 17.8^*^; 15 wk: 29.7 (10.6) 17.4 | Diff ∆^*^:; 3 wk: 15.0; 15 wk: 15.4
Taveggia, 2016^94^; AR; Some concerns | Motricity Index (MI) | 37.0 (19.3); 6 wk: 54.7 (22.2), 17.7 (20.8); 12 wk: 80.5 (24.1): 43.5 (21.7) | 39.2 (15.6); 6 wk: 50.6 (16.4), 11.4 (16.0); 12 wk: 50.3 (16.6), 5.6 (16.1) | Diff ∆^*^:; 6 wk: 6.3; 12 wk: 17.9
Sarig Bahat, 2020^90^; VR; Some concerns | Flexion | 137 (32.2); 7 mo: 152.5 (41.9), 15.5^*^ | 128.5 (43.7); 7 mo: 140.9 (38.8), 12.4^*^ | Diff ∆^*^:; 7 mo: 3.1
Sarig Bahat, 2020^90^; VR; Some concerns | Extension | 190.1 (51.3); 7 mo: 209.6 (68.5), 19.5^*^ | 157.6 (50.9); 7 mo: 177.6 (59.1), 20^*^ | Diff ∆^*^:; 7 mo: −0.5

Notes.

* Calculated by review team.

Abbreviations. AR=augmented reality; Diff ∆=difference in change scores; EuroQoL-5D=European Quality of Life 5 Dimensions; IQR=interquartile range; mo=month; NC=not calculable; NDI=Neck Disability Index; NR=not reported; ROM=range of motion; SD=standard deviation; VAS=Visual Analog Scale; VR=virtual reality; wk=week.