# APPENDIX J POST-SURGICAL PAIN

Appendix Table J1 Detailed Characteristics for Included Trials on Post-Operative Studies

Author, Year; Risk of Bias; Follow-Up Duration; Country; Site(s); Funding source | Inclusion/Exclusion Criteria | Intervention: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Intervention Characteristics | Comparator: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Comparator Characteristics | Primary Outcome; Eligible Outcomes & Measures Reported (Time Points); Other Non-Eligible Outcomes Reported
Eichler, 2019^84^; High; 3 months; 3 Sites (unspecified); German Pension Insurance Berlin-Brandenburg (grant number 10-40.07.05.07.007); Deutsche Forschungsgemeinschaft; and Open Access Publishing Fund of University of Potsdam | Inclusion: “[T]otal hip or knee replacement was performed following idiopathic, posttraumatic, or congenital osteoarthritis, between 18-65 years, and… additional criteria (eg, High Definition Multimedia Interface [HDMI]-compatible screen, minimum 2.5-meter space in front of the screen, and internet access) …”; Exclusion: “Patients not expected to achieve functional safety in walking with full load by the end of the rehabilitation were excluded. For those patients, it was assumed that they would not be able to perform exercises with adequate load or the assessments at the study site. Insufficient verbal and written German-language skills also led to exclusion.” | N=56; Age, mean (SD):; 53.5 (7.0); Female: 54.2%; Home; 3 × per week; 3 months (following 3 weeks of inpatient rehabilitation); “… home-based telerehabilitation program based on the MeineReha system, which consisted of a home component as well as a working portal for the therapist in the clinic…The exercises to build up strength and improve postural control were chosen by the supervising therapist …The training intensity was individualized in terms of the choice of exercises, the number of sets and repetitions, and the duration of the breaks, which could all be adjusted by the therapist… options for the patient and the therapist to communicate …: (1) the patient could record and send audio messages to their therapist…and the therapist was able to listen to it whenever their schedule gave them time to do it; (2) the therapist could respond or start a conversation…with individualized text messages, which the patient was shown whenever they started the system…; and (3) the patient and the therapist were able to make appointments for live video conferences, which they were supposed to conduct on a weekly basis… During the training, the exercises were demonstrated on screen by an avatar… The patient performed the exercises simultaneously and was detected by means of a Kinect sensor…The system…sent them real-time visual feedback in which their relevant body segments were colored green for correct movements and red in the case of incorrect movements … For training supervision, the therapist was given access to the frequency of the training as well as the exercise evaluations.” | N=55; Age, mean (SD):; 56.8 (5.7); Female: 48.7%; Home; NR; 3 weeks inpatient followed by no specific therapy; “Patients in the control group did not receive any study-specific therapy after their inpatient rehabilitation. The follow-up was carried out identically to the [intervention group] three months after randomization. The patients of both groups were also offered the usual aftercare…” | Primary: 6-minute walk test; Pain related functioning or interference (3 mo); - WOMAC; - Five Times Chair Rise Test; Physical performance (3 mo); - TUG; - Stair Ascend Test; Quality of life (3 mo); - SF-36-physical; - SF-36-mental
Fuchs, 2022^82^; High; 6 months; Kaplan Medical Center, Rehovot; “This research did not receive any specific grant from funding agencies in the public, commercial or not-for-profit sectors.” | Inclusion: “(1) Patients diagnosed with osteoarthritis, either uni/double/triple compartmental osteoarthritis, and found suitable for surgery. All grades of osteoarthritis were included in the study; (2) Patients undergoing unilateral TKA.”; Exclusion: “(1) Patients undergoing revision of TKA; (2) Ligament injury or periprosthetic fracture occurring during TKA; (3) Unstable vital signs; (4) Vision loss, hearing loss, or functional illiteracy.” | N=30; Age, mean (SD):; 70 (7); Female: 63.3%; Clinic/facility; 1 session per day; 1-2 days post-operatively; “The VR intervention included a movie that was picked by the patient from several options, either a nature film or a music film. The patient watched the VR film during the CPM physiotherapy.” | N=25; Age, mean (SD):; 70 (7); Female: 52.0%; Clinic/facility; 1 session per day; 1-2 days post-operatively; “The CPM was used as a tool to match the physiotherapy conditions for all patients and to measure a possible change in the range of motion.” | Primary: VAS; Pain related functioning or interference (6 mo); - WOMAC
Janhunen, 2023^85^; Some Concerns; 4 months; Turku University of Applied Sciences, University of Jyväskylä; Päivikki and Sakari Sohlberg Foundation; the Business Finland (grant numbers: 5794/31/2016, 5941/31/2016, 6057/31/2016); Finnish partner companies (SE Innovations Oy [Senior Some Oy], Suunto Oy, Physiotools Oy, GoodLife Technology Oy, Lingsoft Oy, eSeteli Palveluverkko Oy, PN Turku Oy, Ade Animations Design & Effects Oy, Adesante Oy, 4FeetUnder, Intechso and Realmax Oy) | Inclusion: “(1) first primary unilateral TKR, (2) mechanical axis of the limb in varus, (3) posterior stabilising or cruciate-retaining prosthesis and (4) normal vision with or without eyeglasses”; Exclusion: “[F]ractures, rheumatoid arthritis or other biomechanical disruptions in the affected lower limb within 1 year before surgery, a diagnosed memory disorder, cognitive impairment or a neurological condition.” | N=25; Age, mean (SD):; 66.9 (3.1); Women: 64.0%; Home; 4-5 exergames (variable duration and sets) played several times a day; 16 wks; “…[P]rotocol included 11 games…The player controls the games using movements similar to the standard postoperative home exercise program…Exergames were categorized according to exercise target: knee extension and flexion, knee flexion or squatting, weight shifting from side to side, stretching, and functional exergames…The knee extension-flexion games (the Cave Game and Intruders) and stretching game (the Cannon) were played in a sitting position, whereas the other games (the Rowing Game, Pick Up, Squat Pong, Bubble Runner, Hat Trick, Brick Breaker, Hiking, and Toy Golf) were played in a standing position.” | N=27; Age, mean (SD):; 66.4 (4.5); Women: 63.0%; Home; Multiple exercises 2-5 times a day; 16 wks; “[P]rotocol included 11–12 exercises…The control group underwent a standard postoperative home exercise program…The research physiotherapist instructed the control group participants to follow this standard program several times a day for 16 weeks starting after discharge from the hospital. Similar to the exergame group, guidance was provided at the exercise laboratory baseline visit immediately after randomization. Face-to-face individual guidance was provided for 5 to 10 minutes by the same research physiotherapist who had conducted the baseline assessment.” | Primary: Oxford knee score 12-item questionnaire, TUG; Pain intensity (2, 4 mo); - VAS; Physical performance (4 mo); - SPPB; - Active and passive knee flexion and extension, using universal goniometer; - Muscle force flexion and extension, assessed with Metitur Good Strength dynamometer in Jyväskylä (Newton [N]) and a Con-Trex Multijoint dynamometer (Newton-meter [Nm]) in Turku from the operated
Jin, 2018^83^; High; 6 months; Cangzhou Central Hospital; NR | Inclusion:; “1) Patients diagnosed as OA according to The Guidelines for Diagnosis and Treatment of Osteoarthritis issued by the Chinese Rheumatology Association in 2010; 2) Patients undergoing unilateral TKA for the first time…”; Exclusion:; “1) Overweight (BMI ≥ 30 kg/m^2); 2) Severe osteoporosis; 3) Ligament injury or periprosthetic fracture occurring during TKA; 3) Unstable vital signs, complications of incision healing, or clot formation in leg veins; 4) Vision loss, hearing loss, or functional illiteracy. | N=33; Age, mean (SD):; 66.45 (3.49); Female: 54.55%; Clinic/facility; 30 minutes, 3 times per day; NR; “… patients exercised by performing foot dorsiflexion and plantar flexion beginning the first day after TKA. Exercises targeting quadriceps muscle strength occurred from the second day after TKA. Passive exercises on knee flexion began after the drainage tube was removed. Exercises were assisted with psychological intervention and pain management education… In addition, VR (Mide Technology Inc., Cangzhou, China) intervention was applied in the experimental group beginning the second day after TKA. Patients were asked to row a boat using knee flexion (interaction of VR) in an immersive virtual environment…” | N=33; Age, mean (SD):; 66.30 (4.41); Female: 60.61%; Clinic/facility; 30 repetitions, 3 times per day; NR; “…patients exercised by performing foot dorsiflexion and plantar flexion beginning the first day after TKA. Exercises targeting quadriceps muscle strength occurred from the second day after TKA. Passive exercises on knee flexion began after the drainage tube was removed. Exercises were assisted with psychological intervention and pain management education…Patients in the control group were asked to flex their knees passively using their arms until pain tolerance was reached. They held that position for 20 seconds followed by relaxing for 40 seconds.” | Primary: WOMAC, VAS, ROM; Other non-eligible outcomes reported (1, 3, 6 mo); - HSS
Piqueras, 2013^86^; High; 3 months; An acute-care university general hospital, Barcelona; Partially financed by Telefónica Research and Development. | Inclusion: “[S]uccessful primary TKA surgery; post-TKA active range of motion: flexion 80° and extension −10°, without signs of stiffness; ability to walk with the use of a walking aid; ability to read and understand Spanish; ability to understand and accept the trial procedures and to sign an informed consent form in accordance with national legislation.”; Exclusion: “…[S]ensory, cognitive and/or praxic impairment; concomitant medical conditions that may influence the rehabilitation process; discharge to destination other than home; patients with any local or systemic complication (e.g. surgical wound infection, suspicion of deep vein thrombosis) in the 3-month follow-up period were also excluded.” | N=90; Age, mean (SD):; NR; Women: 83%; Home/Clinic or health care facility; 1 hour sessions; 10 days; “The IVT is an interactive virtual software-hardware platform that facilitates the development of remote rehabilitation therapy for multiple diseases…[The] patient receives the information needed to perform the exercises and the therapist can remotely monitor the patient’s performance. For the purpose of this trial, the IVT system was designed for lower limb motor recovery in patients undergoing TKA[…]Wireless sensors (WAGYRO) including a 3-axis accelerometer and two self-powered gyroscopes […] connected to the patient and allow calculation of their movement trajectories. [I]nteractive software with a 3D avatar that demonstrates the exercises to be undertaken, while patients reproduce the movements[…]Web portal for the therapist: receives data and records them for evaluation, with the option to modify the therapy as the rehabilitation evolves[…]The therapist supervised patients remotely on a daily basis from the hospital to check that they were performing the therapy, adjusted the prescribed therapy as appropriate, and contacted the patient via telephone as necessary.” | N= N=91; Age, mean (SD):; NR; Women: 62.5%; Home/Clinic or health care facility; 1 hour sessions; 10 days; “In all cases, functional rehabilitation started the day after TKA. All participants were instructed by a physical therapist in weight bearing to tolerance with an assistive device and underwent inpatient care. (mean length of stay 6.2 days) and outpatient intervention (outpatient physical therapy or IVT) for the first 3 weeks after surgery. Inpatient care consisted of assisted walking within 24 h, knee range of motion exercises and preparing for the return home. After hospital discharge, conventional physical therapy consisted of a 2-week face-to-face rehabilitation programme (progressive exercise and instruction including knee range of motion, gait training, and instructions in negotiating stairs and community-related obstacles). Any signs of adverse knee joint responses (eg, increased swelling or pain) resulted in a lowering of the intensity, frequency and duration of the exercises or elimination of a rehabilitation component.” | Primary outcome NR; Pain intensity (2 wk, 3 mo); - VAS; Physical performance (2 wk, 3 mo); - TUG; - Quadriceps muscle strength, measured in kg (NMMT dynamometer); - Hamstring muscle strength, measured in kilograms (NMMT dynamometer); - Active Knee extension, measured in degrees with a goniometer; - Active Knee flexion, measured in degrees with a goniometer
Prvu Bettger, 2020^87^; Some concerns; 12 weeks; Two academic medical centers and 2 independent private practices; Reflexion Health, “the manufacturer of the VERA system” | Inclusion:; “Patients who had an in-person clinic visit at least 10 days prior to TKA. Patients who were ≥18 years of age, who were scheduled for TKA for the treatment of nontraumatic conditions, and who had a Risk Assessment and Prediction Tool (RAPT) score of ≥ 6 (indicating expected discharge to home after surgical hospitalization) were eligible.”; Exclusion: “[P]atients who were scheduled to undergo bilateral or staged bilateral TKA, who were in a nursing home prior to surgery, or who were unable or unwilling to provide informed consent.” | N=153; Age, mean (SD):; 65.4 (7.7); Female: 59.6%; Home/Clinic or health care facility; NR; NR; “VERA is a cloud-based virtual telehealth system that functions with use of 3-dimensional (3D) tracking technology to quantify pose and motion, an avatar (digitally simulated coach) to demonstrate and guide activity, visual and audible instructions and immediate feedback on exercise quality, and a virtual video connection for synchronous telehealth visits with an assigned intervention telehealth physical therapist. Individualized prescribed therapy regimens were electronically programmed for patients through the clinician interface prior to surgery…; The VERA system tracked activity, performance, exercise quality, and adherence; the telehealth therapist monitored the patient’s progress asynchronously. Patients had a video visit with their telehealth therapist in the week after hospital discharge and weekly thereafter to review progress and to revise the therapy regimen accordingly. The telehealth therapist provided remote clinician oversight to the patients for the duration of the intervention and communicated progress to each clinical site ahead of the patients’ 2 and 6-week postoperative visits. Patients and the telehealth therapist mutually agreed when therapy goals were met for discharge from virtual PT.” | N=153; Age, mean (SD):; 65.1 (9.2); Female: 65.4%; Home/Clinic or health care facility; NR; NR; “Patients in the usual care group followed their care team’s recommendations for all preoperative and postoperative medical and rehabilitative care.” | Primary outcome: Total healthcare costs 12 weeks after discharge; Pain related functioning or interference (6, 12 wk); - KOOS; Pain intensity (12 wk); - NRS; Adverse events (12 wk); - Number of falls, patient-reported; Physical performance (6 wk); - Knee Extension (degrees); - Knee Flexion (degrees); - 10-meter gait speed; Quality of life (12 wk); - PROMIS physical function; - PROMIS mental health; Other non-eligible outcomes reported; - Healthcare costs, total and by different services; - Hospital readmissions, patient-reported
Shim, 2023^88^; Some concerns; 24 weeks; Two academic medical centers, Seoul; Korea Health Technology R&D Project through the Korea Health Industry Development Institute; Ministry of Health Welfare, Republic of Korea (grant no.: HR19C0781). | Inclusion:; “Participants aged ≥ 50 years who underwent TKA and were discharged home.”; Exclusion: “[P]articipants with a history of osteotomy, severe neurological deficits, infection in the affected knee, inability to perform exercises due to severe comorbidities, or inability to participate in the rehabilitation program for other reasons.” | N=28; Age, mean (SD):; 68.6 (5.8); Women: 82.1%; Home; 30 min, daily; 12 wks; “[AR] group performed brochure-based exercises in the early phase… In the advanced phase, exercise was performed using an AR-based digital healthcare system… At levels 1–4, participants performed range of motion and isometric strengthening of lower extremities while lying down or sitting in a chair. At levels 5–9, participants performed a program designed to train stretching and isotonic strengthening of lower extremities while standing with support. At levels 10–12, participants performed a program designed to train stretching and isotonic strengthening, including lunges and squats, while standing without support… The exercises were displayed on the screen (avatar plus written summaries). Participants…were provided with real-time feedback on the screen… The exercise performance and motion accuracy were recorded online and reviewed by a physician. Participants were provided detailed feedback on their performance at the outpatient clinic visits.” | N=28; Age, mean (SD):; 73.0 (4.6); Women: 75.0%; Home; 3-5 sets of exercises (10 repetitions each); 12 wks; “Both groups performed the same exercises for the same duration, but the types of instructions provided at home differed…Participants in the [conventional rehab] group performed brochure-based home exercises, according to the standard rehabilitation protocol for patients after TKA… In the early phase, an exercise program consisting of ankle pumping, ROM, and isometric/isotonic exercise was performed in a sitting or lying position. In addition, gait training using a walker and stair up-and-down training were performed. In the advanced phase, participants performed cane/self-gait training and strengthening exercise, such as squats and lunges.” | Primary: 4-m gait speed; Pain related functioning or interference (3, 12, 24 wk); - WOMAC; Pain intensity (3, 12, 24 wk); - NRS; Physical performance (3, 12, 24 wk); - Berg balance scale; - ROM; - Quadriceps strength; - Hamstring strength; Quality of life (3, 12, 24 wk); - EuroQoL-5D-5L

Abbreviations. AR=augmented reality; BMI=body mass index; CPM=continuous passive motion; h=hour; HSS=hospital for special surgery knee score; IRENA=multimodal intensified aftercare; IVT=interactive virtual telerehabilitation; NMMT=Nicholas manual muscle tester; KOOS=knee injury and osteoarthritis outcome score; NR=not reported; NRS=numerical rating scale; PROMIS=patient-reported outcomes measurement information system; PT=physical therapy; RAPT=risk assessment and prediction tool; ROM=range of motion; SPPB=short physical performance battery; SD=standard deviation; SF-36=short form health survey-36; TKA=total knee arthroplasty; TKR=total knee replacement; TUG=timed up and go test; VAS=visual analogue scale; VERA=virtual exercise rehabilitation assistant; VR=virtual reality; WOMAC=Western Ontario and McMaster Universities Arthritis Index.

Appendix Table J2 Detailed Results for Post-Operative Studies

Author, Year; VR or AR; Risk of Bias | Effect Measure | Intervention; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change (SD) | Comparator; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change (SD) | Comparison
Pain-Related Functioning or Interference
Eichler, 2019^84^; AR; High | WOMAC (3 mo) | 26.4 (18.5); 11.5 (12.7), −14.9 (13.6) | 24.8 (16.4); 13.9 (14.3), −10.9 (13.5) | Diff ∆^*^: −4.0; Stand. Diff ∆: −0.3^*^
Fuchs, 2022^82^; VR; High | WOMAC (6 mo) | 36.4 (15.1); 57.2 (27.3), 20.8 | 34.5 (17.0); 54.2 (25.4), 19.7 | Diff ∆ : 1.1^*^
Janhunen, 2023^85^; AR; Some concerns | OKS | 26.7 (6.7); 2 mo: 33.4 (6.3), 6.7; 4 mo: 38.6 (6.1), 12.1 (7.0^*^) | 26.9 (6.5); 2 mo: 30.3 (5.5), 3.4; 4 mo: 36.7 (6.7), 9.8 (7.0^*^) | Diff ∆^*^:; 2 mo: 3.3; 4 mo: 2.3; Stand. Diff ∆^*^:; 4 mo: 0.33, p=0.27
Jin, 2018^83^; VR; High | WOMAC | 45.03 (5.1); 1 mo: 32.0 (5.2), −13.0; 3 mo: 25.8 (4.2), −19.2; 6 mo: 21.6 (4.2), −23.5 | 44.18 (5.73); 1 mo: 35.1 (5.2), −9.1; 3 mo: 29.7 (5.6), −14.5; 6 mo: 26.3 (3.9), −17.9 | Diff ∆^*^:; 1 mo: −3.9; 3 mo: −4.7; 6 mo: −5.6
Prvu Bettger, 2020^87^; AR; Some concerns | KOOS | 37.0 (12.0); 6 wk: 61.0 (11.5), 24.0; 12 wk: 69.6 (12.1), 32.6 | 36.0 (13.0); 6 wk: 61.8 (13.5), 25.8; 12 wk: 67.2 (14.3), 31.2 | Diff ∆^*^:; 6 wk: −1.8; 12 wk: 1.4
Shim, 2023^88^; AR; Some concerns | WOMAC | 83.1 (13.0); 3 wk: 66.1 (12.5), −17; 12 wk: 46.5 (9.1), −36.6; 24 wk: 40.1 (7.0), −43.0 | 81.1 (14.4); 3 wk: 62.2 (15.0), −18.9; 12 wk: 45.3 (15.0), −35.8; 24 wk: 40.9 (16.0), −40.2 | Diff ∆^*^:; 3 wk: 1.9; 12 wk: −0.8; 24 wk: −2.8
Pain Intensity
Fuchs, 20; VR; High | VAS (2 days) | Means NR; Median (IQR):; Before treatment: 6 (5-8), NC; After treatment: 4 (1-7), NC | Means NR; Median (IQR):; Before treatment: 6 (6-8), NC; After treatment: 5 (2-7), NC | Diff ∆: NC
Janhunen, 2023^85^; AR; Some concerns | VAS | 57.1 (18.3); 2 mo: 30.5 (21.0), −26.6; 4 mo: 20.8 (20.3), −36.3 (24.4^*^) | 54.2 (21.6); 2 mo: 28.7 (20.0), −25.5; 4 mo: 27.0 (27.5), −26.7 (24.7^*^) | Diff ∆^*^:; 2 mo: −1.1; 4 mo: −9.1; Stand. Diff ∆^*^:; 4 mo: −0.39, p=0.18
Jin, 2018^83^; VR; High | VAS | 7.4 (1.14); 3 days: 6.5 (0.9), −0.9; 5 days: 5.4 (0.8), −2.0; 7 days: 3.9 (0.6), −3.5 | 7.4 (1.3); 3 days: 6.8 (1.1), −0.6; 5 days: 6.0 (0.9), −1.5; 7 days: 4.4 (0.8), −3.0 | Diff ∆^*^:; 1 mo: −0.3; 3 mo: −0.5; 6 mo: −0.5
Piqueras, 2013^86^; AR; High | VAS | 3.8 (2.0); 2 wk: 3.1^*^, −0.7 (1.4); 3 mo: 2.0^*^, −1.8 (2.5) | 4.3 (1.9); 2 wk: 3.7^*^, −0.6 (1.9); 3 mo: 2.0^*^, −2.3 (2.0) | Diff ∆^*^:; 2 wk: −0.1; 3 mo: 0.5; Stand. Diff ∆^*^:; 2 wk: −0.1, p=0.80; 3-mo: 0.2, p=0.28
Prvu Bettger, 2020^87^; AR; Some concerns | NRS (12 wk) | 5.2 (2.1); 2.7 (2.0), −2.5 | 5.7 (2.0); 3.0 (2.6), −2.7 | Diff ∆: 0.2^*^
Shim, 2023^88^; AR; Some concerns | NRS | 5.7 (2.1); 3 wk: 5.1 (2.0), −0.6; 12 wk: 2.8 (1.5), −2.9; 24 wk: 2.5 (1.6), −3.2 | 5.5 (2.2); 3 wk: 4.7 (2.0), −0.8; 12 wk: 3.3 (2.1), −2.2; 24 wk: 2.3 (2.1), −3.2 | Diff ∆^*^:; 3 wk: 0.2; 12 wk: −0.7; 24 wk: 0
Adverse Events
Prvu Bettger, 2020^87^; AR; Some concerns | Number of falls, patient-reported (12 wk) | 19.4% | 14.6% | Diff ∆: 4.8%^*^
Physical Performance
Eichler, 2019^84^; AR; High | 6-minute walk test (m) (3 mo) | 440.6 (78.2); 530.4 (79), 88.3 (57.7) | 433.3 (80.2); 513 (70.6), 79.6 (48.7) | Diff ∆: 8.7^*^
Eichler, 2019^84^; AR; High | TUG (s) (3 mo) | 9.3 (1.8); 7.5 (1.2), −1.9 (1.5) | 9.0 (2.4); 7.5 (1.6), −1.5 (2.2) | Diff ∆: −0.4^*^
Eichler, 2019^84^; AR; High | Stair Ascend Test (3 mo) | 8.7 (2.7); 6.2 (1.2), −2.5 (2.4) | 8.6 (4); 6.1 (1.5), −2.5 (3.0) | Diff ∆: 0^*^
Janhunen, 2023^85^; AR; Some concerns | TUG (s) | 9.4 (3.6); 2 mo: 8.2 (1.5), −1.2; 4 mo: 7.6 (1.5), −1.8 | 8.3 (1.7); 2 mo: 8.7 (1.6), 0.4; 4 mo: 7.7 (1.2), −0.6 | Diff ∆^*^:; 2 mo: −1.6; 4 mo: −1.2, p=0.04
Janhunen, 2023^85^; AR; Some concerns | Active and passive knee flexion (4 mo) | 107 (18); 106^*^, −1.0 (15.2^*^) | 107 (13); 100^*^, −7.0 (14.0^*^) | Diff ∆^*^: 6.0, p=0.17
Janhunen, 2023^85^; AR; Some concerns | Active and passive knee extension (4 mo) | 7.3 (7.7); 6.8^*^, −0.5 (7.0^*^) | 6.6 (4.1); 6.7^*^, 0.1 (7.1^*^) | Diff ∆^*^:; −0.6, p=0.76
Janhunen, 2023^85^; AR; Some concerns | Muscle force flexion (4 mo) | 0.6 (0.3); 0.7^*^, 0.1 (0.4^*^) | 0.6 (0.2); 0.7^*^, 0.1 (0.1^*^) | Diff ∆^*^: 0.0, p=0.88
Janhunen, 2023^85^; AR; Some concerns | Muscle force extension (4 mo) | 1.2 (0.5); 1.1^*^, −0.1 (0.2^*^) | 1.1 (0.4); 1.0^*^, −0.1 (0.3^*^) | Diff ∆^*^: 0.0, p=0.85
Janhunen, 2023^85^; AR; Some concerns | SPPB (4 mo) | 9.5 (1.5); 10.6^*^, 1.1 (1.5^*^) | 9.6 (1.5); 10.4^*^, 0.8 (1.6^*^) | Diff ∆^*^: 0.3, p=0.51
Jin, 2018^83^; VR; High | ROM (°); (14 days) | 43.6 (3.4); 93.7 (6.6), 50.2 | 42.9 (3.6); 86.4 (5.0), 43.5 | Diff ∆^*^: 6.7, p=0.0
Prvu Bettger, 2020^87^; AR; Some concerns | 10-m gait speed (s) (6 wk) | 1 (0.3); 1 (0.3), 0 | 1 (0.3); 1 (0.3), 0 | Diff ∆: 0^*^
Shim, 2023^88^; AR; Some concerns | 4-m gait speed | 0.4 (0.2); 3 wk: 0.5 (0.2), 0.1; 12 wk:0.8 (0.2), 0.4; 24 wk: 0.9 (0.2),0.5 | 0.5 (0.3); 3 wk: 0.6 (0.3), 0.1; 12 wk: 0.9 (0.1), 0.4; 24 wk: 1.0 (0.3), 0.4 | Diff ∆^*^:; 3 wk: 0; 12 wk: −0.1; 24 wk: 0.1
Shim, 2023^88^; AR; Some concerns | Berg balance scale | 29.8 (11.9); 3 wk: 34.7 (15.3), 4.9; 12 wk: 45.8 (11.9), 16.0; 24 wk: 49.3 (8.5), 19.5 | 29.7 (10.3); 3 wk: 37.6 (14.2), 7.9; 12 wk: 48.8 (11.3), 19.1; 24 wk: 47.9 (11.5), 18.2 | Diff ∆^*^:; 3 wk: −3; 12 wk: −3.1; 24 wk: 1.3
Shim, 2023^88^; AR; Some concerns | ROM | 79.0 (22.6); 3 wk: 96.6 (21.1), 17.6; 12 wk: 117.9 (11.8), 38.9; 24 wk: 120.6 (12.9), 41.6 | 82.0 (12.6); 3 wk: 106.0 (13.6), 24.0; 12 wk: 118.8 (12.8), 36.8; 24 wk: 122.3 (12.0), 40.3 | Diff ∆^*^:; 3 wk: −6.4; 12 wk: 2.1; 24 wk: 1.3
Shim, 2023^88^; AR; Some concerns | Quadriceps strength | NR; 3 wk: 107.1 (35.2), NR; 12 wk: 138.4 (29.7), NR; 24 wk: 149.2 (37.6), NR | NR; 3 wk: 98.1 (43.8), NR; 12 wk: 131.1 (39.7), NR; 24 wk: 146.5 (41.1), NR | Diff ∆:; 3 wk: NR; 12 wk: NR; 24 wk: NR
Shim, 2023^88^; AR; Some concerns | Hamstring strength | NR; 3 wk: 91.0 (34.1), NR; 12 wk: 153.1 (34.2), NR; 24 wk: 174.1 (42.0), NR | NR; 3 wk: 103.2 (45.3), NR; 12 wk: 146.9 (55.1), NR; 24 wk: 157.7 (45.1), NR | Diff ∆:; 3 wk: NR; 12 wk: NR; 24 wk: NR
Quality of Life
Eichler, 2019^84^; AR; High | SF-36 physical component score (3 mo) | 33.8 (7.6); 44.6 (9.9), 10.7 (10.4) | 33.3 (7.9); 44.4 (8.3), 11.1 (7.2) | Diff ∆: −0.4^*^
Eichler, 2019^84^; AR; High | SF-36 mental component score (3 mo) | 54.8 (10.6); 52.4 (10.6), −2.5 (12.4) | 53.9 (11.8); 54.1 (9.8), 0.1 (8.5) | Diff ∆: −2.6^*^
Prvu Bettger, 2020^87^; AR; Some concerns | PROMIS physical function (12 wk) | 12.5 (2.4); 15.3 (2.4), 2.8 | 12.3 (2.5); 14.8 (2.8), 2.5 | Diff ∆: 0.3^*^
Prvu Bettger, 2020^87^; AR; Some concerns | PROMIS mental health (12 wk) | 15 (2.8); 16.6 (2.5), 1.6 | 14.9 (3.2); 16.1 (3.2), 1.2 | Diff ∆: 0.4^*^
Shim, 2023^88^; AR; Some concerns | EuroQoL-5D-5L | 0.4 (0.2); 3 wk: 0.6 (0.1), 0.2; 12 wk: 0.8 (0.1), 0.3; 24 wk: 0.8 (0.1), 0.4 | 0.5 (0.2); 3 wk: 0.6 (0.1), 0.1; 12 wk: 0.7 (0.1), 0.3; 24 wk: 0.8 (0.1), 0.3 | Diff ∆^*^:; 3 wk: 0.02; 12 wk: 0.1; 24 wk: 0.1

Notes.

* Calculated by review team.

Abbreviations. AR=augmented reality; Diff ∆=between group difference (Intervention-Comparator) in mean change; KOOS=knee injury and osteoarthritis outcome score; NC=not calculable; NR=not reported; NRS=numerical rating scale; OKS=Oxford Knee Score; PROMIS=patient-reported outcomes measurement information system; ROM=range of motion; SD=standard deviation; SF36=36-item Short-Form Health Survey; SPPB=short physical performance battery; Stand Diff ∆=standardized between group differences over SD; TUG=timed up and go test; VAS=visual analogue scale; VR=virtual reality; WOMAC=Western Ontario and McMaster Universities Arthritis Index.