# APPENDIX I KQ1 OTHER CONDITIONS

Appendix Table I1 Detailed Characteristics for Included Trials on KQ1 Other Conditions

Author, Year; Risk of Bias; Follow-Up Duration; Site(s); Funding Source | Inclusion/Exclusion Criteria | Intervention: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Intervention Characteristics | Comparator(s): Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Comparator Characteristics | Primary Outcome; Eligible Outcomes & Measures Reported (Time Points); Other Non-Eligible Outcomes Reported
VR Intervention
Cuneo, 2023^70^; High; 12 weeks; University of Washington headache clinic, USA; Osher Center for Integrative Medicine Small Research Project Grant | Inclusion: “All participants met the International Classification of Headache Disorders (ICHD-3 beta) criteria for chronic migraine, as diagnosed by UW neurologists specializing in headache disorders. All subjects had experienced at least 15 headache days (including at least 8 migraine days) per month in the preceding 3 months. Additional inclusion criteria were 18 to 85 years and the ability to speak English or Spanish.”; Exclusion: “Excluded participants were those with cognitive impairment, severe psychiatric comorbidities (including active suicidal or homicidal ideation and/or psychosis), hearing/seeing difficulties, epileptic or non-epileptic seizures, and prisoners.” | N=25; Age, mean (SD): 42.71 (16.07); Female: 78.6%; Home; 10 minutes/day, at least 3 days/week; “Respiratory rate associated with the lowest LF/HF ratio was chosen as the participant’s optimal respiratory rate. Then calming music with ascending tones (to cue inhalation) and descending tones (to cue exhalation) at the participant specific optimal respiratory rate was uploaded into the participant’s biofeedback-VR device. The Oculus Go headset was placed on the participant’s head…with the option to choose between 2 VR environments, a beach or hilltop setting…The participant was then guided through a trial biofeedback-VR session… During the 10-minute session, participants were asked to “try to improve” the appearance of their feedbacked HRV tracing so that it resembled a sine wave-like curve, the “reward” reflecting synchronous entrainment of respiration and HRV.” | N=25; Age, mean (SD): 42.05 (14.65); Female: 86.4%; Home; 10 minutes/day, at least 3 days/week; Waitlist control group | Primary: mean monthly headache days; Pain-related functioning (12 wk); - Migraine Disability Assessment (MIDAS); Pain intensity/severity (12 wk); - Monthly headache days; Pain catastrophizing (12 wk); - Concerns About Pain (CAP) scale; Adverse events (12 wk); - % of participants with nausea or dizziness; Non-eligible: PHQ-8; Perceived Stress Scale; Insomnia (PROMIS); total acute medication use per month (prescription and over-the-counter)
Chuan, 2023^71^; Some concerns; 3 months; Cancer Therapy Centre, Liverpool Hospital, Sydney, Australia; Tour de Cure Cancer Foundation, HCF Health Foundation, and the NSW Health Department Agency for Clinical Innovation | Inclusion: “…treating oncologist or palliative care physician diagnosed symptoms of neuropathic pain caused by cancer or interventions for their cancer, …aged ≥ 18 years; were functionally independent in most activities of daily living with an Eastern Cooperative Oncology Group Performance Status score ≤ 2”; Exclusion: “Patients with psychological or psychiatric illness not stabilised with therapy or medications were excluded.” | N=19; Age, mean (SD): 56 (8); Female: 58%; Clinic; 3 × 30-min sessions within a 4-week period; “We created a bespoke virtual reality-delivered software programme that taught pain self-efficacy to patients using progressive muscle relaxation and guided pain visualisation techniques…For example, a computer-generated, anatomically correct human body highlighted the deltoid and biceps muscles of the proximal arm, asking the patient to localise tension before guiding the patient in a scripted relaxation exercise. In the pain visualisation therapy, an angry, fiery ball symbolised the patient’s neuropathic pain, evoking imagery of burning and shooting.” | N=20; Age, mean (SD): 63 (11); Female: 70%; Clinic; 3 × 30-min sessions within a 4-week period; “Patients in the control arm were instead asked to view a selection of short documentaries and videos specifically filmed in a virtual reality format for viewing through a virtual reality headset. These publicly available videos were selected from the dedicated virtual reality channel on YouTube. In their 30-minute session, patients could choose from any of the following: a documentary on jaguars in Brazil, a documentary on the Apollo 11 moon landing, an animated cartoon in a snow environment and a car review…” | Primary: feasibility, acceptability, recruitment rates, and risk of cybersickness; Pain-related functioning (1 mo, 3 mo); - BPI-Interference; Pain intensity/severity (1 mo, 3 mo); - BPI-Intensity; Adverse events (1 mo); - Counts of participants with dizziness, nausea, and eyestrain during any session; Quality of life (1 mo, 3 mo); - QLQ-C30 (only global quality subscale); Opioid use (1 mo, 3 mo); - Average MME in the previous week; Non-eligible: feasibility, acceptability, recruitment rates, tolerability
Darnall, 2020^72^; High; 22 days; Community health system, United States; AppliedVR Inc. | Inclusion: “…aged 18-75 years with self-reported chronic nonmalignant low back pain or fibromyalgia, with an average pain intensity >4 over the past month and chronic pain duration >6 months.”; Exclusion: NR | N=35; NR; Female: 26%; Home; 21-day program with 4-8 treatment sessions from 1-15 minutes.; “Treatment consisted of a variety of sessions to support participants in learning self-management skills based on evidence-based CBT principles as well as biofeedback and mindfulness strategies used in pain management. The program was designed to improve self-regulation of cognitive, emotional, and physiological responses to stress and pain and comprised 3 main content categories: skills rooted in pain CBT… relaxation training…[and] mindfulness” | N=39; NR; Female: 13%; Home; 21-day program with 4-8 treatment sessions from 1-15 minutes.; “The audio program consisted of the majority of the same narrative content contained in the VR program, with changes made to the descriptive titles for each session…. approximately one-third of the VR program could not be included verbatim in the audio. Rather, the audio session topical content was closely matched to the corresponding VR session for that day and adapted to eliminate any references to visual content that would be confusing to the listener…” | Primary: Defense and Veterans Pain Rating Scale (DVPRS); Pain-related functioning (21 days); - DVPRS-Stress, Mood, Sleep, & Activity domains; Pain intensity/severity (21 days); - DVPRS-Pain Rating Scale; Pain catastrophizing (21 days); - PCS (no follow-up data, only model statistics); Adverse events (22 days); Pain global change (22 days); - PGIC; Non-eligible: Pain Self-Efficacy Questionnaire, Patient satisfaction with VR
Reynolds, 2022^73,121^; Some concerns; 4 weeks; Community health system, New Zealand; Breast Cancer Foundation New Zealand (Grant #3719356) | Inclusion: “…required to have a diagnosis of MBC, be over 18 years, be able to physically wear and tolerate the VR headset, and have experienced symptoms of fatigue, pain, or anxiety in the week prior to enrolment…”; Exclusion: “…any visual, hearing, or cognitive impairments that would limit their ability to take part in the study, or if they could not read, speak, or write in English.” | N=20; Age, mean (SD): 52.7 (13.2); Women: 100%; Home; >10 minutes/day, 1 week Ripple, 1 week washout, 1 week Happy Place; Randomization was to order of VR interventions.: “Group 1 used Ripple, then Happy Place (R:HP), and Group 2 experienced Happy Place before Ripple (HP:R). “Happy Place…is a commercially available VR application in which participants experience a tranquil, animated camping scene. Participants experience changes to the weather and time of day and can interact with optional tasks, guided relaxation, and soothing music. Ripple is a collection of three short 360° [and] are as follows: 1) a beach where the participant can write words in the sand or the sky; 2) a waterfall where the participant can stack stones; and 3) a mountain range where the participant can jump between different locations amongst mountaintops and lakes.” | N=18; Age, mean (SD): 51.28 (9.32); Women: 100%; Home; >10 minutes/day, 1 week Happy Place, 1 week washout, 1 week Ripple; Happy Place, then Ripple (HP:R). There was a one-week washout period to minimise carryover effects between the two interventions…” | Primary: EQ-5D-5L; Pain-related functioning (7 days, 9 days); - BPI-short form (11 items); Adverse events (9 days); Quality of life (7 days); - EuroQoL-5D (only transformed scores); Non-eligible: FACIT-Fatigue, DASS (Depression, Anxiety and Stress Scales), Acceptability & satisfaction questions/rating
Wankhade, 2022^74^; High; 2 weeks; Data Meghe Institute of Medical Sciences, Musculoskeletal OPD of Acharya, Vinoba Bhave Rural Hospital, Sawangi (Meghe), Wardha, India; NR | Inclusion: “Patients between the age group of 40-60 years…and having stage 2 or stage 3 primary or idiopathic frozen shoulder.”; Exclusion: “Patients with any post-operative history of shoulder joint, fractures, subluxations or dislocations, diabetes, rheumatoid arthritis etc.” | N=25; NR; NR; Clinic; 15-20 minute daily sessions for 2 weeks; “…patients were treated with Oculus-guided physical therapy in addition to Maitland’s mobilization…Hand Physics Lab on Oculus Quest is a program that allows participants to use their hands and fingers to interact with a virtual environment as well as other goods and experiences. Various shoulder movements such as shoulder internal and external rotations can be performed with the help of this games. Shoulder extensions flexion activities can also be carried out with the help of virtual reality games. This various gaming on virtual reality is useful for improving range of motion of joint.” | N=25; NR; NR; Clinic; 15-20 minute daily sessions for 2 weeks; “…conventional therapy which included Maitland’s mobilization…” | Primary: not specified; Pain-related functioning (2 wk); - NRS; Pain intensity/severity (2 wk); - Shoulder Pain and Disability Index (SPADI) Scale; Physical performance (2 wk); - Shoulder flexion; - Shoulder extension; - Shoulder abduction; - Shoulder adduction; - Shoulder internal; - Shoulder external
AR Interventions
Ambrosino, 2020^75^; Some concerns; 12 weeks; Intensive Orthopedic and Rheumatologic Rehabilitation Unit at an unspecified university, Italy; “No funding was received” | Inclusion: “…40 consecutive inpatients 18–35 years of age, diagnosed with RA according to the 1987 American College of Rheumatology revised criteria 21 referring to our Intensive Orthopedic and Rheumatologic Rehabilitation Unit were enrolled. All subjects had been treated with a ‘‘biologic’’ agent (22 adalimumab, 10 golimumab, 8 etanercept) for at least 12 months before admission.”; Exclusion: “… malignancy, intolerance to exercise, unstable medical conditions, pregnancy, any condition that could compromise the patient’s ability to comply with and/or perform study-related activities.” | N= 20; Age, mean (SD): 27.05 (5.71); Female: 65%; Home, Clinic; 50 mins (10 minutes per game) once daily during acute rehab (4 weeks), then at home × 8 weeks; “Participants were asked to play the five preselected Wii-Fit games (running, skiing, balloons shooting, bike slalom, balls moving through labyrinth) for 10 minutes per game, once/daily, throughout the period of hospitalization (Group A and B) and at home (Group A only). Videogames required to perform a wide range of exercises for upper and lower arms, including shoulder flexion/extension, abduction/adduction, internal/external rotation, circumduction, elbow flexion/extension, forearm pronation/supination, hand digit motion, weight shift back and from side-to-side, and knee and ankle flexion/extension.” | N=20; Age, mean (SD): 27.85 (3.41); Female: 60%; Clinic; Same as intervention group for 4 weeks, then “habitual activity” for 8 weeks; 5 games during acute rehab (4 wk only) | Primary: “Our study is aimed to assess the effectiveness of home exergaming with a commercially available nonimmersive videogame system as an additional rehabilitative tool in young RA patients, following a 4-week program of in hospital multidisciplinary rehabilitation.”; Pain-related functioning (12 wk); - Health Assessment Questionnaire (HAQ) measures function & fatigue; Non-eligible: Disease Activity Score (DAS-28); Global Health VAS; ESR; swollen & tender joint counts; FACIT-fatigue
Ditchburn, 2020^81^; High; 6 weeks; Teesside University’s physiotherapy laboratory, United Kingdom; Teesside University doctoral scholarship | Inclusion: “…aged 65 years or over, able to walk unassisted (ie, did not use, or require, any walking aids) for at least 0.5 of a mile and having musculoskeletal pain in two or more joints of more than 12 weeks duration.”; Exclusion: “…diagnosis (or suspicion) of any systemic conditions that may cause pain in two or more joints, of more than 12 weeks duration (such as cancer, rheumatic or neurological disease, or condition), self-report of current condition or self-report of history of any condition or injury which would contra-indicate participation in the exercises under study” | N=27; Age, mean (SD): 71.78 (6.1); Female: 81.5%; Clinic; 40 min sessions twice weekly for 6 weeks.; 5 games from the IREX® system: volleyball, sharkbait, formula racing, snowboard, and birds & balls. “Each IREX® exergame was played for 2 minutes and was repeated three times within a session…In both groups participants were given rest periods of 10 to 30 s, or longer, if required, between exergames, or [traditional] exercise sets.” | N=27; Age, mean (SD): 69.78 (4.48); Female: 65%; Clinic; 40 min sessions twice weekly, for 6 weeks.; “All exercises were completed on a one-to-one basis, with the first author supervising the sessions (and exercising with the [traditional exercise group])…Those in [this] group performed exercises that were matched to the IREX® exergames for movement patterns required, physiological demands, sequence, duration and mode of exercise, by adopting open and closed kinetic chain movements, in the same range and loading, across both groups…exercise was conducted in sets of 2 minutes duration and was repeated three times within a session. In both groups participants were given rest periods of 10 to 30 s, or longer, if required, between exergames, or [traditional] exercise sets.” | Primary: Pain & postural control/sway; Pain intensity/severity (6 wk); - NRS; Adverse events (6 wk); Physical performance (6 wk); - Postural sway with eyes open & closed; Non-eligible: Multi Affect and Pain Survey (MAPS); acceptability measure (UTAUT); Flow State Scale; Rating of Perceived Exertion; Subjective Mental Effort Questionnaire; HR
Gouveia e Silva, 2020^76^; Some concerns; 11 weeks; Instituto Giorgio Nicoli, Sao Paulo, Brazil; Coordination for Improvement of Higher Education Personnel—Brazil (CAPES) | Inclusion: “…individuals with a diagnosis of [post-polio syndrome] established by the consensus of Halstead and Rossi; 40–75 years of age, muscle strength degree >=3 in shoulders and elbows; motor function impairment (Motor Function Measure (MFM)-32 <=81), and who were not performing rehabilitation or physical exercise during intervention.”; Exclusion: “Individuals with clinically assessed shoulder subluxation by palpation (>=2 fingers), upper limb deformities that made it difficult to perform the interventions, and people who were not available to perform the 14 intervention sessions…” | N=19; Age, mean (SD): 54.94 (9.34); Female: 52.5%; Clinic; 50 min sessions twice weekly × 7 weeks, totaling 14 sessions; “[Interactive video game group] participants were positioned in front of a 32” TV placed 1.2m away and attached to the wall, 1.5m from the ground…Participants were then provided with two opportunities to practice for each game. Each game was performed with the help of the researcher who corrected the movements and posture of participants through guidance and verbal commands, instructing them to carry out each movement correctly, to reach the goal of the game. Each game was played for*10 minutes. Players reproduced the movements of each sport.” | N=20; Age, mean (SD): 55.58 (8.08); Female: 55%; Clinic; 50 min sessions twice weekly × 7 weeks, totaling 14 sessions; “[Active Exercises Group] performed similar movements required for playing the four videogames of the IVG… The AEG intervention included upper limb active exercises involving shoulder, elbow, and trunk, in blocks of 8 minutes with a 2-minute rest interval between the exercises (to avoid muscle fatigue).” | Primary: Motor Function Measure-32 (MFM-32); Pain intensity (7 wk, 11 wk); - VAS; Adverse events (11 wk); - Count of events such as upper limb pain, dizziness, nausea, and vomiting; Physical performance (7 wk, 11 wk); - Box and Block; - Functional Reach Assessment; Non-eligible: MFM-32; Functional Independence Measure (FIM); Fatigue Severity Scale; acceptability questions
Karahan, 2016^77^; Some concerns; 8 weeks; Physical Medicine and Rehabilitation Outpatient Clinic of Beyhekim State Hospital, Turkey; NR | Inclusion: “aged 18–65, lack of regular exercise habits during the previous six months.”; Exclusion: “the presence of cardiopulmonary dysfunction that hinders aerobic exercise, such as acute congestive heart failure, unstable angina pectoris, third-stage cardiac block, etc.; regular exercise habits during the previous six months; the presence of central or peripheral neurological disease; the presence of issues hindering standing, such as previous surgery on the lower extremities; the presence of a diagnosed serious psychiatric disorder; the presence of a serious visual disorder; the presence of a serious hearing disorder.” | N=28; Age, mean (SD): 36.1 (12.4); Female: 14%; Clinic; 30 minutes/day, 5 days a week for 8 weeks (40 sessions in total); ““Kinect Adventures,” “Kinect Sports” and “Kinect Sports Season Two” video game programs, which include soccer, table tennis, skiing, tennis, golfing, volleyball, and bowling simulations….” | N=29; Age, mean (SD): 36.6 (11.3); Female: 21%; Clinic; N/A\; No exercises or other treatments | Primary: Not clearly specified but pain at rest and during activity via VAS, change in BASFI score were listed first; Pain-related functioning (8 wk); - Bath Ankylosing Spondylitis Functional Index (BASFI); Pain intensity/severity (8 wk); - VAS; Quality of life (8 wk); - Ankylosing Spondylitis Quality of Life (ASQOL) questionnaire; Non-eligible: Bath Ankylosing Spondylitis Disease Activity Index (BASDAI)
Lewis, 2021^78^; High; 6 weeks; Clinics at The Royal National Hospital for Rheumatic Disease, Royal United Hospitals Bath NHS Foundation Trust, Bath and Walton Center NHS Foundation Trust, CRPS UK network registry, United Kingdom; National Institute for Health Research | Inclusion: “Met the Budapest clinical diagnostic criteria for CRPS affecting one upper limb; aged 18 or over”; Exclusion: “…had no co-morbidity that might influence CRPS symptoms, ie, stroke, diabetes, and fibromyalgia.” | N=23; Age, mean (SD): 52 (11); Female: 65%; Clinic; 5 sessions comprising 4 weekly intervention sessions and a final follow-up session 2 weeks later; “…participants sat with each arm placed into one of the two apertures of the MIRAGE system so that both hands rested palm down on a flat surface within the system… In response to the specific description given by each participant, changes were made in real time to aspects of shape, size and/or colour of the hand, based on how they wished their hand to look, i.e., their desired hand appearance. Participants rated their satisfaction of hand appearance whilst looking at the hand image…the image was further altered to…better match the participant’s desired hand appearance. Once they were satisfied, participants viewed the resultant image for 1 min. No visual changes were made to the unaffected hand…” | N=22; Age, mean (SD): 52 (14.5); Female: 64%; Clinic; 5 sessions comprising 4 weekly intervention sessions and a final follow-up session 2 weeks later; “The procedure and duration (approx. 1 min) for non-manipulation was exactly the same as that described in i) manipulated condition by the operator appearing to click the computer keys with the exception that the image was not actually visually altered, although the participant believed it to have been…. The hand image was viewed for 1 min and followed by post-intervention data collection.” | Primary: body perception disturbance, pain intensity rating scale, and perceptual statement ratings; Pain intensity/severity (1 wk, 6 wk); - NRS; Non-eligible: Body perception disturbance, perceptual statement ratings
Rothangel, 2018^79^; Some concerns; 6 months; Cologne University; 6 rehabilitation clinics, 2 private practices and 1 hospital, Germany; “State of North Rhine-Westphalia (NRW, Germany) and the European Union through the NRW Ziel2 Programme as a part of the European Regional Development Fund (grant no. 005-GW02-035)” | Inclusion: “…adult patients who had a unilateral lower limb amputation and reported an average intensity of PLP of 3 or more on the 11-point NRS and minimally one episode of PLP per week…No restrictions were made regarding gender, age, type of pain sensation or the time since amputation…eligible patients needed to have sufficient cognitive and communicative skills and motor functions in order to use the teletreatment, follow instructions and understand and fill out questionnaires.”; Exclusion: “…comorbidity such as stroke, pain or limited range of motion in the intact limb, severe mental disorders (eg, PTSD), living >50 km away from a participating center and having received more than 6 sessions of mirror therapy during the previous 3 months.” | N=26; Age, mean (SD): 59.7 (16.1); Clinic, home; 10 sessions (each 30-minutes) during first 4-weeks delivered by therapist, self-delivered exercises using iPad at home for 6 weeks; “During the first four weeks, [participants] performed exercises from the following categories with the intact limb in front of the mirror: observation of different positions, basic motor exercises, exercises using sensory stimuli, motor exercises using various objects and mental practice of phantom limb exercises). Patients were instructed to also perform the exercises with the phantom limb as soon as they perceived voluntary, pain-free movements of the phantom limb. During the last session, patients were given a tablet and a set of training materials. They received detailed verbal and written instructions on how to use the teletreatment… Patients were encouraged to use the teletreatment as often as they wished.” | Mirror Therapy; N=25; Age, mean (SD): 62.5 (11.4); Clinic, home; 10 sessions (30-minute each) during first 4-weeks, delivered by therapist, self-delivered MT at home afterwards; First 4-weeks same as iPad group, then “patients were encourages to perform self-delivered MT as much as they wished at home. No training materials were provided.” | Primary: Average pain intensity during preceding week on 11-pt NRS; Pain-related functioning (10 wk, 6 mo); - PDI; Pain intensity/severity (10 wk, 6 mo); - NRS; Quality of life (10 wk, 6 mo); - EuroQoL-5D; Pain global change (10 wk, 6 mo); - Global Perceived Effect (GPE) on pain; Non-eligible: Frequency and duration of phantom limb pain, neuropathic pain symptom inventory (NPSI), patient-specific functional scale (1-3), disturbance in sleep, disturbance in mood, pain-specific self-efficacy
| | | Sensomotor exercises; N=24; Age, mean (SD): 61 (15.2); Clinic, home; 10 sessions (30-minute each) during first 4-weeks, delivered by therapist. Self-delivered exercise as often as they wished.; “Patients received the same amount and frequency of sensomotor exercises performed with the intact limb as those in [other] groups during the first four weeks but without using a mirror. Instead, patients were instructed to look at their intact limb only during all exercises and not to perform exercises with their phantom limb. After these four weeks, patients were encouraged to perform self-delivered sensomotor exercises with the intact limb at home, without handing out training materials.”

Abbreviations. AR=augmented reality; BPI=Brief Pain Inventory; CBT=cognitive behavioral therapy; CRPS=Chronic Regional Pain Syndrome; DVPRS=Defense and Veterans Pain Rating Scale; EQ-5D-5L=European Quality of Life scale; ESR=erythrocyte sedimentation rate; FACIT=Functional Assessment of Chronic Illness Therapy scale; HR=heart rate; HRV=heart rate variability; LF/HF=low frequency to high frequency; MFM-32=Motor Function Measure-32; MME=morphine milligram equivalent; mo=month; MT=mirror therapy; NR=not reported; NRS=Numeric Rating Scale; PCS=Pain Catastrophizing Scale; PDI=Pain Disability Index; PHQ-8=Patient Health Questionnaire-8; QLQ-C30=EORTC Core Quality of Life questionnaire; RA=rheumatoid arthritis; S=seconds; SD=standard deviation; USA=United States of America; VR=virtual reality; wk=week.

Appendix Table I2 Detailed Results for KQ1 Other Conditions Studies

Author, Year; VR or AR; Risk of Bias | Effect Measure | Intervention; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparator; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparison
Pain-Related Functioning or Interference
Ambrosino, 2020^75^; AR; Some concerns | HAQ-function & fatigue | 1.8 (0.21); 12 wk: 1.1 (NR), −0.7^*^ | 1.75 (0.25); 12 wk: 1.6 (NR), −0.15^*^ | Diff ∆^*^:; 12 wk: −0.55
Cuneo, 2023^70^; VR; High | MIDAS | 100.36 (72.76); 12 wk: 72.64 (46.91), −27.72 | 77.55 (64.7); 12 wk: 59.5 (46.4), −18.05 | Diff ∆^*^:; 12 wk:−9.67
Chuan, 2023^71^; VR; Some concerns | BPI-Interference | 4.7 (2.4); 1 mo: 3.7 (2.4), −1.0^*^; 3 mo: 2.8 (2.7), −1.9^*^ | 4.1 (2.7); 1 mo: 4.1 (2.9), 0.0^*^; 3 mo: 3.8 (3.7), −0.3^*^ | Diff ∆^*^:; 1 mo: −1.0; 3 mo: −1.6
Darnall, 2020^72^; VR; High | DVPRS - Stress | 5.6 (2.8); 21 days: 2.8 (NR), −2.67 (3.02) | 5.1 (2.6); 21 days: 3.4 (NR), −1.67 (1.92) | Diff ∆^*^:; 21 days: −1.0
Darnall, 2020^72^; VR; High | DVPRS - Mood | 5.5 (2.7); 21 days: 2.8 (NR), −2.61 (2.79) | 4.8 (2.4); 21 days: 3.6 (NR), −1.58 (2.08) | Diff ∆^*^:; 21 days: −1.03
Darnall, 2020^72^; VR; High | DVPRS - Sleep | 5.5 (2.6); 21 days: 3.2 (NR), −2.25 (2.58) | 5.2 (2.4); 21 days: 3.8 (NR), −1.33 (2.09) | Diff ∆^*^:; 21 days: −0.92
Darnall, 2020^72^; VR; High | DVPRS - Activity | 4.9 (2.1); 21 days: 3.1 (NR), −1.95 (2.35) | 4.8 (2.2); 21 days: 4.2 (NR), −0.62 (2.33) | Diff ∆^*^:; 21 days: −1.33
Karahan, 2016^77^; AR; Some concerns | BASFI | 3.7 (1.5); 8 wk: 2.9 (1.3), −0.8^*^ | 3.9 (1.6); 8 wk: 3.9 (1.7), 0.0^*^ | Diff ∆^*^:; 8 wk: −0.8
Reynolds, 2022^73^; VR; Some concerns | BPI-short form (11 items) | 37.7 (95% CI 31.2, 44.2); 7 days: 35.2 (28.7, 42.0), −2.5^*^; 9 days: 33.8 (27.3, 40.3), −3.9^*^ | 42.1 (95% CI 35.5, 48.6); 7 days: 40.1 (33.4, 46.6), −2.0^*^; 9 days: 33.9 (27.3, 40.5), −8.2^*^ | Diff ∆^*^:; 7 days: −0.5; 9 days: 4.3
Rothgangel, 2018^79^; AR; Some concerns | PDI | 30.5 (16.5); 10 wk:21.5 (13.9), −9.0^*^; 6 mo: 20.6 (14.4), −9.9^*^ | 23.6 (18.2); 10 wk: 9.5 (10.9), −14.1^*^; 6 mo: 10.1 (16.9), −13.5 | Diff ∆:; 10 wk: 5.1; 6 mo: 3.6
Rothgangel, 2018^79^; AR; Some concerns | PDI | 30.5 (16.5); 10 wk:21.5 (13.9), −9.0^*^; 6 mo: 20.6 (14.4), −9.9^*^ | 32.0 (20.1); 10 wk: 19.1 (16.9), −12.9; 6 mo: 21.2 (20.0), −10.8 | Diff ∆:; 10 wk: 3.6; 6 mo: 0.9
Wankhade, 2022^74^; VR; High | SPADI | NR; 2 wk: NR, 30.68 (15.07) | NR; 2 wk: NR, 14.4 (2.93) | Diff ∆^*^:; 2 wk:16.28
Pain Intensity or Severity
Cuneo, 2023^70^; VR; High | Headache days/month | 23.71 (5.58); 12 wk: 15.64 (7.91), −8.07 | 25.41; 12 wk:17.77 (9.45), −7.64 | Diff ∆^*^:; 12 wk: −0.43
Chuan, 2023^71^; VR; Some concerns | BPI-Intensity | 4.9 (1.1); 1 mo: 4.5 (1.6), −0.4^*^; 3 mo: 4.1 (2.1), −0.8^*^ | 4.4 (1.9); 1 mo: 4.5 (2.2), 0.1^*^; 3 mo: 3.8 (2.7), −0.6^*^ | Diff ∆^*^:; 1 mo: −0.5; 3 mo: −0.2
Ditchburn, 2020^81^; AR; High | NRS (current) | 2.96 (1.87); 6 wk: 2.07 (2.11), −0.89^*^ | 3.33 (2.82); 6 wk: 3.48 (3.03), 0.15^*^ | Diff ∆^*^:; 6 wk: 1.04
Ditchburn, 2020^81^; AR; High | NRS (past 30 days) | 5.52 (2.24); 6 wk: 5.04 (2.21), −0.48^*^ | 6.0 (2.34); 6 wk: 5.85 (2.43), −0.15^*^ | Diff ∆^*^:; 6 wk: −0.33
Darnall, 2020^72^; VR; High | DVPRS | 4.7 (1.7); 21 days: 3.2 (NR), −1.5^*^ | 4.5 (1.8); 21 days: 3.8 (NR), −0.7 | Diff ∆^*^:; 21 days: −0.8
Gouveia e Silva, 2020^76^; AR; Some concerns | VAS | 6.22 (2.98); 7 wk: 2.0 (2.47), −4.22 (2.82); 11 wk: 2.33 (2.22), −3.89, (2.93) | 6.89 (1.59); 7 wk: 2.68 (1.53), −4.21 (1.87); 11 wk: 3.05 (1.47), −3.84 (1.83) | Diff ∆:; 7 wk: −0.01; 11 wk: −0.05
Karahan, 2016^77^; AR; Some concerns | VAS | 4.9 (2.0); 8 wk: 3.6 (1.7), −1.3^*^ | 5.1 (2.2); 8 wk: 5 (2.4), −0.1^*^ | Diff ∆^*^:; 8 wk: −1.2
Lewis, 2021^78^; AR; High | NRS | 5.7 (3.3); 6 wk: 5.15 (3.1), −0.55^*^ | 5.45 (3.4); 6 wk: 5.33 (3.4), −0.12^*^ | Diff ∆^*^:; 6 wk: −0.43
Rothgangel, 2018^79^; AR; Some concerns | NRS | 5.9 (1.9); 10 wk: 4.6 (1.9), −1.3^*^; 6 mo: 4.1 (2.6), −1.8^*^ | Non-AR mirror therapy: 5.4 (2.4); 10 wk: 3.6 (3.1), −1.8^*^; 6 mo: 2.7 (2.8), −2.7^*^ | Diff ∆:; 10 wk: 0.5; 6 mo: 0.9
Rothgangel, 2018^79^; AR; Some concerns | NRS | 5.9 (1.9); 10 wk: 4.6 (1.9), −1.3^*^; 6 mo: 4.1 (2.6), −1.8^*^ | Control: 5.8 (2.1); 10 wk: 4.1 (2.6), −1.7^*^; 6 mo: 4.5 (2.8), −1.3^*^ | Diff ∆:; 10 wk: 0.4; 6 mo: −0.5
Wankhade, 2022^74^; VR; High | NRS | NR; 2 wk: NR, 3.56 (0.5) | NR; 2 wk: NR, 2.52 (0.5) | Diff ∆^*^:; 2 wk: 1.04
Adverse Events
Cuneo, 2023^70^; VR; High | % with nausea, dizziness (VR only) | Nausea: 28.6%; Dizziness: 21.4% | AE not assessed | Diff ∆: NC
Chuan, 2023^71^; VR; Some concerns | % with nausea, dizziness, eyestrain during any VR session | Nausea: 4/19 (21%); Dizziness: 4/19 (21%); Eyestrain: 4/19 (21%) | Nausea: 5/20 (25%); Dizziness: 4/20 (20%); Eyestrain: 8/20 (40%) | Diff ∆^*^:; Nausea: 4%; Dizziness: 1%; Eyestrain: −19%
| Free text response on tolerability survey | NR | “For one control patient, the side-effect (severe headache) was severe enough to withdraw…and two control patients were unable to tolerate the headset and did not complete one of their virtual reality sessions.” | Diff ∆: NC
Ditchburn, 2020^81^; AR; High | AE, motion sickness | No events | No events | Diff ∆^*^:; 0
Darnall, 2020^72^; VR; High | Frequency of motion sickness or nausea while using VR (only for VR group | Never: 19/25 (76%); Sometimes: 5/25 (20%); Often: 1 (4%) | AE not assessed | Diff ∆: NC
Reynolds, 2022^73^; VR; Some concerns | Free-text questions on acceptability, suggestions for change | “…some participants reported adverse effects in using the VR headsets including feeling ‘claustrophobic’ and ‘…I got a bit dizzy/nauseous’.” | AE not assessed | Diff ∆: NC
Gouveia e Silva, 2020^76^; AR; Some concerns | % with late upper limb pain after first session | 15% | 10% | Diff ∆^*^:; 5%
Pain Catastrophizing
Cuneo, 2023^70^; VR; High | CAP | 16.07 (5.36); 12 wk: 13.21 (5.67), −2.86 | 11.86 (3.55); 12 wk: 11.36 (4.64), −0.5 | Diff ∆^*^:; 12 wk: −2.36
Pain Global Change
Darnall, 2020^72^; VR; High | PGIC | 21/25 (84%) pain improved, 4/25 (16%) no change, 0/25 worsening pain | 18/29 (62%) pain improved, 10/29 (34%) no change, 1/29 (3%) worsening pain | Diff ∆^*^:; Improved: 24%; Worsened: −3%
Rothgangel, 2018^79^; AR; Some concerns | GPE on pain | 10 wk: 1.1 (1.0); 6 mo: 1.4 (1.1) | non-AR mirror therapy; 10 wk: 1.4 (1.5); 6 mo: 1.2 (1.8) | Diff ∆^*^:; 10 wk: −0.3; 6 mo: 0.2
Rothgangel, 2018^79^; AR; Some concerns | GPE on pain | 10 wk: 1.1 (1.0); 6 mo: 1.4 (1.1) | Control; 10 wk: 1.0 (1.2); 6 mo: 0.8 (1.3) | Diff ∆^*^:; 10 wk: 0.1; 6 mo: 0.6
Quality of Life
Chuan, 2023^71^; VR; Some concerns | QLQ-C30 global quality subscale | 62 (25); 1 mo: 57 (18), −5^*^; 3 mo: 54 (25), −8^*^ | 55 (20); 1 mo: 57 (18), 2^*^; 3 mo: 56 (24), 1^*^ | Diff ∆^*^:; 1 mo: −7; 3 mo: −9
Karahan, 2016^77^; AR; Some concerns | ASQOL (0-18) | 9.5 (6.1); 8 wk: 6.8 (4.3), −2.7^*^ | 10.2 (6.0); 8 wk: 10.3 (6.4), 0.1 | Diff ∆^*^:; 8 wk: −2.8
Rothgangel, 2018^79^; AR; Some concerns | EuroQoL-5D | 0.6 (0.3); 10 wk: 0.7 (0.2), 0.1^*^; 6 mo: 0.8 (0.2), 0.2^*^ | Traditional mirror therapy; 0.6 (0.3); 10 wk: 0.8 (0.3), 0.2^*^; 6 mo: 0.7 (0.3), 0.1^*^ | Diff ∆^*^:; 10 wk: −0.1; 6 mo: 0.1
Rothgangel, 2018^79^; AR; Some concerns | EuroQoL-5D | 0.6 (0.3); 10 wk: 0.7 (0.2), 0.1^*^; 6 mo: 0.8 (0.2), 0.2^*^ | Control; 0.4 (0.3); 10 wk: 0.7 (0.3), 0.3^*^; 6 mo: 0.7 (0.3), 0.3^*^ | Diff ∆^*^:; 10 wk: −0.2; 6 mo: −0.1
Opioid Use
Chuan, 2023^71^; VR; Some concerns | Average MME in the previous week | Means NR; Median (IQR; baseline 0 (0-23; 1 mo0 (0-19; 3 mo0 (0-15 | Means NR; Median (IQR; Baseline 0 (0-24; 1 mo0 (0-38; 3 mo0 (0-51 | Diff ∆: NC
Physical Performance
Ditchburn, 2020^81^; AR; High | Postural sway with eyes open – AP SD | 5.45 (2.06); 6 wk: 4.64 (2.03), −0.81^*^ | 4.44 (1.4); 6 wk: 3.92 (1.66), −0.52^*^ | Diff ∆^*^:; 6 wk: −0.29
Ditchburn, 2020^81^; AR; High | Postural sway with eyes open – AP range | 25.92 (6.25); 6 wk: 21.25 (6.79), −4.67^*^ | 21.42 (5.89); 6 wk: 18.02 (7.54), −3.4^*^ | Diff ∆^*^:; 6 wk: −1.27
Ditchburn, 2020^81^; AR; High | Postural sway with eyes open – ML SD | 3.15 (1.89); 6 wk: 2.56 (1.52), −0.59^*^ | 2.13 (0.83); 6 wk: 1.84 (0.59), −0.29^*^ | Diff ∆^*^:; 6 wk: −0.3
Ditchburn, 2020^81^; AR; High | Postural sway with eyes open – ML range | 17.82 (10.24); 6 wk: 13.97 (7.72), −3.85^*^ | 12.42 (4.46); 6 wk: 10.17 (3.78), −2.25^*^ | Diff ∆^*^:; 6 wk: −1.6
Ditchburn, 2020^81^; AR; High | Postural sway with eyes open – Center of pressure velocity | 32.69 (10.73); 6 wk: 32.38 (9.58), −0.31 | 29.47 (6.72); 6 wk: 31.48 (10.43), 2.01 | Diff ∆^*^:; 6 wk: −2.32
Gouveia e Silva, 2020^76^; AR; Some concerns | Functional Reach Assessment | 31.1 (3.38); 7 wk: 34.4 (3.45), 2.28 (2.08); 11 wk: 34.1 (3.23), 1.94 (2.04) | 30.8 (3.10); 7 wk: 32.1 (3.47), 1.26 (1.10); 11 wk: 31.9 (3.57), 1.11 (1.15) | Diff ∆:; 7 wk: 1.02; 11 wk: 0.83
Gouveia e Silva, 2020^76^; AR; Some concerns | Box and Block test | 101 (10.9); 7 wk: 111 (15.7), 9.89 (8.96); 11 wk: 109 (13.95), 8.11 (7.51) | 88.2 (13.2); 7 wk: 92.7 (11.9), 4.58 (4.09); 11 wk: 91.4 (11.7), 3.21 (3.51) | Diff ∆:; 7 wk: 5.31; 11 wk: 4.90
Wankhade, 2022^74^; VR; High | Shoulder flexion ROM | NR; 2 wk: NR, 29.6 (8.88) | NR; 2 wk: NR, 23.4 (8.0) | Diff ∆^*^:; 2 wk: 6.2
Wankhade, 2022^74^; VR; High | Shoulder extension | NR; 2 wk: NR, 9.92 (3.12) | NR; 2 wk: NR, 6.8 (3.78) | Diff ∆^*^:; 2 wk: 3.12
Wankhade, 2022^74^; VR; High | Shoulder abduction | NR; 2 wk: NR, 34.0 (10.1) | NR; 2 wk: NR, 20.2 (10.04) | Diff ∆^*^:; 2 wk: 13.8
Wankhade, 2022^74^; VR; High | Shoulder adduction | NR; 2 wk: NR, 9.48 (1.89) | NR; 2 wk: NR, 6.4 (3.06) | Diff ∆^*^:; 2 wk: 3.08
Wankhade, 2022^74^; VR; High | Shoulder internal | NR; 2 wk: NR, 11.8 (2.84) | NR; 2 wk: NR, 7.4 (2.92) | Diff ∆^*^:; 2 wk: 4.4
Wankhade, 2022^74^; VR; High | Shoulder external | NR; 2 wk: NR, 12.84 (2.86) | NR; 2 wk: NR, 11.0 (3.22) | Diff ∆^*^:; 2 wk: 1.84

Notes.

* Calculated by review team.

Abbreviations. AR=augmented reality; ASQOL=Ankylosing Spondylitis Quality of Life; BASFI=Bath Ankylosing Spondylitis Functional Index; BPI=Brief Pain Inventory; CAP=Concerns About Pain; CI=confidence interval; Diff ∆= difference in change scores; DVPRS=Defense and Veteran Pain Rating Scale; EuroQoL-5D= European Quality of Life 5 Dimensions; GPE=Global Perceived Effect; HAQ=Health Assessment Questionnaire; IQR=interquartile range; MIDAS=Migraine Disability Assessment; MME=morphine milligram equivalents; mo=month; NR=not reported; NRS=Numeric Rating Scale; oMEDD=oral morphine equivalent daily dose; PCS=Pain Catastrophizing Scale; PDI=Pain Disability Index; PGIC=Patient Global Impression of Change; QLQ-C30=Quality of Life Questionnaire-C30; ROM=range of motion; SD=standard deviation; SPADI=Shoulder Pain and Disability Index; VAS=Visual Analog Scale; VR=virtual reality; wk=week.