# APPENDIX H CHRONIC KNEE PAIN

Appendix Table H1 Detailed Characteristics for Included Trials on Chronic Knee Pain

Author, Year; Risk of Bias; Follow-Up Duration; Site(s); Funding source | Inclusion/Exclusion Criteria | Intervention: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Intervention Characteristics | Comparator(s): Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Comparator Characteristics | Primary Outcome; Eligible Outcomes & Measures Reported (Time Points); Other Non-Eligible Outcomes Reported
VR Intervention
Ozlu, 2023^65^; High; 7 weeks; Kutahya Health Sciences University, Turkey; No funding | Inclusion:; Age between 40 and 64 years; American College of Rheumatology concordant diagnosis of stage 2 or 3 knee OA; Minimental status test score of ≥22; Exclusion:; Recent or previous operation on the affected lower extremity; History of lower extremity injury including fracture, meniscus and/or ligament tear; History of intra-articular injection to the affected knee in preceding 6 months, knee physical therapy in preceding 6 months; History of rheumatological disease, septic arthritis, cardiovascular disease or other impairment affecting ability to exercise, balance, hearing or vision | N=41; Age, mean (SD): 53.3(10.4); Female: 48.6%; Clinic; 15 mins VR (in addition to time for ultrasound and TENS) per day, 5 days a week (total 15 sessions) 3 weeks; Fish Game: Participants wear Oculus VR glasses and intercept incoming virtual fish using lateral flexion movement of the trunk. Training focused on weight transfer, balance and proprioception of the patients.; Monkey Game: Participants wear Oculus VR glasses and intercept incoming virtual bananas using lateral stepping movements. Training focused on patient depth sense. | N=41; Age, mean (SD): 53.7(9.7); Female: 68.4%; Clinic; 27 mins per day, 5 days/week (total 15 sessions) 3 weeks; Therapeutic ultrasound to affected knee for 7 minutes; Transcutaneous electrical nerve stimulation on both knees for 20 minutes | Primary outcome NR; Pain-related functioning (3, 7 wk); - WOMAC; Pain intensity (3, 7 wk); - VAS; Physical performance (3, 7 wk); - 6-min walk; - Berg Balance Scale
AR Interventions
Elshazly, 2016^66^; Some concerns; 8 weeks; Prince Sattam Bin Abdul Aziz University, Saudi Arabia; Grant from deanship of scientific research, Prince Sattam Bin Abdul Aziz University, Saudi Arabia | Inclusion:; Male and Female; Age between 35 and 65 years; ≥ 3 months of symptomatic osteoarthrits; Ambulate at least 30 feet with or without assistance; Not in any sports or physical therapy; Able to complete physical therapy three times weekly; Exclusion:; Acute medical illness or knee surgery within 6 months of enrollment; History of metal implants, peripheral vascular disease, infection, fever, mental deficit, femur or tibial condyle fracture, joint effusion, laboratory abnormality, systemic or psychiatric illness, corticosteroid use in the preceding 30 days, malignancy, gout or any other disease preventing participation | AR Physical Activity:; N=20; Age, mean (SD): 58(6); NR; NR; 15-30 minute sessions, 3 times weekly 8 weeks; Light Race: Participants use Xbox 360 Kinect to step on a virtual platform displayed on a monitor. On-screen commands have participants step forward, backward, right and left in both sitting and standing positions for 10 repetitions with a two-minute rest between exercises. Exercises focused on lower limb strength, flexibility, coordination, and balance. Sessions were held in small groups of three or less subjects | Sensorimotor Training (SMT):; N=20; Age, mean (SD):; 60(8); NR; NR; 3 times weekly; 8 weeks; Participants were trained through three stages:; Static [ie, standing upright position (30 s), single leg stance with closed eyes, half-step position for 10 s, one-leg balance for 10 s]; Dynamic [ie, forward stepping thrust, T-band kicks exercise],; Functional [ie, 1) walking exercise on a firm surface, then on a foam surface: (a) toe skipping, (b) heel skipping; 2) squatting exercise: (a) against a wall and away from the wall, (b) one leg squats on affected and non-affected limbs; 3) balance exercise on wobble board: (a) multidirectional rolling movement from sitting, (b) multidirectional rolling movement from standing on both legs between parallel bars with eyes open, then eyes closed, (c) multidirectional rolling movement from standing on one leg between parallel bars with eyes open, then eyes closed].” | Primary outcome NR; Pain-related functioning (4, 8 wk); - WOMAC; Pain intensity; (4, 8 wk); - VAS; Physical performance (4, 8 wk); - Position sense; Quality of life (4, 8 wk); - CDC Health Related Quality of Life
Elshazly, 2016^66^; Some concerns; 8 weeks; Prince Sattam Bin Abdul Aziz University, Saudi Arabia; Grant from deanship of scientific research, Prince Sattam Bin Abdul Aziz University, Saudi Arabia | | | Conventional Exercise Therapy (CET):; N=20; Age, mean (SD): 59(7); NR; NR; 3 times weekly; 8 weeks; 5 minutes warm up followed by 12 minutes of walking at comfortable pace and 5 minutes cool down.
Lin, 2020^67^; Some concerns; 3 months; Shin Kong Wu Ho-Su Memorial Hospital, Taiwan; Grants from Shin Kong Wu Ho-Su Memorial Hospital and Ministry of Science and Technology, Taiwan | Inclusion:; Age 40 to 85 years; American College of Rheumatology concordant diagnosis of knee OA; Kellgren and Lawrence score ≥2; Able to walk > 15 m; Able to undergo 4 weeks of treatment and 3 months of follow-up; Not needing non-steroidal anti-inflammatory drugs during the research; Exclusion:; Any infection, inflammation, autoimmune disease, or fracture; History or underlying disease affecting posture and balance, such as malignancy, dizziness, vertigo, or stroke; History of any knee operation or internal fixation; Pregnancy or planning to become pregnant; Undergoing any other treatment for knee OA.” | N=40; Age, mean (SD): 55.9(15.8); Female: 60%; Clinic; 3 times per week; 4 weeks; Hot packs applied to both knees for 20 min, transcutaneous electric nerve stimulation (TENS) for 20 min, 20 min of active video games or therapeutic exercise; Whack-a-mole: Participants use Hot Plus gaming system and a step sensing pad. Participants step on step sensing pad to stamp on-screen moles into holes. Training focused on fast movement and improving lower limb range of motion, strength and coordination. Activity lasts 10 minutes.; Archery: Participants use Hot Plus gaming system and a step sensing pad. Participant steps on sensing pad to shoot arrows at on-screen targets. Training focused on fast movement and improving lower limb range of motion, strength, and coordination. Activity last 10 minutes. | N=40; Age, mean (SD): 58.1(16.9); Female: 42.5%; Clinic; 3 times per week; 4 weeks; Hot packs applied to both knees for 20 min, transcutaneous electric nerve stimulation (TENS) for 20 min, 20 min of active video games or therapeutic exercise; Therapeutic exercise includes stretching warm-up, stabilization exercises, weight-shift training for knees and pelvis …, cycling for 10 min with approximately 40% to 60% heart rate reserve, and stretching cool-down. Sandbag and Thera-band were used in strength exercises with a maximum of 10 repetitions and 5 to 10 repetitions per session, for 3 to 5 sets. Activity lasts for a total of 20 min and supervised by physical therapists. | Primary: WOMAC (only separate domain scores for pain, stiffness, & function); Pain intensity (2, 4, 8, 16 wk); - Chronic Pain Grade Questionnaire- overall grade; disability points; disability score; pain intensity; Adverse events (4 wk); - Non-specific adverse events; Physical performance (2, 4, 8, 16 wk); - Biodex Stability System, Postural Stability & Limits of Stability,; - 10 m walk; - Stair ascent, descent times; Quality of life (2, 4, 8, 16 wk); - WHOQOL-BREF (domain scores for physical, psychological, social, & environmental); Other non-eligible outcomes reported; - HADS; - Multidimensional Fatigue Inventory; - Work Ability Index
Mete, 2022^68^; High; 6 Weeks; Physical therapy and rehabilitation clinic of medical center (name NR) in Istanbul, Turkey; Marmara University Scientific Research Projects Committee (Project Number: SAG-C-YLP-070617-0349) | Inclusion:; Aged 40 to 65 years; Diagnosis of knee OA; Kellgren Lawrence stage 2 or 3; Exclusion:; History of surgery at knee, hip, ankle, or/and foot, systemic anti-inflammatory joint disease, any condition with contraindication for electrical stimulation and/or exercise, previous knee physiotherapy in preceding 6 months and a history of corticosteroid injection in preceding 3 months | N=32; Age, mean (SD): NR; Median age: 59.5 (55,64); Female: 80%; Clinic; 20 games for 5 days per week; 6 weeks; Crazy Wings: Participant controls an on-screen bird avatar through obstacles using knee movement. Sensors from the MarVAJED system were placed above and below knee, which evaluate the ROM of the joints, analyze the sensation of joint position, and allow control of on-screen avatars. Knee flexion and extension triggers bird avatar movement up and down, respectively. Training aimed to have participants complete squat exercises.; Blasting Ball: Participant controls the size of a virtual ball size on a screen through knee flexion. Sensors from the MarVAJED system were placed above and below knee, which evaluate the ROM of the joints, analyze the sensation of joint position, and allow control of on-screen avatars. The ball would explode when the degree of knee flexion reached a peak value. Training aimed to have participants complete leg press exercises and increase degree of knee flexion. | N=32; Age, mean (SD): NR; Median age: 57 (51, 65); Female: 76.6%; Clinic; 5 days per week; 6 weeks; Electrotherapy, exercise program, hot and cold pack therapy, therapeutic ultrasound, and conventional transcutaneus electrical nerve stimulation were completed. Participants with edema were treated with a cold pack, and participants without edema received hot pack. Exercise program consists of isometric strengthening of the quadriceps muscle, terminal knee extension, leg press exercise with elastic band, and hamstring stretching. Elastic band training involved 3 sets of 10 repetitions. | Primary outcome NR; Pain related functioning or interference (6 wk); - WOMAC-stiffness; - WOMAC-function; Pain intensity (6 wk); - WOMAC-pain; - VAS; Pain Catastrophizing (6 wk); - TSK; Physical performance (6 wk); - PEDALO Sensamove balance score; - Knee flexion/extension ROM; - Knee proprioception at 30, 60 degrees; - Peak torque of knee flexion/extension (absolute and normalized to body weight) at 120°, 240°
Nambi, 2020c^69^; Some concerns; 3 months; Prince Sattam Bin Abdulaziz University Hospital and King Khalid Hospital, Al-Kharj, Saudi Arabia; Deanship of Scientific Research at Princess Nourah bint Abdulrahman University through the Fast-track Research Funding Program | Inclusion:; Male gender; Age 18 to 25 years; ≥3 months post-traumatic osteoarthritis following ACL injury as diagnosed by an orthopedic surgeon; Pain rating 4 to 8 in visual analog scale (VAS); Exclusion:; Other orthopedic, neural, systemic, psychological diagnosis; Any pending surgical procedure; Participation in any other treatment and physical training | N=20; Age, mean (SD): 22.8(1.3); NR; Clinic; 2 20-minute sessions per day, 5 days a week; 4 weeks; Participants used the Pro-Kin system PK 252 N Techno body. Training involved standing on the affected limb and following commands on a computer display screen to shoot virtual balls. Interaction with balls was controlled by having the participant follow specified knee movements. | SMT:; N=20; Age, mean (SD): 22.6(1.4); NR; Clinic; 5 days per week; 4 weeks; Sensorimotor training exercises in three consecutive stages: Static phase where the participant stands straight for 30 seconds on a hard plate and 30 seconds on a foam plate. Next, the participant was instructed to stand on a single leg (affected side) with closed eyes for 20 seconds on a hard plate and 20 seconds on a foam plate, followed by a semi knee bending position for 10 seconds. Dynamic phase where the participant performs forward kicking for 30 seconds and T-band kicking for 30 seconds. Functional phase where the participant was informed to do toe jumping for 20 meters and heel jumping for 20 meters. Then the participant performs bilateral and unilateral squatting exercises for 10 repetitions with and without the support of a wall. All exercises were continued for 3 sets each with 5 repetitions and 3 minutes rest between the sets. | Primary outcome NR; Pain related functioning or interference (4, 8 wk, 3 mo); - WOMAC-total; Pain intensity (4, 8 wk, 3 mo); - VAS; Other non-eligible outcomes reported; - Bone morphogenic protein levels (BMP 2,4,5 and 7); - Inflammatory biomarkers serum levels (CRP, TNF-alpha, IL2, IL4 and IL6)
| | | Control, Supervised Exercise:; N=20; Age, mean (SD): 21.9(1.3); NR; Clinic or health care facility; 5 days per week; 4 weeks; Control group completed supervised conventional exercise programs for the knee muscles. Exercises laid special stress on the quadriceps, hamstrings, glutei, and calf muscles. The participants performed 10–15 repetitions in one set for 3 sets with 1 minute rest between the sets. Then participants completed stretching focused on each muscle group for 3 repetitions for 15 seconds per muscle group”

Abbreviations. ACL=anterior cruciate ligament; AR=augmented reality; BMP=bone morphogenic protein; CET=conventional exercise therapy; CDC=Centers for Disease Control and Prevention; CRP=C reactive protein; HADS=Hospital Anxiety and Depression Scale; IL=interleukin; m=minutes; MarVAJED=Marmara visual auditory joint education device; Nm=Newton meter; NR=not reported; OA=osteoarthritis; PTOA=post-traumatic osteoarthritis; ROM=range of motion; s=seconds; SD=standard deviation; TENS= transcutaneous electric nerve stimulation; TNF=tumor necrosis factor; US=ultrasound; VAS=visual analogue scale; VRT=virtual reality training; WHO-BREF=World Health Organization Quality of Life-Brief Version; WOMAC=Western Ontario and McMaster Universities Arthritis Index.

Appendix Table H2 Detailed Results for Chronic Knee Pain Studies

Author, Year; VR or AR; Risk of Bias | Effect Measure | Intervention; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparator; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparison
Pain-Related Functioning or Interference
Elshazly, 2016^66^; AR; Some concerns | WOMAC-total | 71.6 (3.4); 4 wk: 39.8 (7.8), −31.9^*^; 8 wk: 14.6 (3.1), −57.0^*^ | Sensorimotor training (SMT); 71.7 (2.8); 4 wk: 53.3 (3.8), −18.4^*^; 8 wk: 34.1 (3.9), −37.6^*^ | Diff ∆^*^:; 4 wk: −13.5; 8 wk: −19.5
Elshazly, 2016^66^; AR; Some concerns | WOMAC-total | 71.6 (3.4); 4 wk: 39.8 (7.8), −31.9^*^; 8 wk: 14.6 (3.1), −57.0^*^ | Conventional exercise training (CET); 71.9 (3.05); 4 wk: 54.1 (6.1), −17.8^*^; 8 wk: 44.8 (4.3), −27.2^*^ | Diff ∆^*^:; 4 wk: −14.05; 8 wk: −29.9
Lin, 2020^67^; AR; Some concerns | WOMAC-function | 505.1 (328.4); 2 wk: 520.3 (296.7),15.2^*^; 4 wk: 510.6 (303.5), 5.5^*^; 8 wk: 472.5 (300.1), −32.6^*^; 16 wk: 456.4 (298.2), −48.7^*^ | 581.0 (383.8); 2 wk: 557.1 (218.5), −23.9^*^; 4 wk: 526.2 (314.6), −54.8^*^; 8 wk: 458.4 (331.1), −122.6^*^; 16 wk: 449.5 (220.2), −131.5^*^ | Diff ∆^*^:; 2 wk: 39.1; 4 wk: 60.3; 8 wk: 90.0; 16 wk: 82.8
Lin, 2020^67^; AR; Some concerns | Graded Chronic Pain Scale, Overall Pain Grade | 1.5 (0.4); 2 wk: 1.3 (0.3), −0.2^*^; 4 wk:1.2 (0.3), −0.3^*^; 8 wk:1.2 (0.2), −0.3^*^; 16 wk: 1.0 (0.2), −0.5^*^ | 1.4 (0.5); 2 wk: 1.4 (0.4), 0.0^*^; 4 wk: 1.2 (0.1), −0.2^*^; 8 wk: 1.3 (0.3), −0.1^*^; 16 wk: 1.1 (0.2), −0.3^*^ | Diff ∆^*^:; 2 wk: −0.2; 4 wk: −0.1; 8 wk: −0.2; 16 wk: −0.2
Lin, 2020^67^; AR; Some concerns | Graded Chronic Pain Scale, disability score | 38.6 (20.8); 2 wk: 35.7 (20.3), −2.9^*^; 4 wk: 34.2 (21.2), −4.4^*^; 8 wk: 33.2 (19.3), −5.4^*^; 16 wk: 34.4 (19.2), −4.2^*^ | 39.3 (21.5); 2 wk: 38.3 (21.7), −1.0^*^; 4 wk: 37.6 (20.4), −1.7^*^; 8 wk: 36.7 (19.6), −2.6^*^; 16 wk: 35.6 (20.3), −3.7^*^ | Diff ∆^*^:; 2 wk: −1.9; 4 wk: −2.7; 8 wk: −2.8; 16 wk: −0.5
Mete, 2022^68^; AR; High | WOMAC-total | Means NR; Medians (IQR):; 19.7 (18.2, 21); 6 wk: 7.59 (4.95, 9.4) | Means NR; Medians (IQR):; 15.1 (9.3, 18); 6 wk: 9.9 (6.4, 11.5) | Diff ∆: NC
Mete, 2022^68^; AR; High | WOMAC-function | Means NR; Medians (IQR):; 6.74 (6.4, 7.2); 6 wk: 2.35 (2, 3.38) | Means NR; Medians (IQR):; 5.2 (5.7, 6.4); 6 wk: 3.23 (2.45, 3.18) | Diff ∆: NC
Nambi, 2020c^69^; AR; Some concerns | WOMAC-total | 72.33 (4.2); 4 wk: 34.1 (3.4), −38.2^*^; 8 wk: 22.4 (2.1), −49.9^*^; 3 mo: 11.2 (2.1), −61.1^*^ | SMT:; 72.47 (4.5); 4 wk: 56.3 (3.8), −16.2^*^; 8 wk: 32.4 (2.8), −40.1^*^; 3 mo: 25.3 (2.1), −47.2^*^ | Diff ∆^*^:; 4 wk: −22.1; 8 wk: −9.8; 3 mo: −13.9
Nambi, 2020c^69^; AR; Some concerns | WOMAC-total | 72.33 (4.2); 4 wk: 34.1 (3.4), −38.2^*^; 8 wk: 22.4 (2.1), −49.9^*^; 3 mo: 11.2 (2.1), −61.1^*^ | CET:; 71.2 (3.8); 4 wk: 62.3 (3.2),; 8 wk: 52.3 (3.2), −18.9^*^; 3 mo: 35.2 (2.8), −36.0^*^ | Diff ∆^*^:; 4 wk: −29.3; 8 wk: −30.9; 3 mo: −25.1
Ozlu, 2023^65^; VR; High | WOMAC-total | 31.66 (6.75); 3 wk: 23.1 (8.7), −8.6^*^; 7 wk: 26.4 (9.4), −5.2^*^ | 33.0 (7.86); 3 wk: 33.1 (7.9), 0.1^*^; 7 wk: 32.9 (7.9), −0.2^*^ | Diff ∆^*^:; 3 wk: −8.7; 7 wk: −5.0
Pain Intensity or Severity
Elshazly, 2016^66^; VR; Some concerns | VAS | 6.81 (0.87); 4 wk: 3.7 (1.1), −3.1^*^; 8 wk: 2.9 (0.97), −3.9^*^ | SMT:; 6.62 (1.17); 4 wk: 5.4 (0.96), −1.2^*^; 8 wk: 4.5 (0.8), −2.1^*^ | Diff ∆^*^:; 4 wk: −1.9; 8 wk: −1.8
Elshazly, 2016^66^; VR; Some concerns | VAS | 6.81 (0.87); 4 wk: 3.7 (1.1), −3.1^*^; 8 wk: 2.9 (0.97), −3.9^*^ | CET:; 6.68 (0.84); 4 wk: 5.37 (0.9), −1.3^*^; 8 wk: 4.74 (0.7), −1.9^*^ | Diff ∆^*^:; 4 wk: −1.8; 8 wk: −1.97
Lin, 2020^67^; AR; Some concerns | WOMAC-pain | 161.2 (114.7); 2 wk: 160.9(109.4), −0.3^*^; 4 wk: 155.6 (103.1), −5.6^*^; 8 wk: 119.8 (89.5), −41.4^*^; 16 wk: 102.3 (88.9), −58.9^*^ | 170.2 (121.3); 2 wk: 169.2 (120.1), −1.0^*^; 4 wk: 160.7 (118.2), −9.5^*^; 8 wk: 148.7 (106.7), −21.5^*^; 16 wk: 106.4 (97.3), −63.8^*^ | Diff ∆^*^:; 2 wk: 0.7; 4 wk: 3.9; 8 wk: −19.9; 16 wk: 4.9
Lin, 2020^67^; AR; Some concerns | WOMAC-stiffness | 76.9 (60.4); 2 wk: 74.3 (59.1), −2.6^*^; 4 wk: 72.8 (56.7), −4.1^*^; 8 wk: 69.9 (52.2), −7.0^*^; 16 wk: 64.4 (52.1), −12.5^*^ | 65.2 (53.7); 2 wk: 66.1 (52.4), 0.9^*^; 4 wk: 67.2 (53.2), 2.0^*^; 8 wk: 61.6 (51.6), −3.6^*^; 16 wk: 63.4 (55.7), −1.8^*^ | Diff ∆^*^:; 2 wk: −3.5; 4 wk: −6.1; 8 wk: −3.4; 16 wk: −10.7
Lin, 2020^67^; AR; Some concerns | Graded Chronic Pain Scale, pain intensity | 47.8 (20.3); 2 wk: 42.5(19.5), −5.3^*^; 4 wk: 46.2 (19.3), −1.6^*^; 8 wk: 44.6 (20.1), −3.2^*^; 16 wk: 43.3 (19.4), −4.5^*^ | 48.4 (20.7); 2 wk: 49.7 (19.5), 1.3^*^; 4 wk: 48.2 (21.2), −0.2^*^; 8 wk: 47.3 (19.1), −1.1^*^; 16 wk: 46.5 (18.2), −1.9^*^ | Diff ∆^*^:; 2 wk: −6.6; 4 wk: −1.4; 8 wk: −2.1; 16 wk: −2.6
Mete, 2022^68^; AR; High | VAS at rest | Means NR; Medians (IQR):; 32.2 (20.75, 40; 6 wk: 10 (0, 12.5) | Means NR; Medians (IQR):; 36.6 (30, 40); 6 wk: 20 (10, 20) | Diff ∆: NC
Mete, 2022^68^; AR; High | VAS with activity | Means NR; Medians (IQR):; 74.2 (60, 80); 6 wk: 30 (30, 40) | Means NR; Medians (IQR):; 65.2 (50, 70); 6 wk: 40 (30, 40) | Diff ∆: NC
Mete, 2022^68^; AR; High | VAS at night | Means NR; Medians (IQR):; 43 (27.5, 40); 6 wk: 10 (0, 20) | Means NR; Medians (IQR):; 44 (20, 50); 6 wk: 20 (10, 30) | Diff ∆: NC
Mete, 2022^68^; AR; High | WOMAC-pain | Means NR; Medians (IQR):; 6 (5.37, 7.12); 6 wk: 2.25 (1.5, 3) | Means NR; Medians (IQR):; 4.5 (4.3, 6); 6 wk: 3 (2.5, 4) | Diff ∆: NC
Nambi, 2020c^69^; AR; Some concerns | VAS | 7.2 (0.5); 4 wk: 3.3 (0.4), −3.9^*^; 8 wk: 2.5 (0.4), −4.7^*^; 3 mo: 0.5 (0.3), −6.7^*^ | SMT: 7.4 (0.4); 4 wk: 5.8 (0.5), −1.6^*^; 8 wk: 3.5 (0.5), −3.9^*^; 3 mo: 1.5 (0.4), −5.9^*^ | Diff ∆^*^:; 4 wk: −2.3; 8 wk: −0.8; 3 mo: −0.8
Nambi, 2020c^69^; AR; Some concerns | VAS | 7.2 (0.5); 4 wk: 3.3 (0.4), −3.9^*^; 8 wk: 2.5 (0.4), −4.7^*^; 3 mo: 0.5 (0.3), −6.7^*^ | Control: 7.3 (0.4); 4 wk: 6.5 (0.5), −0.8^*^; 8 wk: 4.2 (0.5), −3.1^*^; 3 mo: 3.8 (0.4), −3.5^*^ | Diff ∆^*^:; 4 wk: −3.1; 8 wk: −1.6; 3 mo: −3.2
Ozlu, 2023^65^; VR; High | Visual analog scale (VAS) | 5.57 (0.88); 3 wk: 4.11 (1.34), −1.46^*^; 7 wk: 4.05 (0.72), −1.52^*^ | 5.78 (0.74); 3 wk: 5.05 (1.43), −0.73^*^; 7 wk: 5.36 (0.99), −0.42^*^ | Diff ∆^*^:; 3 wk: −0.73; 7 wk: −1.1
Adverse Events
Lin, 2020^67^; AR; Some concerns | Adverse effects (during 4 wks of intervention) | “No adverse effects were reported during or after treatment in either group.” | | NR
Pain Catastrophizing & Kinesiophobia
Mete, 2022^68^; AR; High | TSK | Means NR; Medians (IQR):; 46.5 (42.7, 50); 6 wk: 39 (36.7, 40) | Means NR; Medians (IQR):; 48 (45, 49.25); 6 wk: 45.5 (41, 48) | Diff ∆: NC
Quality of Life
Elshazly, 2016^66^; AR; Some concerns | CDC Health Related Quality of Life | 1.35 (0.48); 4 wk: 3.1 (0.5), 1.8^*^; 8 wk: 4.5 (0.6), 3.2^*^ | SMT:; 1.60 (0.50); 4 wk: 2.5 (0.5), 0.9^*^; 8 wk: 3.3 (0.5), 1.7^*^ | Diff ∆^*^:; 4 wk: 0.9; 8 wk: 1.4
Elshazly, 2016^66^; AR; Some concerns | CDC Health Related Quality of Life | 1.35 (0.48); 4 wk: 3.1 (0.5), 1.8^*^; 8 wk: 4.5 (0.6), 3.2^*^ | CET:; 1.6 (0.51); 4 wk: 2.2 (0.4), 0.7^*^; 8 wk: 2.5 (0.5), 0.95^*^ | Diff ∆^*^:; 4 wk: 1.1; 8 wk: 2.2
Lin, 2020^67^; AR; Some concerns | WHOQOL-BREF Physical | 58.1 (10.2); 2 wk: 58.4 (9.1), 0.3^*^; 4 wk: 59.2 (7.4), 1.1^*^; 8 wk: 59.3 (7.5), 1.2^*^; 16 wk: 61.1 (6.6), 3.0^*^ | 53.4 (12.1); 2 wk: 53.1 (11.5), −0.3^*^; 4 wk: 53.2 (11.2), −0.2^*^; 8 wk: 54.1 (10.3), 0.7^*^; 16 wk: 54.5 (10.9), 1.1^*^ | Diff ∆^*^:; 2 wk: 0.6; 4 wk: 1.3; 8 wk: 0.5; 16 wk: 1.9
Lin, 2020^67^; AR; Some concerns | WHOQOL-BREF Psychological | 57.2 (10.4); 2 wk: 57.5 (10.1), 0.3^*^; 4 wk: 58.1 (9.6), 0.9^*^; 8 wk: 58.4 (9.7), 1.2^*^; 16 wk: 60.0 (9.4), 2.8 | 58.7 (9.8); 2 wk: 58.9 (9.8), 0.2^*^; 4 wk: 59.0 (9.4), 0.3^*^; 8 wk: 59.4 (8.9), 0.7^*^; 16 wk: 60.2 (8.8), 1.5 | Diff ∆^*^:; 2 wk: 0.1; 4 wk: 0.6; 8 wk: 0.5; 16 wk: 1.3
Lin, 2020^67^; AR; Some concerns | WHOQOLBREF, social | 57.3 (12.60); 2 wk: 57.4 (11.2), 0.1^*^; 4 wk: 58.2 (10.8), 0.9^*^; 8 wk: 58.4 (10.1), 1.1^*^; 16 wk: 60.3 (9.9), 3.0^*^ | 54.4 (12.60); 2 wk: 55.9 (13.9), 1.5^*^; 4 wk: 55.9 (14.4), 1.5^*^; 8 wk: 57.3 (13.7), 2.9^*^; 16 wk: 57.4 (13.2), 3.0^*^ | Diff ∆^*^:; 2 wk: −1.4; 4 wk: −0.6; 8 wk: −1.8; 16 wk: 0.0
Lin, 2020^67^; AR; Some concerns | WHOQOL-BREF, environmental | 60.4 (9.8); 2 wk: 60.8 (9.9), 0.4^*^; 4 wk: 61.1 (10.1), 0.7^*^; 8 wk: 61.3 (9.2), 0.9^*^; 16 wk: 61.9 (9.3), 1.5^*^ | 58.9 (10.6); 2 wk: 59.2 (10.2), 0.3^*^; 4 wk: 59.3 (9.8), 0.4^*^; 8 wk: 59.7 (10.1), 0.8^*^; 16 wk: 60.2 (9.6), 1.3^*^ | Diff ∆^*^:; 2 wk: 0.1; 4 wk: 0.3; 8 wk: 0.1; 16 wk: 0.2
Physical Performance
Elshazly, 2016^66^; VR; Some concerns | Position sense | 118.9 (4.60); 4 wk: 127.6 (2.06), 8.7^*^; 8 wk: 134.0 (1.16), 15.1^*^ | SMT:; 120.5 (4.16); 4 wk: 123.5 (2.28), 3.0^*^; 8 wk: 127.0 (1.93), 6.5^*^ | Diff ∆^*^:; 4 wk: 5.7; 8 wk: 8.6
Elshazly, 2016^66^; VR; Some concerns | Position sense | 118.9 (4.60); 4 wk: 127.6 (2.06), 8.7^*^; 8 wk: 134.0 (1.16), 15.1^*^ | CET:; 120.95 (3.79); 4 wk: 123.1 (3.29), 2.15^*^; 8 wk: 124.45 (2.96), 3.5^*^ | Diff ∆^*^:; 4 wk: 6.6; 8 wk: 11.6
Lin, 2020^67^; AR; Some concerns | Biodex Stability System, Postural Stability | 0.7 (0.5); 2 wk: 0.6 (0.4), −0.1^*^; 4 wk: 0.6 (0.5), −0.1^*^; 8 wk: 0.5 (0.3), −0.2^*^; 16 wk: 0.5 (0.2), −0.2^*^ | 0.8 (0.4); 2 wk: 0.7 (0.5), −0.1^*^; 4 wk: 0.6 (0.4), −0.2^*^; 8 wk: 0.5 (0.3), −0.3^*^; 16 wk: 0.5 (0.4), −0.3^*^ | Diff ∆^*^:; 2 wk: 0.0; 4 wk: 0.1; 8 wk: 0.1; 16 wk: 0.1
Lin, 2020^67^; AR; Some concerns | Biodex Stability System, Limits of Stability | 40.2 (12.9); 2 wk: 41.0 (12.6), 0.8^*^; 4 wk: 42.1 (12.1), 1.9^*^; 8 wk: 43.4 (11.5), 3.2^*^; 16 wk: 45.5 (10.7), 5.3^*^ | 41.5 (12.7); 2 wk: 42.1 (14.8), 0.6^*^; 4 wk: 41.9 (14.1), 0.4^*^; 8 wk: 42.6 (13.2), 1.1^*^; 16 wk: 44.3 (12.4), 2.8^*^ | Diff ∆^*^:; 2 wk: 0.2; 4 wk: 1.5; 8 wk: 2.1; 16 wk: 2.5
Lin, 2020^67^; AR; Some concerns | 10 meter walking time (s) | 14.1 (7.6); 2 wk: 14.7 (6.7), 0.6^*^; 4 wk: 12.6 (5.2), −1.5^*^; 8 wk: 12.1 (4.9), −2.0^*^; 16 wk: 11.2 (4.1), −2.9^*^ | 15.8 (7.3); 2 wk: 15.3 (6.4), −0.5^*^; 4 wk:14.4 (5.9), −1.4^*^; 8 wk: 13.9 (5.6), −1.9^*^; 16 wk: 13.8 (4.7), −2.0^*^ | Diff ∆^*^:; 2 wk: 1.1; 4 wk: −0.1; 8 wk: −0.1; 16 wk: −0.9
Lin, 2020^67^; AR; Some concerns | Stair ascent time (s) | 18.8 (10.3); 2 wk: 17.9 (10.2), −0.9^*^; 4 wk: 17.3 (11.8), −1.5^*^; 8 wk: 14.9 (12.7), −3.9^*^; 16 wk: 14.8 (11.9), −4.0^*^ | 17.5 (12.3); 2 wk: 16.8 (12.7), −0.7^*^; 4 wk: 15.9 (12.4), −1.6^*^; 8 wk:15.5 (13.2), −2.0^*^; 16 wk: 14.9 (10.8), −2.6^*^ | Diff ∆^*^:; 2 wk: −0.2; 4 wk: 0.1; 8 wk: −1.9; 16 wk: −1.4
Lin, 2020^67^; AR; Some concerns | Stair descent time (s) | 17.9 (10.8); 2 wk: 17.8 (10.7), −0.1^*^; 4 wk: 16.3 (10.5), −1.6^*^; 8 wk: 15.9 (12.7), −2.0^*^; 16 wk: 14.6 (11.9), −3.3^*^ | 15.5 (11.3); 2 wk: 15.8 (11.2), 0.3^*^; 4 wk: 14.5 (10.4), −1.0^*^; 8 wk: 14.3 (10.2), −1.2^*^; 16 wk: 14.1 (9.8), −1.4^*^ | Diff ∆^*^:; 2 wk: −0.4; 4 wk: −0.6; 8 wk: −0.8; 16 wk: −1.9
Lin, 2020^67^; AR; Some concerns | Pedalo Balance Score (percentage) | Means NR; Medians (IQR):; 57 (50.2, 62.2); 6 wk: 75 (65, 80) | Means NR; Medians (IQR):; 70 (60, 78.5); 6 wk: 72.5 (63.7, 80) | Diff ∆: NC
Mete, 2022^68^; AR; High | Knee Flexion ROM (°) (6 wk) | Means NR; Medians (IQR):; 100 (95, 110.5); 6 wk: 115.5 (110 and 120) | Means NR; Medians (IQR):; 110 (100, 120); 6 wk: 111.5 (104.7 and 120) | Diff ∆: NC
Mete, 2022^68^; AR; High | Knee proprioception at 30° (6 wk) | Means NR; Medians (IQR); 6.25 (5.75, 8); 6 wk: 3.5 (3, 4) | Means NR; Medians (IQR):; 7 (6, 8); 6 wk: 6 (5, 7) | Diff ∆: NC
Mete, 2022^68^; AR; High | Knee proprioception at 60° (6 wk) | Means NR; Medians (IQR):; 8 (6, 10); 6 wk: 4 (3, 5) | Means NR; Medians (IQR):; 9 (7.3, 10); 6 wk: 8 (6, 9) | Diff ∆: NC
Mete, 2022^68^; AR; High | Peak Torque of knee flexion at 120° (normalized, Nm/kg) (6 wk) | Means NR; Medians (IQR):; 23.5 (14, 30); 6 wk: 36.9 (26.4, 47) | Means NR; Medians (IQR):; 20 (12, 26); 6 wk: 30.8 (24.3, 40.5) | Diff ∆: NC
Mete, 2022^68^; AR; High | Peak Torque of knee extension at 120° (normalized, Nm/kg) (6 wk) | Means NR; Medians (IQR):; 27.9 (21.6, 39.2); 6 wk: 52.5 (43.7, 66.2) | Means NR; Medians (IQR):; 25.6 (17.7, 35.8); 6 wk: 40.2 (30.6, 60) | Diff ∆: NC
Mete, 2022^68^; AR; High | Peak Torque of knee flexion at 240° (normalized, Nm/kg) (6 wk) | Means NR; Medians (IQR):; 16.4 (12.4, 23.5); 6 wk: 26 (21.3, 31.4) | Means NR; Medians (IQR):; 15.8 (10, 21.4); 6 wk: 22.12 (19, 28) | Diff ∆: NC
Mete, 2022^68^; AR; High | Peak Torque of knee extension at 240° (normalized, Nm/kg) (6 wk) | Means NR; Medians (IQR):; 16.4 (13, 24.8); 6 wk: 36.8 (26.3, 44.2) | Means NR; Medians (IQR):; 20.3 (13.4, 26.4); 6 wk:31.7 (22.5, 39) | Diff ∆: NC
Ozlu, 2023^65^; VR; High | 6-minute walk test (m) | 525.1 (70.5); 3 wk: 525.1 (70.5), 0.0^*^; 7 wk: 526.3 (68.5), 1.1^*^ | 530.4 (54.6); 3 wk: 531.3 (54.6), 0.9^*^; 7 wk: 532.5 (67.3), 2.1^*^ | Diff ∆^*^:; 3 wk: −0.9; 7 wk: −0.9
Ozlu, 2023^65^; VR; High | Berg Balance Scale | 42.8 (4.8); 3 wk: 45.3 (4.2), 2.5^*^; 7 wk: 46.0 (4.0), 3.6^*^ | 42.9 (5.9); 3 wk: 43.5 (6.07), 0.6^*^; 7 wk: 43.2 (6.0), 0.3^*^ | Diff ∆^*^:; 3 wk: 1.9; 7 wk: 2.9

Notes.

* Calculated by review team.

Abbreviations. AR=augmented reality; CET=conventional exercise training; Diff ∆= difference in change scores; IQR=interquartile range; NC=not calculable; Nm=Newton meter; NR=not reported; PT=physical therapy; ROM=range of motion; SD=standard deviation; SMT=sensorimotor training; VAS=visual analogue scale; VR=virtual reality; WHOQOL-BREF=World Health Organization Quality of Life-Brief Version; wk=weeks; WOMAC=Western Ontario and McMaster Universities Arthritis Index.