# APPENDIX G FIBROMYALGIA

Appendix Table G1 Detailed Characteristics for Included Trials on Fibromyalgia

Author, Year; Risk of Bias; Follow-Up Duration; Site(s); Funding Source | Inclusion/Exclusion Criteria | Intervention: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Intervention Characteristics | Comparator(s): Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Comparator Characteristics | Primary Outcome; Eligible Outcomes & Measures Reported (Time Points); Other Non-Eligible Outcomes Reported
Carvalho, 2019^58^; High; 7 Weeks; Federal University of Alfenas, Alfenas, Mina Gerais; Research Support Foundation of Minas Gerais (APQ 02794-11); Tutorial Education Program (PET-MEC-SESU); Coordination for the Improvement of Higher Education Personnel (CAPES)—Finance Code 001. | Inclusion:; ≥18 years of age; Female gender; American College of Rheumatology concordant fibromyalgia diagnosis; Exclusion:; Male gender; Cardiovascular, pulmonary, orthopedic, neurological, or dermatological conditions, affecting muscle strength and physical capabilities; Pregnancy | N=16; Age, mean (SD):; 55.64 (9.16); Women: 100%; Clinic; 1-hour sessions three times weekly; 7 weeks; Wii exergames: Participants completed 6 Wii Fit Plus subgames:; Jogging Plus which involves stationary running. Activity requires active and constant movement of the lower limb muscles for 15 minutes.; ‘Bird’s-eye Bull’s-eye game which requires active movement of the upper limbs in isolation from weight and balance training for 9 minutes.; Yoga game which involves control of expiratory and inspiratory movements and active control of the body’s center of gravity for 3 minutes.; Super Hula Hoop game which involves circular rhythmic movements as well as balance control for 9 minutes.; Step game which consists of active and alternating movements of the lower limb muscles, which requires control of balance and unipodal discharge for 9 minutes.; Rhythm Parade which consists of stationary walking with active and rhythmic movements of the lower limb muscles for 9 minutes. | N=19; Age, mean (SD):; 47.70 (15.46); Women: 100%; Clinic; 1-hour three times weekly; 7 weeks; Chain muscle stretching: Positions were held during four deep and prolonged expirations. Stretches were chosen from an existing isometric stretching program to include multiple positions and globally engage muscle groups.; Position 1: orthostatic position, feet parallel, semiflexion of the knees, pelvic retroversion, arms outstretched and slightly backward, wrists and fingers flexed in extension, gluteal muscles contracted, scapular adduction, and erect spine. Variation 2 of this position, which is performed with the hands in contact, was also used.; Position 15: standing position, anterior trunk inclination, knees flexed, and arms flexed with the hands supported on the back of the head.; Position 16: dorsal decubitus position, legs flexed, feet on the floor, and arms crossed.; Position 19: dorsal decubitus position, lower limbs in hip flexion at 90 and knees in extension, shoulders and elbows in 90 flexion, foot dorsiflexion, and scapular adduction.; Position 21: dorsal decubitus position, knees and hips semiflexed vertically and in external rotation, the soles of the feet in contact, and the arms positioned along the sides of the body.; Position 35: dorsal decubitus position, arms in extension and slight abduction, and legs extended at 90.; Position 36: seated position, erect spine, lower limbs semiflexed, feet supported on the floor, horizontal abduction and extension of the arms, and wrist extension at 90.; Position 38: seated position, erect spine, lower limbs semiflexed, feet supported on the floor, upper limbs in extension behind the body, and hands in contact with one another.; Position 40: seated position, shoulder abduction, and hands positioned behind the head.” | Primary: FIQ, Exercise capacity; Pain-related functioning (4, 7 wk); - FIQ (domain scores for physical function and total); Physical performance (4, 7 wk); - Number of steps up/down (25 cm height); Other non-eligible outcomes reported; - Pain threshold (algometry); - Vitals during exercise (HR, BP, etc.)
Collado-Mateo, 2017a^60^; Collado-Mateo, 2017b^61^; Some concerns; 8 Weeks; Recruitment via 2 local FM associations (per #2284); Spanish National R+D+i plan (no. DEP2012-39828); Government of Extremadura; EU Development Funds (no GR10127); Spanish Ministry of Education, Culture and Sport (no. FPU14/01283) | Inclusion:; Female gender; Age 30 to 75 years; American College of Rheumatology concordant fibromyalgia diagnosis by a rheumatologist; Exclusion:; Pregnancy; Any change to usual care therapies during 8 weeks of treatment; Contraindications for physical exercise. | N=42; Age, mean (SD):; 52.52 (9.73); Women: 100%; Clinic; 2 1-hour sessions per week; 8 weeks; VirtualEx-FM: Exergame program focused on postural control, coordination of upper and lower limbs, aerobic conditioning, strength and mobility in 3 virtual environments.; First, participants complete a warm-up by imitating an expert on video displaying upper and lower limb joint movements.; Second, participants complete an aerobic dance routine by following dance steps marked by a kinesiologist and dance teacher.; Third, participants train postural control and coordination by following on-screen prompts to reaching for a virtual apple using a specified limb. All activity is completed in groups of three. Training is designed to improve physical conditioning.; Fourth, walk training is developed using a circuit comprising a trail of footprints on a virtual floor. Participants must step on the virtual footprints and walk on the circuit. Participants are guided regarding mplitude, cadence, and different types of step. | N=41; Age, mean (SD):; 52.47 (8.75); Women: 100%; Clinic; NR; NR; Comparator group continued usual care without intervention. | Primary: EuroQoL-5D; Pain-related functioning (8 wk); - FIQ; - FIQ-80 (without work); - FIQ-100 (physical impairment); Physical performance (8 wk); - TUG; - Functional reach
Polat, 2021^57^; High; 8 Weeks; Gazi University Department of Physical Medicine and Rehabilitation; NR | Inclusion:; 2010 American College of Rheumatology concordant diagnosis of fibromyalgia; Age 18 to 65 years; ≥8 years of formal education; Unchanged fibromyalgia medication regimen for ≥3 months.; Exclusion:; Diagnosis of secondary fibromyalgia; Presence of intellectual deficits, visual deficits, inflammatory rheumatic disease or orthopedic surgery in preceding 6 months | N=20; Age, mean (SD):; 47.0 (7.1); Women: 100%; Home, Clinic; 4 weeks of cycling program for 20-minute sessions, 3 days per week and augmented reality exercise for 15-minute sessions, 3 days per week.; Home exercises for additional 4 weeks; Cycling program: cycling to 60-70% age adjusted maximum heart rate with 5 minutes of stretching prior to and after exercise.; Beach Volleyball: Kinect Sports’ videogame that involved participant replicating several movements in volleyball including serves, bumps, sets, and spikes. system.; Home exercise program: moderate-intensity aerobic physical activity for 30 minutes on 5 days each week, muscle strengthening and balance exercises 2 days a week, and flexibility exercises with stationary stretches every day for 4 weeks. | N=20; Age, mean (SD):; 42.6 (8.7); Women: 100%; Home, Clinic; 4 weeks of cycling program for 20-minute sessions, 3 days per week and additional non-aerobic exercise program for 15-minute sessions, 3 days per week; Home exercises for additional 4 weeks; Cycling program: cycling to 60-70% age adjusted maximum heart rate with 5 minutes of stretching prior to and after exercise.; Non-aerobic exercises were performed in a single series containing 10 repetitions at an intensity of 40% of the estimated 1 repetitive maximum, including upper and lower extremity large muscle groups in standing and sitting positions, as a standard exercise protocol with moderate intensity. Additional training in balance and flexibility exercises were completed alongside muscle strengthening.; Home exercise program: moderate-intensity aerobic physical activity for 30 minutes on 5 days each week, muscle strengthening and balance exercises 2 days a week, and flexibility exercises with stationary stretches every day for 4 weeks. | Primary: FIQ; Pain intensity (4, 8 wk); - VAS; Physical performance (4, 8 wk); - 6-minute walk; Quality of life (4, 8 wk); - European Quality of Life 5 (EuroQoL-5D-5L); Other non-eligible outcomes reported (4, 8 wk); - Symptom Severity Scale; - Fatigue Severity Scale; - HADS
Garcia-Palacios, 2015^64^; High; 6 Weeks; Universitat Jaume I and Rheumatology Service of Hospital General de Castellon; NR | Inclusion:; Age 18 to 70 years old; American College of Rheumatology concordant diagnosis of fibromyalgia by a rheumatologist; Exclusion:; Severe mental disorders such as schizophrenia, bipolar disorder, mental retardation, substance abuse or dependence, nor a mental disorder in need of immediate treatment; Requesting or suing for disability.” | N=61; Age, mean (SD):; NR; Women: 100%; Clinic; 6 2-hour group sessions twice a week; EMMA: Augmented reality display of 5 predefined scenarios aimed at promoting emotions and motivation. Scenarios include projected images, sounds and narratives. Scenarios chosen were beach and the meadow settings. Program structure involved a session with rationale of activity management for fibromyalgia and instructions to enhance motivation to start to perform meaningful activities (VR1). Another session explores overcoming barriers that prevent performance of activities (VR2). Lastly, a third session type provides instructions to acknowledge personal strengths that could motivate participants to get involved in meaningful activities (VR3). VR1 was used in session 2 of the program, VR2 was used in sessions 3 and 5, and VR3 was used in sessions 4 and 6.” | N=30; Age, mean (SD):; NR; Women: 100%; Clinic; 1 session in the 4 weeks after the pretreatment assessment; Partiipcants continued “usual care in a rheumatology unit in a public setting in Spain that consists of follow-up sessions by a rheumatologist to review the medication treatment.” | Primary: FIQ; Pain-related functioning (6 wk); - BPI- interference; Pain intensity (6 wk); - BPI- intensity; Quality of life (6 wk); - Quality of Life Index (QLI-Sp); Other non-eligible outcomes reported; - Chronic Pain Coping Inventory,; - Beck Depression Inventory II (BDI-II); - Acceptability and Satisfaction
Villafaina, 2019a^59^; Villafaina, 2019b^62^; Viallafaina, 2020^63^; Some concerns; 24 Weeks; NR; Spanish National R+D+i Plan, Spanish Ministry of Economy and Competitivenesss (reference no DEP2015-70356); Research Grant for Groups (GR18155) funded by Junta de Extremadura (Regional Government of Extremadura) and European Regional Development Fund (ERDF/FEDER) | Inclusion:; Female gender; Age 30 to 75 years; 2010 American College of Rheumatology concordant fibromyalgia diagnosis by rheumatologist; Exclusion:; Any change to usual care therapies during the 24 weeks of the treatment; Contraindications for physical exercise programs; Pregnancy | N=28; Age, mean (SD):; 54.04 (9.56); Female: 100%; Clinic; 1 hour sessions twice per week; 24 weeks.; VirtualEx-FM: Exergame program focused on postural control, coordination of upper and lower limbs, aerobic conditioning, strength and mobility in 3 virtual environments. Activity completed in groups of two participants.; First, participants complete a warm-up by imitating an expert on video displaying upper and lower limb joint movements.; Second, participants complete an aerobic dance routine by following dance steps marked by a kinesiologist and dance teacher.; Third, participants train postural control and coordination by following on-screen prompts to reaching for a virtual apple using a specified limb. All activity is completed in groups of three. Training is designed to improve physical conditioning.; Fourth, walk training is developed using a circuit comprising a trail of footprints on a virtual floor. Participants must step on the virtual footprints and walk on the circuit. Participants are guided regarding mplitude, cadence, and different types of step. | N=27; Age, mean (SD):; 53.41 (9.92); Female: 100%; Clinic; NR; NR; Participants continued care as usual, including previous medication use. | Primary: EuroQoL-5D, VAS; Pain-related functioning (24, 48 wk); - FIQ; Physical performance (24, 48 wk); - 6-minute walk test; - Sit-to-stand test; - 10 step stair test (seconds); - TUG; - Arm curl; - back scratch test; - sit and reach test (single and dual-task conditions)

Abbreviations. 3D=3 dimensional; ACR=American College of Rheumatology; BP=blood pressure; BPI=Beck pain inventory; CG=control group; cm=centimeters; EuroQoL-5D=European Quality of Life 5 dimensions; FIQ=Fibromyalgia Impact Questionnaire; FM=fibromyalgia; FMS=fibromyalgia syndrome; HADS=Hospital Anxiety and Depression Scale; HR=heart rate; NR=not reported; QLI-Sp=Quality of Life Index (Spanish version) SD=standard deviation; TAU=treatment as usual; TUG=timed up and go test; VAS=Visual Analog Scale; VR=virtual reality; wk=weeks.

Appendix Table G2 Detailed Results for Fibromyalgia Studies

Author, Year; VR or AR; Risk of Bias | Effect Measure | Intervention; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparator; Baseline Mean (SD); Follow-UpMean (SD), Mean Change | Comparison
Pain-Related Functioning or Interference
Carvalho, 2019^58^; AR; High | FIQR | 64.6 (16.1); 4 wk: 41.4 (13.6), −23.2^*^; 7 wk: 33.4 (6.3), −31.2^*^ | 72.0 (9.1); 4 wk: 63.1 (13.6), −8.9^*^; 7 wk: 46.4 (13.0), −25.6^*^ | Diff ∆^*^:; 4 wk: −14.3; 7 wk: −5.6
Carvalho, 2019^58^; AR; High | FIQR-physical function subscale | 7.2 (3.4); 4 wk: 5.1 (3.4), −2.1^*^; 7 wk: 4.6 (1.9), −2.6^*^ | 7.5 (5.2); 4 wk: 6.0 (5.3), −1.5^*^; 7 wk: 3.5 (2.6), −4.0^*^ | Diff ∆^*^:; 4 wk: −0.6; 7 wk: 1.4
Collado-Mateo, 2017^60^; AR; Some concerns | FIQ-100 (8 wk) | 50.6 (12.9); 44.9 (13.8), −5.7^*^ | 49.2 (15.3); 51.8 (16.4), 2.5^*^ | Diff ∆^*^: −8.3
Collado-Mateo, 2017^60^; AR; Some concerns | FIQ-80 (without work) (8 wk) | 42.6 (10.2); 37.3 (10.4), −5.3^*^ | 42.4 (12.5); 43.3 (12.9), 0.9^*^ | Diff ∆^*^: −6.1
Collado-Mateo, 2017^60^; AR; Some concerns | FIQ 100-physical impairment (8 wk) | 2.85 (1.73); 2.53 (1.87), −0.32^*^ | 2.6 (2.1); 2.5 (2.0), −3.0^*^ | Diff ∆^*^: −0.3
Garcia-Palacios, 2015^64^; AR; High | FIQ (6 wk) | 61.6 (19.9); 42.4 (15.7), −19.2^*^ | 60.6 (21.4); 57.0 (17.5), −3.6^*^ | Diff ∆^*^: −15.7
Garcia-Palacios, 2015^64^; AR; High | BPI-Interference; (6 wk) | 32.2 (14.8); 31.2 (17.7), −1.0^*^ | 32.3 (16.7); 37.1 (12.9), 4.7^*^ | Diff ∆^*^: −5.7
Polat, 2021^57^; AR; High | FIQ-80 | 54.7 (13.3); 4 wk: 42.7 (11.8), −12^*^; 8 wk: 40.1 (12.8), −14.6^*^ | 58.5 (9.2); 4 wk: 51.7 (9.1), −6.8^*^; 8 wk: 50.7 (12.1), −7.8^*^ | Diff ∆^*^:; 4 wk: −5.2; 8 wk: −6.8
Villafaina, 2019^59^; AR; Some concerns | FIQR | 53.2 (16.9); 24 wk: 51.6 (18.3), −1.6^*^; 48 wk: 51.1 (19.0), −2.1^*^ | 54.2 (20.0); 24 wk: 55.4 (20.1), 1.2^*^; 48 wk: 52.1 (18.4), −2.1^*^ | Diff ∆^*^:; 24 wk: −2.8; 48 wk: 0.01
Pain Intensity
Garcia-Palacios, 2015^64^; AR; High | BPI-Intensity; (6 wk) | 23.6 (5.1); 22.6 (6.3), −0.9 | 22.4 (7.9); 20.7 (8.3), −1.7 | Diff ∆^*^: 0.7
Polat, 2021^57^; AR; High | VAS | 6.40 (1.4); 4 wk: 4.3 (1.3), −2.2^*^; 8 wk: 3.9 (2.1), −2.6^*^ | 6.45 (1.3); 4 wk: 4.9 (1.4), −1.6^*^; 8 wk: 4.8 (1.6), −1.7^*^ | Diff ∆^*^:; 4 wk: −0.6; 8 wk: −0.9
Villafaina, 2019^59^; AR; Some concerns | VAS (24 wk) | 62.1 (19.3); 58.9 (16.3), −3.26 | 60.4 (19.3); 68.2 (17.3), 7.8 | Diff ∆^*^: −11.1
Quality of Life
Collado-Mateo, 2017^60^; AR; Some concerns | EuroQoL-5D; (8 wk) | 0.6 (0.2); 0.7 (0.2), 0.1^*^ | 0.6 (0.2); 0.6 (0.2), 0.0^*^ | Diff ∆^*^: 0.1
Garcia-Palacios, 2015^64^; AR; High | Quality of Life Index; (6 wk) | 4.5 (1.2); 6.1 (1.4), 1.6^*^ | 5.0 (1.2); 5.3 (1.3), 0.2^*^ | Diff ∆^*^: 1.4
Polat, 2021^57^; AR; High | EuroQoL-5D; (4 wk) | 0.5 (0.2); 4 wk: 0.7 (0.2), 0.2^*^; 8 wk: 0.8 (0.2), 0.3^*^ | 0.5 (0.1); 4 wk: 0.6 (0.2), 0.1^*^; 8 wk: 0.6 (0.2), 0.1^*^ | Diff ∆^*^:; 4 wk: 0.1; 8 wk: 0.2
Villafaina, 2019^59^; AR; Some concerns | EuroQoL-5D; (24 wk) | 0.5 (0.3); 0.6 (0.2), 0.1^*^ | 0.57 (0.3); 0.52 (0.2), 0.0^*^ | Diff ∆^*^: 0.1
Physical Performance
Carvalho, 2019^58^; AR; High | Number of Steps up/down (25 cm height) | 97.6 (16.4); 4 wk: 112.1 (15.0), 14.5^*^; 7 wk: 112.6 (12.1), 15.0^*^ | 93.0 (36.1); 4 wk: 95.7 (35.9), 2.7^*^; 7 wk: 103.4 (30.9), 10.4^*^ | Diff ∆^*^:; 4 wk: 11.8; 7 wk: 4.6
Collado-Mateo, 2017b^61^; AR; Some concerns | TUG; (8 wk) | 6.7 (0.9); 6.2 (0.6), −0.5^*^ | 6.7 (0.8); 6.9 (1.1), 0.2^*^ | Diff ∆^*^: −0.7
Collado-Mateo, 2017b^61^; AR; Some concerns | Functional reach (cm); (8 wk) | 19.7 (7.5); 23.0 (5.2), 3.3^*^ | 19.5 (5.7); 18.4 (6.6), −1.1^*^ | Diff ∆^*^: 4.4
Polat, 2021^57^; AR | 6-minute walk test (m) | 467.0); 6.7 (1.3), −0.8^*^ | 443.2.8), 1.0^*^ | Diff ∆^*^: −1.8
Villafaina, 2019^59^; Martin-Martinez, 2019^62^; AR; Some concerns | TUG; (24 wk) | 7.5 (2.0); 6.7 (1.3), −0.8^*^ | 7.7 (1.6); 8.8 (2.8), 1.0^*^ | Diff ∆^*^: −1.8
Villafaina, 2019^59^; Martin-Martinez, 2019^62^; AR; Some concerns | 6-minute walk test (m) | 491.2 (80.2); 24 wk: 506.5 (70.2), 15.3^*^; 48 wk: 499.7 (80.1), 8.6^*^ | 517.5 (58.4); 24 wk: 498.2 (68.5), −19.2^*^; 48 wk: 481.7 (92.3), −35.8^*^ | Diff ∆^*^:; 24 wk: 34.6; 48 wk: 44.3
| Sit-to-stand test | 10.9 (2.9); 24 wk: 11.8 (2.5), 0.8^*^; 48 wk: 11.1 (2.7), 0.2^*^ | 11.67 (2.5); 24 wk: 11.00 (2.4), −0.7^*^; 48 wk: 11.00 (2.9), −0.7^*^ | Diff ∆^*^:; 24 wk: 1.5; 48 wk: 0.8
| 10 step stair test (s) | 5.4 (2.8); 24 wk: 5.2 (2.1), −0.2^*^; 48 wk: 5.3 (1.8), −0.2^*^ | 5.5 (1.9); 24 wk: 5.6 (2.3), 0.1^*^; 48 wk: 5.9 (2.3), 0.4^*^ | Diff ∆^*^:; 24 wk: −0.4; 48 wk: −0.6

Notes.

* Calculated by review team.

Abbreviations. 5D=5 dimension; 5L=5 level; BPI=Beck Pain Inventory; cm=centimeters; Diff ∆= difference in change scores; EuroQoL-5D=European Quality of Life 5 Dimensions; FIQ=Fibromyalgia Impact Questionnaire; FIQR= 2009 Revised Fibromyalgia Impact Questionnaire; SD=standard deviation; TUG=timed up and go test; VAS=Visual Analogue Scale; wk=weeks.