# APPENDIX F CHRONIC NECK PAIN

Appendix Table F1 Detailed Characteristics for Included Trials on Chronic Neck Pain

Author, Year; Risk of Bias; Follow-Up Duration; Site(s); Funding source | Inclusion/Exclusion Criteria | Intervention: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Intervention Characteristics | Comparator(s): Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Comparator Characteristics | Primary Outcome; Eligible Outcomes & Measures Reported (Time Points); Other Non-Eligible Outcomes Reported
VR Intervention
Cetin, 2022^51^; High; 6 weeks; Hacettepe University Hospital’s Neurosurgery Department, Turkey; NR | Inclusion: “…aged between 18 and 65 years with a minimum of 6 months of neck pain, a baseline NDI score of at least 20% (10 points), and the neck region as the primary pain area.”; Exclusion: “…having undergone cervical spine surgery; having rheumatologic, vestibular, neurological, or cardiopulmonary diseases; having receiving interventions including exercise or physical therapy in the previous 6 months; and being pregnant.” | N=21; Age, mean (SD): 40.0 (11.88); Female: 70.5%; Clinic; 3 × 40 min (20 min control exercises + 20 min VR) per week; 6 weeks; “Two VR applications were installed: “Ocean Rift” and “Gala 360”. “Ocean Rift” provides a VR experience that allows watching sea animals that can be selected with the remote control. “Gala 360” provides views from countries and cities all over the world… The patients were seated in a chair that allowed 360° movement and were asked to look in all directions during the VR application…They were encouraged to move their necks by expressions such as “follow that dolphin, the sea turtles you chose will come soon, there may be a starfish below. Now you are in front of the Eiffel Tower, you can look around”.” | N=20; Age, mean (SD): 41.94 (10.76); Female: 64.7%; Clinic; 3 × 40 min per week; 6 weeks; “The MC exercises included strengthening of the deep cervical flexors (DCFs), deep cervical extensors (DCEs), and axioscapular muscles; stretching exercises; and postural correction exercises. The 3-level treatment protocol developed by Jull was used in the training of the cervical muscles in our study (Jull et al., 2004). In the first level, craniocervical flexion (CCF) exercises were used for low-load endurance training of the DCFs and cervical extension exercises were used for endurance training of the DCEs. The exercises were performed slowly to provide MC and increase kinesthetic awareness. The ability to do the CCF exercises for 10 s was used as a reference to indicate progress in the exercises. In the second level, elastic bands were used to increase the strength and endurance of the DCFs and DCEs. In the third level, the aim was to gain dynamic balance, and this was achieved by the patient holding an exercise ball against a wall with the front/back of the head. All patients were informed about neutral spinal posture from the first session. They were trained to actively correct postures and maintain them for 10 s (in sitting and standing positions).” | Primary: ROM, Joint Position Sense Error (JPSE); Pain-related functioning (6 wk); - ProFitMap-Neck; Pain intensity (6 wk); - VAS; Adverse events (6 wk); Quality of life (6 wk); - SF-36 (domain scores only); Physical performance (6 wk); - ROM & JPSE (flexion, extension, right/left lateral flexion, right/left rotation); Non-eligible: Pain pressure thresholds, HADS
Nusser, 2021^52^; High; 3 weeks; Federseeklinik Bad Buchau, Germany; NR | Inclusion: “Diagnoses [of non-traumatic chronic neck pain (more than 3 months)] were primarily made by patients’ general practitioners and confirmed by the physician in charge at the rehabilitation hospital. Further inclusion criteria were such that the patients must be adults aged 18 years or more and have taken no pain medication or muscle relaxants for 24 hours before the tests.”; Exclusion: “… traumatic neck pain, neck pain originating from whiplash, cervical fracture/dislocation, operations in the cervical spine area, damage to the inner ear, vertebrobasilar insufficiency, basic neurological diseases, range of motion of the cervical spine < 10° in flexion, extension, and/or rotation.” | N=17; Mean (SD) age: 51.2 (8.8); 6 20-minute sessions over 3 weeks; Clinic; “In addition to the “standard rehabilitation programme,” patients in the VRG completed a total of 120 min of “neck-specific sensorimotor training” (NSST) using a VR device in individual therapy. Due to the required concentration, the training was divided into 6 20min sessions… A globe was shown, moving in a virtual space on predetermined trajectories, on the monitor… The patient was asked to follow by moving the head the orbital pathways of the globe… A 3Space Fastrak System (Polhemus Inc., Colchester, VT, USA) was used for head movement tracking… Before each training session, the current maximum active cervical range of motion (ACROM) of the patient was determined in a total of 8 directions: flexion, extension, right, and left rotation, and the diagonals in between… In every NSST session, the VRG patients underwent each of the following tasks twice: the Head Repositioning Test (HRT) …, the Head to Target Test (HTT), and a dynamic exercise including 5 different trajectories… Rest breaks of approximately 3 min were given between tasks, and extended if any side effect (eg, motion sickness, nausea, or headaches) was reported.” | N=20; Mean (SD) age: 49.8 (8.1); 3 weeks; Clinic; “The CG underwent a “standard rehabilitation programme”, including a combination of individual and group therapies instructed by physiotherapists and certified sports scientists… the programme comprised different forms of general and neck-specific exercise therapy, such as strengthening, mobilization, relaxation, medical training therapy, functional gymnastics, aqua therapy, physical therapy, and traditional “back school”… Patients also received special lectures from orthopaedists and psychologists, who provided information about chronic pain, along with therapeutic goals, and an emphasis on the importance of being proactive.” | Primary outcome NR; Pain-related functioning (3 wk); - NDI; Pain intensity/severity (3 wk); - NRS; Adverse events (3 wk); Physical performance (3 wk); - ACROM
Nusser, 2021^52^; High; 3 weeks; Federseeklinik Bad Buchau, Germany; NR | | N=18; Mean (SD) age: 53.1 (5.7); 4 × 30-minute sessions over 3 weeks; Clinic; “The SMG received the “standard rehabilitation programme” plus a total of 120 min of “general sensorimotor training”. This training… was instructed by a physiotherapist or a certified sports scientist. The objective was training and improvement in patients’ coordination through skill exercises (eg, passing an obstacle course, dribbling, rope skipping, tossing balls through rings), balance exercises (eg, standing with eyes closed, single leg stance, slacklining), small game forms (eg, juggling, curling, throwing and catching), and partner games, such as badminton or table tennis.” | | Primary outcome NR; Pain-related functioning (3 wk); - NDI; Pain intensity/severity (3 wk); - NRS; Adverse events (3 wk); Physical performance (3 wk); - ACROM
Tejara, 2020^53^; Some concerns; 4 months; Rey Juan Carlos University; CEU San Pablo University; Community of Madrid, Spain; NR | Inclusion: “(a) non-specific chronic neck pain; (b) age 18 to 65 years”; Exclusion: “(a) pregnancy; (b) specific neck pain caused by metastasis, neoplasia, infectious or inflammatory disorders, bone fractures or traumatic precedents with neck injuries; (c) positive neurological signs or evidence of spinal compression (abnormal diuse sensitivity, hyperreflexia, or diuse weakness); (d) cervical osteoarthritis; (e) spondyloarthritis; (f) neck pain associated with vertigo (vestibular involvement); (g) neck pain associated with whiplash injuries; (h) previous cervical surgeries; (i) headaches prior to the onset of neck pain and without cervical origin; and (e) inability to provide informed consent.” | N=22; Age, mean (SD): 32.72 (11.63); Female: 50%; Clinic; 2 sessions/week for 4 weeks; “Two VR mobile applications were installed…The subjects started with the free mobile application “Fulldive VR” …. The patient was immersed in an environment that simulated the living room of a house and at the same time they could visualize a gallery of previously selected photos. Then, they had to change the images in the viewfinder by tilting their neck bilaterally, as well as naming the photos that were displayed… Once the patient felt comfortable with the system and adapted to the headset, then after one minute rest, the difficulty of the exercise program was increased with the free mobile application “VR Ocean Aquarium 3D” where flexion, extension and rotation movements were added. The patient was immersed in a virtual environment that simulated an ocean, moving forward and observing different marine animals by making the neck movements. The patient named the animals they were visualizing…In the first sessions, the patients were instructed to perform a previous cranio-cervical flexion before starting any movement. Then, the therapist controlled the contraction of the superficial musculature with their hands. Gradually, the aid of the physiotherapist was removed so that the participants could integrate deep muscle contraction and the correct cranio-cervical posture innately… For these patients to carry out the same work as the control group, the physiotherapist counted and controlled in each exercise the number of movements the patient performed, in order to not exceed the dose proposed: 3 series of 10 repetitions of each exercise with 30 s rest between exercises.” | N=22; Age, mean (SD): 26.68 (9.21); Female: 54.5%; Clinic; 2 sessions/week for 4 weeks; “This group performed three series of 10 repetitions of every exercise, with a 30 s rest between exercises. The researcher provided the necessary verbal corrections for the proper execution of the exercises, using the same verbal commands for all participants. Flexion exercise: in a sitting position, a ball was placed between the wall and the neck of the patient that performed a controlled neck flexion with a previously maintained cranio-cervical flexion. Extension exercise: in a sitting position, the participant was asked to perform a controlled neck extension and a cranio-cervical flexion before returning to the initial position. Rotation and tilt exercises: in a sitting position, the subject who had previously done a cranio-cervical flexion to activate the deep flexor musculature was asked to perform the movement.” | Primary: Pain intensity, pain modulation (CPM), temporal summation (TS); Pain-related functioning (4 wk, 4 mo); - NDI; Pain intensity/severity (4 wk, 4 mo); - VAS; Pain catastrophizing (4 wk, 4 mo); - Pain Catastrophizing Scale (PCS); - Pain Anxiety Symptom Scale (PASS-20); - Fear Avoidance Beliefs Questionnaire (FABQ); - TSK; Physical performance (4 mo); - Cervical ROM; Non-eligible: CPM; TS; fear-avoidance beliefs; pain pressure thresholds; pain-related anxiety
Bahat, 2017^54,120^; Some concerns; 4 months^54^, 5 months ^120^; University of Queensland, Australia; Physiotherapy Research Fellowships (HMR); Queensland Government (2013003214) | Inclusion: “Adults aged 18 years or more with neck pain for more than 3 months… NDI score greater than 12%, and VAS during the recent week greater than 20 mm. Lastly, VR assessment indicated a reduction of mean velocity of at least one SD from control values.”; Exclusion: “Existing vestibular pathology; cervical fracture/dislocation; systemic diseases, epilepsy or other neurological condition; cardiovascular, or respiratory disorders affecting physical performance; history of traumatic head injury; inability to provide informed consent; inability to complete the assessment, or pregnancy.” | N=30 (+18 added in phase 2); Age, median (IQR): 48 (38.5, 57.5); Female: 63%; Home; 5-minute sessions, 4 times a day (20 mins/day total), 4 days a week, for 4 weeks; “Three modules were developed, including range of motion (ROM), velocity and accuracy modules. These modules enable elicitation of cervical motion by the patient’s response to the provided visual stimuli. A full kinematic report for each patient was generated after completion of the modules. During the VR session, the virtual pilot flying the red airplane was controlled by the patient’s head motion and interacted with targets appearing from four directions (to elicit flexion, extension, right rotation, left rotation). The VR software did not elicit side flexion movement…” | N=30 (+14 added phase 2); Age, median (IQR): 48 (35.5, 59); Female: 70%; Home; 5-minute sessions, 4 times a day (20 mins/day total), 4 days a week, for 4 weeks; “Kinematic training with a head-mounted laser beam aimed at a 70 by 70 cm poster. Tasks in the laser group were similar to the VR exercises, such as following the line with the laser, moving quickly from one circle to another, etc. The laser beam provided visual feedback relating to head motion, but unlike the VR, laser training velocity was not controlled.” | Primary: NDI, global perceived effect (GPE), cervical motion velocity (mean & peak); Pain-related functioning (4 wks); - NDI; Pain intensity/severity (4 wks); - VAS; Adverse events (4 wks); - Side effects post-intervention for VR group only, includes both phases 1+2; Pain catastrophizing (4 wks); - TSK; Physical performance (4 wks); - Velocity; - # of velocity peaks; - Time to peak velocity percentage; - Accuracy error; - Cervical ROM
Bahat, 2017^54,120^; Some concerns; 4 months^54^, 5 months ^120^; University of Queensland, Australia; Physiotherapy Research Fellowships (HMR); Queensland Government (2013003214) | | | N=30; Age, median (IQR): 48 (35, 59); Female: 77%; Home; NA (waitlist control)
Sarig Bahat, 2015^55^; Some concerns; 4 months; Neck Pain and Whiplash Research Unit, University of Queensland, Brisbane, Australia; University of Haifa | Inclusion: ““age 18 years or more; prolonged neck pain for more than three months; and the… NDI score greater than 10%”; Exclusion: “existing vestibular pathology; cervical fracture/dislocation; systemic diseases; neurological, cardiovascular, or respiratory disorders affecting physical performance; history of traumatic head injury; inability to provide informed consent; or pregnancy.” | N=16; Age, mean (SD): 40.63 (14.18); Female: 68.8%; Clinic; 4-6 supervised sessions (30 minutes each) over 5 weeks, 30-minutes at least 3 × per week over 3 months; “Three modules were developed, including range of motion (ROM), velocity and accuracy modules. These modules enable elicitation of cervical motion by the patient’s response to the provided visual stimuli… During the VR session, the virtual pilot flying the red aeroplane (in the web version) is controlled by the patient’s head motion and interacts with targets appearing from four directions (flexion, extension, right rotation, left rotation) …The VR training program was tailored to each participant and progressed according to the patients’ performance… In the VR training system, range of motion was individually challenged by positioning targets further away, velocity by reducing targets lifetime (the shorter time a target appeared it required faster response), and accuracy by increasing velocity of the moving target to pursuit in the accuracy module.” | N=16; Age, mean (SD): 41.13 (12.59); Female: 68.8%; Clinic & Home; 4-6 supervised sessions (30 minutes each) over 5 weeks, KT home sessions × 3 months; “The KT group undertook a 30-minute training session using a laser pointer that was mounted on the participant’s head and projected onto a poster for feedback. Kinematic training involved active neck movements to increase ROM, quick head movement in between targets to facilitate quick cervical motion control, static head positioning while moving the body was used to advance head stability, and smooth head movement following a target was used to train accurate head neck movement. These exercises were supervised by the physiotherapist and performed in the clinic by the KT group, and then encouraged to be performed at home. The kinematic home exercises were tailored to each individual and their performance re-evaluated and progressed during each supervised session.” | Primary: NDI, cervical ROM, head movement velocity & accuracy; Pain-related functioning (4 wk, 4 mo); - NDI; Pain intensity/severity (5 wk, 4 mo); - VAS; Adverse events (4 mo); - Motion sickness; Pain catastrophizing (5 wk, 4 mo); - TSK; Pain global change (4 mo); - Global Perceived Effect (GPE) on pain; Physical performance (4 mo); - ROM (flexion, extension, right rotation, left rotation); - Peak Velocity (flexion, extension, right rotation, left rotation),; - Mean Velocity (flexion, extension, right rotation, left rotation),; - TTP% (flexion, extension, right rotation, left rotation),; - Sway SD (pitch, yaw),; - Accuracy (pitch, yaw); - Sensorimotor (eyes closed balance, single leg stance, and step test); Non-eligible: cervical ROM, head movement velocity and accuracy
AR Interventions
Rezaei, 2019^56^; High; 9 weeks; Community health system in Iran; Vice Chancellor for Research of Shiraz University of Medical Sciences (grant no. 92-6895) | Inclusion: “… history of nontraumatic NP for more than 3 months and age between 20 and 55 years.”; Exclusion: “…a score ≥15 and ≤9 (out of possible 50) on… NDI, history of cervical and thoracic trauma within the 6 months before examination, neurological signs and symptoms in the upper extremities, nerve injury, spinal cord compression, cervical spine pathology or surgery and cancer.” | N=22; Age, mean (SD): 36.19 (9.8); Female: 42.9%; Clinic; 21 min sessions, 2 sessions per week for 4 weeks (8 total); “A new video game (Cervigame® version 1.01) was designed for training… The main visual component of the game is a rabbit attempting to reach carrots. The virtual carrots appear continuously along the line of the movement pattern being trained. This avatar is controlled by the patient’s head movements… Stages increase in difficulty as obstacles…appear in predefined positions…The best score in each stage was obtained by capturing all carrots without colliding with any obstacles… Based on the patient’s head movement (along a line or in a plane) the stages are divided into two main categories: unidirectional and two-directional…The order of 50 stages progresses from easy to hard, based on the stage category, number and acuity of the angles, shape and variation in the range of trajectories and the arrangement of obstacles. In the first 3 treatment sessions, the patients play only unidirectional stages. Combinations of unidirectional and two-directional stages are played alternately in the fourth and fifth sessions. In the last 3 sessions, only two-directional stages are played.” | N=22; Age, mean (SD): 31.23 (9.49); Female: 52.4%; Clinic; 21 min sessions, 2 sessions per week for 4 weeks (8 total); “… Exercises consisted of eye-follow, gaze stability, eye-head coordination and position sense and movement sense practice. In the eye-follow exercise, patients moved their eyes to follow the target while seated with their head stationary. The target was a pen held by a physical therapist, who initially moved it slowly in one plane and then increased the speed and changed the direction of movement. For the gaze stability exercise, patients actively moved their head in all directions while visually fixing on the target. The exercise for eye-head coordination began by moving the head and eyes to the same side. Then participants moved their eyes first to keep focused on the target, and then moved their head. Finally, they moved their eyes in one direction while simultaneously rotating their head in the opposite direction. These exercises were initially done slowly in a restricted range of movements, then the speed and range of movements gradually increased. Exercises were done in both vertical and horizontal directions. For joint position sense and movement sense exercises, participants wore a laser pointer attached to a headband. The patients sat 1 meter from a point marked on the wall, and were instructed to move their head until the laser beam was aimed on the point, and then to close their eyes and memorize their head-neck position for 5 s. Maximal movement of the head was performed in one direction (flexion, extension, rotation or lateral flexion), after which the patients tried to recover their initial head position as closely as possible, and opened their eyes. The relocation error indicated by the distance of the laser beam from the point marked on the wall was used as feedback. Movement sense was practiced by using the head-mounted laser pointer to trace a moving object held by the physical therapist. The task was progressed by increasing the speed and changing the pattern of movement.” | Primary: Patient-reported neck pain & disability; Pain-related functioning (4 wk, 9 wk); - NDI; Pain intensity (4 wk, 9 wk); - VAS; Physical performance (4 wk, 9 wk); - Dynamic balance: Y-balance test

Abbreviations: ACROM=acute cervical range of motion; AR=augmented reality; CG=control group; CPM=conditioned pain modulation; HADS=Hospital Anxiety-Depression Scale; IQR=interquartile range; JPSE=Joint Position Sense Error; MC=motor control exercises; mo=month; NDI=Neck Disability Index; NR=not reported; NRS=Numeric Rating Scale; ROM=range of motion; SD=standard deviation; SF-36=Short Form-36; SMG=sensorimotor group; TS=temporal summation; TSK=Tampa Scale of Kinesiophobia; TTP=time-to-peak; VAS=Visual Analog Scale; VR=virtual reality.

Appendix Table F2 Detailed Results for Chronic Neck Pain Studies

Author, Year; VR or AR; Risk of Bias | Effect Measure | Intervention; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparator; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparison
Pain-Related Functioning or Interference
Cetin, 2022^51^; VR; High | ProFitMap – Neck | 69.3 (11.3); 6 wk: Follow-up NR, 12.97 | 65.22 (13.49); 6 wk: Follow-up NR, 10.59 | Diff ∆:; 6 wk: 2.37
Nusser, 2021^52^; VR; High | NDI | 18.7 (5.2); 3 wk: 11.4 (7.5), −7.3^*^ | SMG; 21.5 (6.4); 3 wk: 13.7 (7.9), −7.8^*^ | Diff ∆^*^:; 3 wk: 0.5
Nusser, 2021^52^; VR; High | NDI | 18.7 (5.2); 3 wk: 11.4 (7.5), −7.3^*^ | Control; 18.2 (6.7); 3 wk: 13.7 (7.0), −4.5 | Diff ∆^*^:; 3 wk: −2.8
Rezaei, 2019^56^; AR; High | NDI | 13.0 (1.3); 4 wk: 4.57 (2.39), −8.43; 9 wk: 4.38 (3.3), −8.62 | 12.28 (1.38); 4 wk: 8.14 (3.13), −4.14; 9 wk: 9.22 (3.66), −3.06 | Diff ∆:; 4 wk: −4.29; 9 wk: −5.56^*^
Sarig Bahat, 2017^54^; VR; Some concerns | NDI | 32.88 (12.5); 4 wk: 23.75 (15.7), −9.13^*^ | Laser; 32.19 (13.3); 4 wk: 26.88 (14.0), −5.31^*^ | Diff ∆^*^:; 4 wk: −3.82
Sarig Bahat, 2017^54^; VR; Some concerns | NDI | 32.88 (12.5); 4 wk: 23.75 (15.7), −9.13^*^ | Control; 4.48 (10.7); 4 wk: 23.60 (11.8), −1.12^*^ | Diff ∆^*^:; 4 wk: −8.01
Sarig Bahat, 2015^55^; VR; Some concerns | NDI | 20.38 (7.6); 4 wk: 12.85 (7.5), −7.76 (6.2); 4 mo: 13.57 (7.9), −6.92 (6.0) | 20.19 (6.5); 4 wk: 14.0 (15.1), −5.64 (7.0); 4 mo: 14.0 (8.5), −3.42 (14.9) | Diff ∆^*^:; 4 wk: −2.12; 4 mo: −3.5
Tejara, 2020^53^; VR; Some concerns | NDI | 13.72 (6.68); 4 wk: 6.9 (6.28), −6.82^*^; 4 mo: 4.95 (6.60), −8.77^*^ | 14.09 (9.32); 4 wk: 7.45 (5.36), −6.64^*^; 4 mo: 5.77 (4.67), −8.32^*^ | Diff ∆^*^:; 4 wk: −0.18; 4 mo: −0.45
Pain Intensity
Nusser, 2021^52^; VR; High | NRS | 4.9 (2.1); 3 wk: 2.2 (1.2), −2.7^*^ | SMG: 4.4 (3.1); 3 wk: 2.9 (2.2), −1.5^*^ | Diff ∆^*^:; 3 wk: −1.2
Nusser, 2021^52^; VR; High | NRS | 4.9 (2.1); 3 wk: 2.2 (1.2), −2.7^*^ | CG: 4.2 (2.6); 3 wk: 3.2 (3.0), −1.0^*^ | Diff ∆^*^:; 3 wk: −1.7
Rezaei, 2019^56^; AR; High | VAS | 47.11 (10.24); 4 wk: 10.75 (8.43), −36.36; 9 wk: 9.75 (11.03), −37.54 | 38.95 (10.07); 4 wk: 19.63 (9.15), −19.32; 9 wk: 20.17 (11.97), −18.78 | Diff ∆^*^:; 4 wk: −17.04; 9 wk: 18.76
Sarig Bahat, 2015^55^; VR; Some concerns | VAS | 35.72 (17.7); 5 wk: 22.1 (24.1), −13.62^*^; 4 mo: 26.95 (16.5), −8.77 | 35.17 (16.7); 5 wk: 27.72 (21.9), −7.45^*^; 4 mo: 30.33 (18.5), −4.84 | Diff ∆^*^:; 5 wk: −21.07; 4 mo: −3.93
Sarig Bahat, 2017^54^; VR; Some concerns | VAS | 47.49 (20.9); 4 wk: 31.1 (23.6), −16.39^*^ | 52.47 (19.5); 4 wk.: 35.97 (22.9), −16.5^*^ | Diff ∆^*^:; 4 wk: 0.11
Sarig Bahat, 2017^54^; VR; Some concerns | VAS | 47.49 (20.9); 4 wk: 31.1 (23.6), −16.39^*^ | 45.78 (21.5); 4 wk: 39.45 (22.0), −6.33^*^ | Diff ∆^*^:; 4 wk: −10.06
Tejara, 2020^53^; VR; Some concerns | VAS | 4.97 (1.88); 4 wk: 2.67 (1.91), −2.3^*^; 4 mo: 2.17 (1.99), −2.8^*^ | 4.27 (1.35); 4 wk: 3.11 (1.47), −1.16^*^; 4 mo: 1.72 (2.09), −2.55^*^ | Diff ∆^*^:; 4 wk: −1.14; 4 mo: −0.25
Adverse Events
Cetin, 2022^51^; VR; High | Count of adverse events | No AE observed | No AE observed | Diff ∆^*^: 0
Nusser, 2021^52^; VR; High | Count of adverse events | “Besides the weight of the helmet, which some patients found unpleasant, no other negative side effects were reported regarding the VR device or in general. Therefore, all patients (not including the 4 who discontinued participation) could complete the measurements required for the training, as planned.” | | Diff ∆: NC
Sarig Bahat, 2017^54^; VR; Some concerns | Side effects post-intervention, includes phases 1+2 | “There were a few cases of side effects from the VR use. Out of 14 dropouts at post-intervention assessment, 5 were due to VR-associated sickness and headache.” | AE not assessed | Diff ∆: NC
Sarig Bahat, 2015^55^; VR; Some concerns | Count of participants who experienced motion sickness | “Four participants experienced motion sickness with the use of the VR device during assessment. Two participants reported motion sickness prior to randomization, and therefore were excluded. Two other participants experienced delayed motion sickness (up to 24 hours after assessment) and after being randomized to the KT[VR] group and hence withdrew from further participation. There were no reports of pain exacerbation.” | | Diff ∆: NC
Pain Catastrophizing & Kinesiophobia
Sarig Bahat, 2017^54^; VR; Some concerns | TSK | 35.22 (7.4); 4 wk: 33.26 (7.8), −1.96^*^ | Laser; 34.79 (5.9); 4 wk: 34.58 (8.2), −0.21^*^ | Diff ∆^*^:; 4 wk: −1.75
Sarig Bahat, 2017^54^; VR; Some concerns | TSK | 35.22 (7.4); 4 wk: 33.26 (7.8), −1.96^*^ | Control; 32.64 (7.2); 4 wk: 33.96 (6.2), 1.32^*^ | Diff ∆^*^:; 4 wk: −3.28
Sarig Bahat, 2015^55^; VR; Some concerns | TSK | 32.75 (6.8); 5 wk: 30.13 (5.7), −2.13 (4.2); 4 mo: 31.23 (6.5), −1.23 (6.8) | 30.38 (5.8); 5 wk: 28.64 (9.9), −1.5 (8.3); 4 mo: 30.0 (5.9), −0.92 (4.5) | Diff ∆^*^:; 5 wk: −0.63; 4 mo: −0.31
Tejara, 2020^53^; VR; Some concerns | TSK | 22.9 (7.11); 4 wk: 18.9 (10.73), −4.0^*^; 4 mo: 12.09 (7.77), −10.81^*^ | 21.4 (6.63); 4 wk: 18.36 (7.48), −3.04; 4 mo: 17.5 (6.89), −3.9 | Diff ∆^*^:; 4 wk: −0.96; 4 mo: −6.91
Tejara, 2020^53^; VR; Some concerns | PCS | 17.36 (11.49); 4 mo: 4.95 (8.08), −12.41^*^ | 11.95 (9.39); 4 mo: 4.86 (8.4), −7.09^*^ | Diff ∆^*^:; 4 mo: −5.32
Tejara, 2020^53^; VR; Some concerns | PASS-20 | 27.52 (20.52); 4 mo: 12.33 (16.09), −15.19^*^ | 26.59 (16.5); 4 mo: 15.9 (11.3), −10.69^*^ | Diff ∆^*^:; 4 mo: −4.5
Tejara, 2020^53^; VR; Some concerns | FABQ | 28.25 (16.43); 4 mo: 12.3 (13.48), −15.95^*^ | 25.68 (13.02); 4 mo: 16.59 (14.32), −9.09^*^ | Diff ∆^*^:; 4 mo: −6.86
Quality of Life
Cetin, 2022^51^; VR; High | SF-36 – Physical functioning | Median (IQR): 75.0 (60.0-85.0); 6 wk median (IQR): NR, 15.0 (5.0-17.5) | Median (IQR) 75.0 (60.0-90.0); 6 wk median (IQR): NR, 5.0 (0.0-17.5) | Median (95% CI) diff at 6 weeks: 2.94 (−5.17, 11.05)
Cetin, 2022^51^; VR; High | SF-36 – Role limitations due to physical health | Median (IQR): 66.7 (33.3-83.3); 6 wk median (IQR): NR, 25.0 (0.0-46.0) | Median (IQR): 33.3 (33.3-66.7); 6 wk median (IQR): NR, 25.0 (10.0-50.0) | Median (95% CI) diff at 6 weeks: −3.62 (27.62, 20.36)
Cetin, 2022^51^; VR; High | SF-36 – Role limitations due to emotional health | Median (IQR): 55.0 (55.0-60.0); 6 wk median (IQR): NR, 33.3 (0.0-33.5) | Median (IQR): 45.0 (32.6-55.0); 6 wk median (IQR): NR, 33.4 (0.0-66.7) | Median (95% CI) diff at 6 weeks: −5.86 (−18.76, 7.03)
Physical Performance
Cetin, 2022^51^; VR; High | Flexion | 49.05 (7.89); 6 wk: NR, 10.64 (7.44) | 44.64 (9.92); 6 wk: NR, 8.47 (7.21) | Diff ∆:; 6 wk: −2.17
Cetin, 2022^51^; VR; High | Extension | 62.47 (11.88); 6 wk: NR, 10.05 (9.25) | 61.23 (9.44); 6 wk: 7.70 (7.05) | Diff ∆:; 6 wk: −2.35
Cetin, 2022^51^; VR; High | Right lateral flexion | 40.23 (8.35); 6 wk: 7.63 (8.84) | 39.42 (7.83); 6 wk: 7.30 (5.81) | Diff ∆:; 6 wk: −0.33
Cetin, 2022^51^; VR; High | Left lateral flexion | 42.56 (8.25); 6 wk: 4.96 (7.41) | 43.66 (7.23); 6 wk: 4.92 (5.78) | Diff ∆:; 6 wk: −0.04
Cetin, 2022^51^; VR; High | Right rotation | 56.76 (9.83); 6 wk: 6.05 (13.6) | 51.47 (8.43); 6 wk: 8.52 (6.06) | Diff ∆:; 6 wk: 2.47
Cetin, 2022^51^; VR; High | Left rotation | 55.0 (9.18); 6 wk: 7.35 (9.0) | 49.11 (8.33); 6 wk: 9.41 (9.98) | Diff ∆:; 6 wk: 2.05
Nusser, 2021^52^; VR; High | Flexion | 40.9 (14.6); 3 wk: 48.5 (13.3), 7.6^*^ | SMG; 38.9 (12.2); 3 wk: 37.9 (14.8), −1.0^*^ | Diff ∆^*^:; 3 wk: 8.6
Nusser, 2021^52^; VR; High | Flexion | 40.9 (14.6); 3 wk: 48.5 (13.3), 7.6^*^ | CG; 45.8 (12.9); 3 wk: 42.9 (12.6), −2.9 | Diff ∆^*^:; 3 wk: 10.5
Nusser, 2021^52^; VR; High | Extension | 35.4 (12.8); 3 wk: 37.7 (15.1), 1.9^*^ | SMG; 39.1 (12.7); 3 wk: 44.6 (12.9), 5.5^*^ | Diff ∆^*^:; 3 wk: −3.6
Nusser, 2021^52^; VR; High | Extension | 35.4 (12.8); 3 wk: 37.7 (15.1), 1.9^*^ | CG; 43.1 (13.3); 3 wk: 39.8 (14.7), −3.3^*^ | Diff D^*^:; 3 wk: 5.2
Nusser, 2021^52^; VR; High | Left rotation | 57.4 (12.7); 3 wk: 65.2 (16.9), 7.8^*^ | SMG; 51.7 (17.9); 3 wk: 55.8 (15.5), 4.1^*^ | Diff ∆^*^:; 3 wk: 3.7
Nusser, 2021^52^; VR; High | Left rotation | 57.4 (12.7); 3 wk: 65.2 (16.9), 7.8^*^ | CG; 59.3 (10.1); 3 wk: 59.9 (9.3), 0.6 | Diff ∆^*^:; 3 wk: 7.2
Nusser, 2021^52^; VR; High | Right rotation | 55.6 (10.4); 3 wk: 59.5 (14.0), 3.9^*^ | SMG; 54.6 (13.7); 3 wk: 58.6 (13.4), 4.0^*^ | Diff ∆^*^:; 3 wk: −0.1
Nusser, 2021^52^; VR; High | Right rotation | 55.6 (10.4); 3 wk: 59.5 (14.0), 3.9^*^ | CG; 61.8 (15.3); 3 wk: 64.0 (0.2), 2.2^*^ | Diff ∆^*^:; 3 wk: 1.7
Rezaei, 2019^56^; AR; High | Dynamic balance: Y-balance test | 78.65 (5.37); 4 wk: 84.67 (7.01), 6.02^*^; 9 wk: 86.24 (8.15), 7.59^*^ | 81.55 (8.76); 4 wk: 88.69 (8.92), 7.14^*^; 9 wk: 88.98 (10.7), 7.43^*^ | Diff ∆^*^:; 4 wk: −1.12; 9 wk: 0.16
Sarig Bahat, 2015^55^; VR; Some concerns | Flexion | 38.69 (14.6); 5 wk: 57.31 (11.3), 18.62^*^; 4 mo: 55.38 (11.2), 16.69^*^ | 43.94 (14.3); 5 wk: 49.87 (17.2), 5.93^*^; 4 mo: 58.4 (11.4), 14.46^*^ | Diff ∆^*^:; 5 wk: 12.69; 4 mo: 2.23
Sarig Bahat, 2015^55^; VR; Some concerns | Extension | 48.72 (15.1); 5 wk: 57.45 (14.1), 8.73^*^; 4 mo: 57.64 (8.8), 8.92^*^ | 51.09 (13.2); 5 wk: 54.19 (12.8), 3.1^*^; 4 mo: 54.5 (11.0), 3.41^*^ | Diff ∆^*^:; 5 wk: 5.63; 4 mo: 5.51
Sarig Bahat, 2015^55^; VR; Some concerns | Right rotation | 62.32 (13.1); 5 wk: 71.84 (14.0), 9.52^*^; 4 mo: 72.04 (16.2), 9.72^*^ | 57.06 (16.6); 5 wk: 77.21 (10.6), 20.15^*^; 4 mo: 88.89 (21.4), 31.83 | Diff ∆^*^:; 5 wk:; 4 mo:
Sarig Bahat, 2015^55^; VR; Some concerns | Left rotation | 58.58 (15.3); 5 wk: 77.74 (16.0); 4 mo: 70.38 (20.6) | 57.94 (15.3); 5 wk: 72.58 (13.6); 4 mo: 84.26 (23.3) | Diff ∆^*^:; 5 wk: 5.16; 4 mo: −13.88
Sarig Bahat, 2015^55^; VR; Some concerns | Eyes closed balance | 28.05 (15.3); 5 wk: 26.67 (11.6); 4 mo: 31.73 (19.2) | 4.48 (20.1); 5 wk: 25.08 (17.3); 4 mo: 27.87 (32.1) | Diff ∆^*^:; 5 wk: 1.59; 4 mo: 3.86
Sarig Bahat, 2017^54^; VR; Some concerns | Flexion | 60.54 (10.1); 4 wk: 61.38 (7.1), 0.84^*^ | Laser; 64.7 (7.2); 4 wk: 65.44 (9.0), 0.74^*^ | Diff ∆^*^:; 4 wk: 0.1
Sarig Bahat, 2017^54^; VR; Some concerns | Flexion | 60.54 (10.1); 4 wk: 61.38 (7.1), 0.84^*^ | Control; 62.98 (7.3); 4 wk: 64.52 (6.0), 1.54^*^ | Diff ∆^*^:; 4 wk: −0.7
Sarig Bahat, 2017^54^; VR; Some concerns | Extension | 63.17 (11.9); 4 wk: 64.67 (11.0), 1.5^*^ | Laser; 62.91 (14.6); 4 wk: 65.28 (12.8), 2.37^*^ | Diff ∆^*^:; 4 wk: −0.87^*^.
Sarig Bahat, 2017^54^; VR; Some concerns | Extension | 63.17 (11.9); 4 wk: 64.67 (11.0), 1.5^*^ | Control; 65.42 (11.2); 4 wk: 67.11 (7.9), 1.69^*^ | Diff ∆^*^:; 4 wk: −0.19
Sarig Bahat, 2017^54^; VR; Some concerns | Right rotation | 73.77 (16.2); 4 wk: 75.28 (13.3), 1.51^*^ | Laser; 78.14 (14.7); 4 wk: 80.65 (14.2), 2.51^*^ | Diff ∆^*^:; 4 wk: −1.0
Sarig Bahat, 2017^54^; VR; Some concerns | Right rotation | 73.77 (16.2); 4 wk: 75.28 (13.3), 1.51^*^ | Control; 78.87 (12.2); 4 wk: 79.08 (11.5), 0.21 | Diff ∆^*^:; 4 wk: 1.3
Sarig Bahat, 2017^54^; VR; Some concerns | Left rotation | 76.86 (14.5); 4 wk: 77.43 (11.9), 0.57^*^ | Laser; 77.18 (15.9); 4 wk: 77.45 (15.0), 0.27^*^ | Diff D^*^:; 4 wk: 0.3
Sarig Bahat, 2017^54^; VR; Some concerns | Left rotation | 76.86 (14.5); 4 wk: 77.43 (11.9), 0.57^*^ | Control; 78.93 (16.0); 4 wk: 81.17 (12.3), 2.24^*^ | Diff D^*^:; 4 wk: −1.67
Tejara, 2020^53^; VR; Some concerns | Flexion/extension | 110.22 (19.19); 4 mo: 112.03 (23.99), 1.81^*^ | 116.13 (22.34); 4 mo: 117.60 (24.27), 1.47^*^ | Diff ∆^*^:; 4 mo: 0.34
Tejara, 2020^53^; VR; Some concerns | Lateroflexion | 79.54 (20.61); 4 mo: 84.93 (21.47), 5.39^*^ | 87.21 (17.96); 4 mo: 86.42 (16.79), −0.79^*^ | Diff ∆^*^:; 4 mo: 6.18
Tejara, 2020^53^; VR; Some concerns | Rotation | 114.1 (18.97); 4 mo: 121.9 (18.49), 7.8^*^ | 118.48 (15.19); 4 mo: 124.3 (15.55), 5.82^*^ | Diff ∆^*^:; 4 mo: 1.98

Notes.

* Calculated by review team.

Abbreviations. AR=augmented reality; CG=control group; Diff ∆= difference in change scores; FABQ=Fear Avoidance Beliefs Questionnaire; JPSE=Joint Position Sense Error; KT=kinematic therapy; mo=month; NDI=Neck Disability Index; NC=not calculable; NR=not reported; NRS=Numeric Rating Scale; PASS-20=Pain Anxiety Symptom Scale; PCS=Pain Catastrophizing Scale; QoL=quality of life; ROM=range of motion; SD=standard deviation; SF-36=Short Form-36; SMG=sensorimotor group; TSK=Tampa Scale of Kinesiophobia; TTP=time-to-peak; VAS=Visual Analog Scale; VR=virtual reality; wk=week.