# APPENDIX E CHRONIC BACK PAIN

Appendix Table E1 Detailed Characteristics for Included Trials on Chronic Low Back Pain

Author, Year; Risk of Bias; Follow-Up Duration; Site(s); Funding source | Inclusion/Exclusion Criteria | Intervention: Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Intervention Characteristics | Comparator(s): Participants Randomized; Demographics; Setting; Frequency; Duration; Detailed Comparator Characteristics | Primary Outcome; Eligible Outcomes & Measures Reported (Time Points); Other Non-Eligible Outcomes Reported
VR Interventions
Eccleston, 2022^27^; Some concerns; 10 Months; NR, Finland; Orion Corporation; Business Finland | Inclusion: Adults with LBP ≥3 months, average pain intensity ≥ 4/10 over past week on NRS, ODI ≥26%, and medium (34-41) or high (42-68) TSKscore; had clear, flat ground surface at home of at least 2 m^2^ using the digital intervention for pain; and could bend without severe pain.; Exclusion: history of epilepsy, migraine, vertigo, or psychosis, a confirmed diagnosis of cancer, susceptibility to motion sickness requiring treatment, pregnancy, current physiotherapy that contraindicated intervention goals, severe or acute structural pathologies that the intervention could make worse, had psychotherapy in the previous 2 years or currently receiving psychotherapy, reported any condition that affected posture or balance, any prior participation in a digital therapeutics intervention for pain study | N=14; Age, mean (SD): 55.1 (10.5); Female: 86%; Home; 15-60 minute sessions, 5 sessions per week, for 30 unique days designed to last 6-8 weeks; DTxP: Mentor guidance and instruction for tasks and building working alliance using an Oculus Quest headset. Participants entered the virtual world from inside cabin then engaged in gamified activities like fruit picking outside. 24 behavior change modules alternated new content and practice. | N=17; Age, mean (SD): 52.8 (11.19); Female: 82%; Home; 15-60 minute sessions, 5 sessions per week, for 30 unique days designed to last 6-8 weeks; Relaxation instructions to enjoy virtual summer cabin and lakeshore environment with ambient wildlife sounds using an Oculus Quest headset. No DTxP content provided. | Primary: NR; Pain-related functioning (8 wk):; - ODI; - PROMIS pain interference; Pain intensity (8 wk):; - NRS; - PROMIS pain intensity; Adverse events (8 wk):; - Mild, moderate, severe; - Treatment-related; Pain catastrophizing (8 wk):; - TSK; Quality of life (8 wk):; - European Quality of Life 5; Opioid use (5 mo); Pain global change (8 wk):; - PGIC
Eccleston, 2022^27^; Some concerns; 10 Months; NR, Finland; Orion Corporation; Business Finland | | | N=11; Age, mean (SD): 57.1 (8.3); Female: 100%; Home; NA; Usual care
Groenveld, 2023^28^; Some concerns; 4 Months; Rijnstate Hospital, Netherlands; This work was supported by the European Regional Development Fund (ERDF) [PROJ-00840, 2018] | Inclusion: 18 years and older with nonspecific chronic lower back pain (lasting at least 3 months) reporting an average pain score of 4 and higher on an 11-point Likert scale in the week preceding enrollment. Additionally, the person has an estimated waiting period of at least 6 weeks on the day of recruitment on the waiting list, is not yet receiving treatment, apart from analgesics or physiotherapy, and did not receive any invasive treatment for his chronic nonspecific low-back pain in the last year.; Exclusion: People with radicular pain that is worse than the CLBP, participating in another trial to evaluate new ways of treating pain, severe anxiety or depression, unable to handle VR due to delirium, dementia, epilepsy, severe hearing/visual impairment, skin of the head or face not intact, and high risk of Meticillin-resistant Staphylococcus aureus | N=20; Age, mean (SD): 51 (2.9); Female: 85%; Home; Four weeks of thrice daily sessions lasting between 10 and 30 minutes.; Pain education and psychological therapy VR treatment using the Oculus Gof. Patients embark on a ‘journey’ through the nervous system and can play five games, each rooted in different psychological treatment principles. | N=21; Age, mean (SD): 52 (2.5); Female: 80%; NA; NA; Usual care | Primary: SF-12; Pain-related functioning (4 wk, 4 mo):; - BPI; - ODI; Pain intensity (30 days):; - VAS; Adverse events (4 mo); Pain Catastrophizing (4 wk, 4 mo):; - PCS; Non-eligible outcomes:; - Pain Coping and Cognition List (PCCL); - Nottingham Extended Activities of Daily Living (NEADL); - Positive Health Questionnaire; - Hospital Anxiety and Depression Scale (HADS)
Harvie, 2022^24^; Some concerns; 1 Week; Metro South Health Persistent Pain Management Service, Australia; Seeding grant from The Hopkins Centre; Early Career Research Fellowship from the National Health and Medical Research Council of Australia (GNT1142929) | Inclusion: Adults referred to the Metro South Health Persistent Pain Management Service for the management of CLBP (duration at least six months), scored at least ‘moderate’ on Question 7 (‘How much bodily pain have you had during the past 4 weeks?’), and Question 8 (‘During the past 4 weeks, how much did pain interfere with your normal work [including both work outside the home and housework]?’) of the SF-36; Exclusion: Diagnosis of, or the presence of red flags, indicating serious spinal pathology (i.e., infection, tumour, recent fracture, significant structural deformity, such as unstable/unstabilized spondylolisthesis or progressive scoliosis, inflammatory disorder, and neuropathic radicular syndrome or cauda equina syndrome). They were also excluded if they had an inability to tolerate visual stimulation (e.g., susceptibility to migraines aggravated by light) or inability to tolerate the head mounted display (e.g., sensitivity to touch around the face and head). | N=20; Age, mean (SD): 51.9 (14.5); Female: 45%; Clinic; 1 session, three 6 minute long experiences with 5 minute intervals between each.; Embodiment experiences and movement (e.g., boxing, creating earthquakes) using the Oculus Rift S head mounted display with touch controllers with three avatar characters: a boxer, superhero, and rock climber using the Oculus Rift S. | N=10; Age, mean (SD): 56.9 (14.3); Female: 50%; Clinic; 1 session, three 6 minute blocks with 5 minute intervals; VR control condition. Embodiment of cartoon-like virtual hands. Explored 3 scenarios in Vacation Simulator app: built sandcastle, stood in sea at beach, cooked barbecue at beach using the Oculus Rift S. | Primary: NRS; Pain global change (1 wk):; - PGIC; Pain catastrophizing (1 wk):; - Photograph Series of Daily Activities; Physical performance (1 wk):; - Maximum grip strength; Non-eligible:; - Body image; - Embodiment
Kammler-Sücker, 2023^26^; Some concerns; 117 Days; VR Core Facility at the Center for Innovative Psychiatric and Psychotherapeutic Research (CIPP) at Central Institute for Mental Health (Mannheim, Germany), Gernaby; Reinhart Koselleck award of the Deutsche Forschungsgemeinschaft to HF (FL 156/41-1) | Inclusion: Chronic back pain lasting for more than 6 months and an age of 18–75 years.; Exclusion: Any acute primary causes for back pain (e.g., injuries or inflammation), acute neurological complications, inability or medical prohibition to lift weights of up to 15 kg, and a history of epileptic seizures triggered by flickering lights. | N=17; Age, mean (SD): 46.1 (17.6); Female: 71%; Clinic; Three sessions at least 4 and a maximum of 117 days apart. Due to the pandemic situation they had to reschedule the participants when there was a ban on laboratory activity. The mean duration between sessions was 13.65 ± 16.08 days.; 3D photos taken for avatar creation in AVA. The avatars were animated with prerecorded movements of a healthy model (motion capture with an infrared 12-camera system, OptiTrack, Corvallis, OR). Participants copied movements from virtual models based on previous kinematic studies. | N=16; Age, mean (SD): 51.9 (17.4); Female: 56%; Clinic; The subsequent three experimental sessions (sessions 1–3) were at least 4 and a maximum of 117 days apart. Due to the pandemic situation they had to reschedule the participants when there was a ban on laboratory activity. The mean duration between sessions was 13.65 ± 16.08 days.; Control group watched a virtual 2D screen inside the virtual environment showing a videotaped movement model (VID). | Primary: NR; Pain-related functioning (sessions 1-3):; - NRS; Pain intensity (sessions 1-3):; - NRS
Maddox, 2022^29–33^; Some concerns in domain 4 only; 18 Months; United States; AppliedVR | Inclusion: People aged 18-85, with self-reported diagnosis of chronic low back pain without radicular symptoms lasting 6 months or more, an average pain intensity of 4 or more out of 10 for the past month.; Exclusion: People with gross cognitive impairment, current or prior diagnosis of epilepsy, seizure disorder, dementia, migraines, or other neurological diseases that may prevent the use of virtual reality or adverse effects medical condition predisposing to nausea or dizziness, hypersensitivity to flashing light or motion, no stereoscopic vision or severe hearing impairment, injury to eyes, face, or neck that impedes comfortable use of virtual reality, cancer-related pain, moderate depressive symptoms as indicated by the Patient Health Questionnaire-2 (PHQ-2 [44,45]) depression screen score of 2 or more, previous use of EaseVRx for pain, current or recent completion of participation (past 2 months) in any interventional research study, currently pregnant or planning to become pregnant during the study period. | N=94; Age, mean (SD): 51.5 (13.5); Female: 75.3%; Home; 56 sessions 2-16 minutes in length for 8 weeks; EaseVRx (AppliedVR) incorporates evidence-based principles of CBT, mindfulness, and pain neuroscience education. Participants complete modules that include pain education, relexation/interoception, mindful escapes, pain distraction games, and dynamic breathing. | N=94; Age, mean (SD): 51.4 (12.9); Female: 78.7%; Home; Each VR experience is 2-16 minutes in length (average of 6 minutes).; Nonimmersive, 2D content within a VR headset as the most rigorous VR placebo. The Sham VR headset displayed 2D nature footage (eg, wildlife in the savannah) with neutral music that was selected to be neither overly relaxing, aversive, nor distracting. The experience of Sham VR is similar to viewing nature scenes on a large-screen television and is not interactive. Twenty videos were rotated over the 56 sessions, with average duration of sessions closely matching those of EaseVRx. | Primary: DVPRS; Non-eligible outcomes (8 wk):; - PROMIS physical function; - PROMIS sleep disturbance
Yelvar, 2016^25^; High; 2 Weeks; Turgut Ozal University Hospital Department of Physical Therapy and Rehabilitation, Turkey; NR | Inclusion: Diagnosis of subacute and chronic LBP by a physician, no experience with surgical treatments for disc herniation, spina bifida, or spinal stenosis, no visual problems, no nerve root compression, no neurological problems, and patients who have fear of avoidance.; Exclusion: None | N=23; Age, mean (SD): 46.3 (3.4); Female: 45.5%; Clinic; Five times a week for 2 weeks; Embodiment using iPod with video glasses where participants passively viewed a virtual walking video clip and were asked to imagine they were walking. They also underwent physical therapy (15 minutes of hotpack therapy, 15 minutes of TENS, and 5 minutes of deep heat with ultrasound, and therapeutic exercises, including extension exercise, posterior pelvic tilt, cat–camel exercise, and stretching of the lumbar extensor muscle). | N=23; Age, mean (SD): 52.8 (11.5); Female: 81.8%; Clinic; Five times a week for 2 weeks; Participants underwent physical therapy (15 minutes of hot pack therapy, 15 minutes of TENS, and 5 minutes of deep heat with ultrasound, and therapeutic exercises, including extension exercise, posterior pelvic tilt, cat–camel exercise, and stretching of the lumbar extensor muscle). | Primary: NR; Pain-related functioning (2 wk):; - ODI; Pain intensity (2 wk):; - VAS; Pain catastrophizing (2 wk):; - TSK; Physical performance (2 wk):; - Timed-up and go test (TUG); - 6-minute walk test; Quality of life (2 wk):; - Nottingham Health Profile
AR Intervention
Afzal, 2022^38^; Some concerns; 4 Weeks; Government Services Hospital, Lahore, Pakistan, Pakistan; None | Inclusion: Adults aged 25-50 with a history of CLBP.; Exclusion: “Patients with congenital deformity, history of trauma, fracture of the spine, or the lower extremity, any systematic disease, or neurological diseases, those on corticosteroid and pregnant females were excluded.” | N=45; Age, mean (SD): 38.2 (11.8); Female: 69.0 %; Clinic; 3 sessions per week for a total of 12 sessions; “kinetic exergames, like the body ball game and reflex ridge, with on-screen display for 5 minutes each, along with RPT… patients were subjected to trunk slide flexion, sitting to avoid obstacles, jumping and combined movement of arms for 5 minutes… After 30 seconds of rest, the body ball game, including moving arm, head pushing and kicking of ball, for 5 minutes was introduced.” | N=45; Age, mean (SD): 37.5 (12.5); Female: 64.3%; NR; 3 sessions per week for a total of 12 sessions; “RPT with 10 minutes of heat therapy by a moist hot pack, and hamstring stretching. Back strengthening exercises included 10 repetition of bridging, prone leg raises, trunk extension in prone with arms behind the back, trunk rotation exercises, knee to chest, and prone position with a diagonal elevation of the arm and the leg.” | Primary: VAS; Pain-related functioning (4 wk); - MODI
Fatoye, 2022^36^; High; 8 Weeks; Obafemi Awolowo University; Ladoke Akintola University of Technology Teaching Hospital, Nigeria; This research was partially funded by an African Doctoral Dissertation Research Fellowship (ADDRF) re-entry grant awarded by the African Population and Health Research Centre (APHRC) in partnership with the International Development Research Centre (IDRC). | Inclusion: Patients with LBP of not less than 3 months, as determined by the standard McKenzie Institute Lumbar Spine Assessment Algorithm. Patients who demonstrated Directional Preference (DP) for extension.; Exclusion: Patients with DP for flexion, positive history of red flags indicative of serious spinal pathology; any obvious spinal deformity or neurological disease; pregnancy; previous spinal surgery; and previous experience of MDT extension protocol, as well as, those with underlying systemic or visceral disease and specific condition such as dementia, cognitive dysfunction, visual impairment and previous history of epilepsy were excluded. | N=29; Age, mean (SD): 47.6 (11.5); NR; NR; Three times a week for 8 weeks; Microsoft Kinect interactive video game to achieve therapeutic activities comparable to the McKenzie “extension in standing” protocol. Participants were asked to head virtual balls on the screen as though they were coming towards them, moving only their trunk and head. | N=28; Age, mean (SD): 48.8 (10.2); NR; NR; Three times a week for 8 weeks; Participants did the McKenzie extension protocol, where they stand upright with feet slightly apart, place their hands on the small of their back, then stretch their trunk backwards as far as they can 10 times. | Primary NR; Pain-related functioning (8 wk); - ODI; Non-eligible: Resource use, cost, cost-effectiveness
Kim, 2014^48^; High; 4 Weeks; A K hospital, Korea; NR | Inclusion: Suffer from chronic lower back pain; Exclusion: None listed | N=15; Age, mean (SD): 44.3 (NR); Female: 100%; Clinic; 12 sessions over the course of four weeks, with each session lasting 30 minutes.; “A 30-minute virtual reality-based yoga program using Wii Fit activities such as deep breathing, the half-moon pose, warrior pose, tree pose, chest to knee pose, chair pose, and palm tree pose… There were seven exercise programs. Three minutes of exercise were performed followed by one minute of rest.” | N=15; Age, mean (SD): 50.5 (NR); Female: 100%; Clinic; Each movement was comprised of two sets lasting 30 minutes. One set included 10 repetitions.; “Trunk stabilizing exercise was performed with contraction exercise for the transverse abdominis and multifidus followed by curl ups in order to contract the rectus abdominis. The dead bug exercise, quadruped opposite arm and leg reach exercises, bridge, side bridge on knees, middle anterior plank position, and balancing on unstable surfaces were performed.” | Primary: RMDQ, VAS, ODI; Pain Catastrophizing (4 wk):; - FABQ
Kim, 2019^43^; High; 6 Months; Korea University, Republic of Korea; NR | Inclusion: People aged 20–64 years with nonspecific LBP lasting at least 3 months, with an average numeric rating scale (NRS) in the previous 7 days of ≥4 (scale 0–11); Exclusion: Presented with specific causes of LBP, had other sensory or motor dysfunctions resulting from neurological disorders, had any cardiovascular or psychological disease, had any other mental or physical limitation, had surgery or trauma within the past 6 months, or were pregnant or planning to become pregnant | N=24; Age, mean (SD): 26 (3.8); Female: 31.8%; Clinic; 16 46-minute sessions over 8 weeks; Equine therapy using the SHR system, that simulates a horse gait. The workout consists of walking, slow trotting, and fast trotting at a real horse gait. | N=24; Age, mean (SD): 28.8 (9.1); Female: 57.7%; Clinic; 16 46-minute sessions over 8 weeks; “The STB exercise with suspension (Redcord AS, Arendal, Norway) consisted of a supine pelvic lift, supine and prone bridging exercise, and side-lying hip abduction… Time required to perform each movement was about 10 seconds.” | Primary: NRS; Pain-related functioning (8 wk, 6 mo):; - ODI; - RMDQ; Pain Catastrophizing (8 wk, 6 mo):; - FABQ physical; - FABQ work
Li 2021^39^; High; 2 Weeks; First Affiliated Hospital of Sun Yat-sen University, China; “This research project was supported by the National Natural Science Foundation of China (grant number 82002375, 81772434, and 32071316); the Guangdong Province Medical Science Technology Research Grant (grant number A2019452) and the Guangdong Basic and Applied Basic Research Foundation (No. 2020A1515011356); the Guang zhou Science and Technology Program key projects (grant numbers 201704020122 and 201907010034); and the Non Profit Central Research Institute Fund of Chinese Academy of Medical Sciences (No. 2020-JKCS-005).” | Inclusion: People aged between 18 and 40 years with persistent or periodic LBP for longer than 3 months, and no referred symptoms of radiating pain below the knee or paresthesia during the straight-leg raise test.; Exclusion: People with a history of pelvic or spinal column surgery in the past two years, diagnosis of any specific lumbar pathological condition and/or severe or progressive scoliosis, body mass index (BMI) ≥30kg/m2, history of a treatment program within the past three months, pregnant, history of severe dysfunction of vital organs (heart, lungs, and kidneys) and/or cognitive deficits, and history of visual or hearing problems. | N=11; Age, mean (SD): 21.91 (2.4); Female: 72.7%; Home; Clinic; 6 3-minute sessions per day, with a 2 minute break between sessions, 5 days a week for 2 weeks; Participants played Fruit Ninja on the Microsoft Kinect, wherein participants waved their hands to crush fruit in the game. Participants were asked to limit bending their trunk or turning. They also received 20 minutes of magnetic therapy. | N=12; Age, mean (SD): 23.75 (4.1); Female: 83.3%; Home; Clinic; Approximately 1 30-minute session, 5 days a week for 2 weeks; Participants did Motor Control Exercise (MCE) with ultrasound-guided abdominal drawing-in maneuver (ADIM). 3 sets of 10 repetitions holding for 10 sec, with 2 min breaks between sets. Four-point kneeling lifting each arm/leg for 5 sec, 3 reps each with 15 sec breaks. Raised contralateral arm and leg in bird dog position, held 5 sec, 3 reps with 15 sec breaks. They also received 20 minutes of magnetic therapy.; N=11; Age, mean (SD): 25.4(3.7); Female: 63.6%; Home; Clinic; 20 minute sessions, 5 days a week, two weeks; Participants received 20 minutes, medium heat level conventional magnetic therapy | Primary NR; Pain-related functioning (2 wk):; - ODI; Pain intensity (2 wk):; - VAS; Non-eligible: Muscle activation times, electromyography
Mbada, 2019^50^; High; 8 Weeks; Obafemi Awolowo University (OAU) Teaching Hospital, Ile Ife, Nigeria (OAUTHC); Department of Medical Rehabilitation, OAU; and Ladoke Akintola University of Technology Teaching Hospital, Osogbo, Nigeria (LAUTECH), Nigeria; This research was partially funded by an African Doctoral Dissertation Research Fellowship re-entry grant awarded by the African Population and Health Research Centre in partnership with the International Development Research Centre (IDRC). | Inclusion: Adults with long-term mechanical lower back pain and directional preference for extension.; Exclusion: Patients who demonstrated directional preference for flexion, lateral, or no directional preference. | N=28; Age, mean (SD): 32.6 (11.5); Female: 45.5%; NR; Thrice weekly for 8-week[s]; Microsoft Kinect interactive video game to achieve therapeutic activities comparable to the McKenzie “extension in standing” protocol. Participants were asked to head virtual balls on the screen as though they were coming towards them, moving only their trunk and head. | N=29; Age, mean (SD): 48.8 (10.2); Female: 79.2%; NR; Thrice weekly for 8-week[s]; Participants did the McKenzie extension protocol, where they stand upright with feet slightly apart, place their hands on the small of their back, then stretch their trunk backwards as far as they can up to 10 times. Participants also received a 9-item back care education guide on activities of daily living. | Primary: ODI, RMDQ, VAS, TSK, FABQ work, FABQ physical, Modified Biering-Sørensen test of Static Muscular Endurance (bSME); QoL (8 wk):; - SF-12 mental; - SF-12 physical
Monteiro-Junior, 2015^46^; High; 8 Weeks; Fisioprime Clinical of Physiotherapy, Brazil; NR | Inclusion: People with chronic lower back pain, not participating in systematic exercise program; Exclusion: People without medical recommendation (Physical Activity Readiness Questionnaire (PAR-Q),who underwent spine surgery, with cancer, with acute musculoskeletal injuries in lower limbs, with neurological illnesses; and with vestibular noncontrolled disorders. | N=17; Age, mean (SD): NR (NR); Women: 100%; Clinic; Eight weeks with three sessions a week; The intervention lasted eight weeks and sessions were performed three times a week. In core exercises the postures adopted by subjects lasted 15-30 seconds or in accordance with the capacity of each person. Each exercise (squat, lunge, chair abductor, chair adductor, leg curl, knee extension, unilateral plantar flexion) was performed three times (i.e., sequential method) with 10 repetitions. Participants also did 30 minutes of virtual physical training (eight exercises) using Nintendo Wii-motion and Wii Balance Board. | N=17; Age, mean (SD): NR (NR); Women: 100%; Clinic; Eight weeks with three sessions a week; Control group performed strength training and core exercises. Weight load was moderate and was increased gradually based on pain reduction. Each exercise was performed in 3 sets of 10 repetitions. | Primary: NRS, Sit-to-stand test; Non-eligible: Balance, Total Mood
Nambi 2020a^37^; Some concerns; 6 Months; Prince Sattam bin Abdul Aziz University; University Hospital and King Khalid Hospital, Saudi Arabia; Deanship of Scientific Research at Princess Nourah Bint Abdulrahman University through the Fast-track Research Funding Program | Inclusion: University male football players aged 18–25 years, with chronic (≥3 months) LBP, and 4 to 8 pain intensity in VAS.; Exclusion: People with severe musculoskeletal, neural, somatic, and psychiatric conditions, waiting for spine surgery, having alcohol or drug abuse, and involving in other weight and balance training programs were excluded from the study. Participants with other soft tissue injuries, fracture at the lower limbs and pelvic bone, and deformities were also excluded from the study. | N=15; Age, mean (SD): 21.25 (1.2); Male: 100%; Home; Clinic; 30 minute sessions, 5 days a week for 4 weeks; Participants used the ProKin system to play a shooting game. The game was controlled by participants moving their trunk back and forth and left and right. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and five minutes ultrasound therapy. | N=15; Age, mean (SD): 20.23 (1.6); Male: 100%; Home; Clinic; 5 days a week for 4 weeks; Participants used the Isokinetic Dynamometer to perform extension and flexion exercises consisting of 3 sets of 15 repetitions. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and five minutes ultrasound therapy. | Primary: NR; Pain intensity (4 wk, 8 wk, 6 mo):; - VAS; Physical performance (4 wk, 8 wk, 6 mo):; - 40 m sprint performance; - 4×5 sprint; - Submaximal shuttle running; - Countermovement jump; - Squat jump; Non-eligible: Self-reported player wellness (Likert scale)
| | | N=15; Age, mean (SD): 20.8 (1.6); Male: 100%; Home; clinic; 5 days per week for 4 weeks; Participants did conventional balance training for core muscles, including active isotonic and isometric exercises for abdominal muscles (ie, internal oblique, external oblique, transverse abdominis, and rectus abdominis) and deep abdominal muscles. They also underwent 20 minutes of hot pack therapy and 5 minutes ultrasound therapy.
Nambi, 2020b^42^; High; 6 Months; Prince Sattam Bin Abdulaziz University Hospital, Al-Kharj; King Khalid Hospital, Saudi Arabia; self-funded | Inclusion: University male students in the age group of 18–25 years with cLBP (3 months) and 4 to 8 pain intensity on the VAS; Exclusion: Participants with severe musculoskeletal-, neural-, somatic- and psychiatric conditions, who were waiting for spine surgery, with alcohol or drug abuse symptoms, are involved in other weight and balance training programs, have other soft tissue injuries, fracture at the lower limbs and pelvic bone, or deformities. | N=20; Age, mean (SD): 23.2 (1.5); Male: 100%; NR; 30 minute sessions 5 days a week for 4 weeks; Participants used the ProKin system to play a shooting game. The game was controlled by participants moving their trunk back and forth and left and right. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and five minutes ultrasound therapy. Exercises other than the ones in the protocol were at the decision of the supervising therapist and were documented in the log book. | N=20; Age, mean (SD): 22.8 (1.6); Male: 100%; NR; 5 days a week for 4 weeks; Participants used the Isokinetic Dynamometer to perform extension and flexion exercises consisting of 3 sets of 15 repetitions. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and five minutes ultrasound therapy. Exercises other than the ones in the protocol were at the decision of the supervising therapist and were documented in the log book. | Primary: VAS, TSK; Non-eligible: Stress hormone levels
Nambi, 2020b^42^; High; 6 Months; Prince Sattam Bin Abdulaziz University Hospital, Al-Kharj; King Khalid Hospital, Saudi Arabia; self-funded | | | N=20; Age, mean (SD): 23.3 (1.5); Male: 100%; NR; 5 days a week for 4 weeks; Participants did conventional balance training for core muscles, including active isotonic and isometric exercises for abdominal muscles (i.e., internal oblique, external oblique, transverse abdominis, and rectus abdominis) and deep abdominal muscles. They also underwent 20 minutes of hot pack therapy and 5 minutes ultrasound therapy. | Primary: VAS, TSK; Non-eligible: Stress hormone levels
Nambi, 2021^41^; High; 6 Months; King Khalid University Hospital and Department of Physical Therapy andHealth Rehabilitation, Prince Sattam Bin Abdulaziz University, Saudi Arabia; NR | Inclusion: Male American university soccer players aged 18–25 years, with chronic (≥3 mo) LBP, and 4 to 8 pain intensity on a VAS; Exclusion: Participants with severe musculoskeletal, neural, somatic, and psychiatric conditions, as well as those waiting for spine surgery, having alcohol or drug abuse issues, or involved in other weight and balance training programs, with other soft tissue injuries, fracture at the lower limbs and pelvic bone, and deformities. | N=18; Age, mean (SD): 22.3(1.6); Male: 100%; Home; 30 minutes in each session for 5 days a week for 4 weeks.; Participants used the ProKin system to play a shooting game. The game was controlled by participants moving their trunk back and forth and left and right. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and five minutes ultrasound therapy. Exercises other than the ones in the protocol were at the decision of the supervising therapist and were documented in the log book. | N=18; Age, mean (SD): 21.9 (1.8); Male: 100%; Home; 5 days a week for 4 weeks; Participants used the Isokinetic Dynamometer to perform extension and flexion exercises consisting of 3 sets of 15 repetitions. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and five minutes ultrasound therapy. Exercises other than the ones in the protocol were at the decision of the supervising therapist and were documented in the log book. | Primary: VAS, TSK; Non-eligible: Stress hormone levels
Nambi, 2021^41^; High; 6 Months; King Khalid University Hospital and Department of Physical Therapy andHealth Rehabilitation, Prince Sattam Bin Abdulaziz University, Saudi Arabia; NR | | | N=18; Age, mean (SD): 21.4 (1.8); Male: 100%; Home; 15 times per set for 3 sets, 5 times per week for 4 weeks.; Participants did conventional balance training for core muscles, including active isotonic and isometric exercises for abdominal muscles (i.e., internal oblique, external oblique, transverse abdominis, and rectus abdominis) and deep abdominal muscles. They also underwent 20 minutes of hot pack therapy and 5 minutes ultrasound therapy. | Primary: VAS, TSK; Non-eligible: Stress hormone levels
Nambi, 2023^35^; Some concerns in domain 4 only; 4 Weeks; Department of Physiotherapy, Prince Sattam bin Abdulaziz University, Saudi Arabia,; University Hospital and King Khalid Hospital, Riyadh, Saudi Arabia, Saudi Arabia; Prince Sattam bin Abdulaziz University project number (PSAU/2023/R/1444) | Inclusion: Male soccer players aged 18–25 years, chronic non-specific LBP for three or more months, and pain score ranging from 4 to 8 on a 10-centimetre VAS; Exclusion: People with lumbar stenosis, lumbar radiculopathy, lumbar spondylolisthesis, spinal injuries, associated low back muscle and tendon injuries, fracture of the pelvic bone and lower extremity bones, spine dysfunctions, awaiting spine surgery, participants taking steroids, medications or analgesics, having serious pathologies of the thoracolumbar spine, participating in other resistance training and physical training programs | N=20; Age, mean (SD): 23.2 (1.6); Male: 100%; Clinic; Thirty minutes per session, five days a week, for 4 weeks; Participants used the ProKin system to play a shooting game. The game was controlled by participants moving their trunk back and forth and left and right. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and five minutes ultrasound therapy. | N=20; Age, mean (SD): 22.9 (1.7); Male: 100%; Clinic; Thirty minutes per session, five days a week, for 4 weeks; Participants used the Isokinetic Dynamometer to perform extension and flexion exercises consisting of 3 sets of 15 repetitions. They also performed a home-based exercise protocol and underwent 20 minutes of hot pack therapy and 5 minutes ultrasound therapy. | Primary: VAS; Non-eligible: Radiological measures, inflammatory biomarkers
| | | N=20; Age, mean (SD): 22.8 (1.8); Male: 100%; Clinic; Thirty minute per session, five days a week, for 4 weeks; Participants did conventional balance training for core muscles, including active isotonic and isometric exercises for abdominal muscles (i.e., internal oblique, external oblique, transverse abdominis, and rectus abdominis) and deep abdominal muscles. They also underwent 20 minutes of hot pack therapy and 5 minutes ultrasound therapy. | Primary: VAS; Non-eligible: Radiological measures, inflammatory biomarkers
Oh, 2014^49^; High; 8 Weeks; Hanseo University, Korea; NR | Inclusion: Complaining of back pain in everyday life for over 3 months; Exclusion: Past or present neurological, hypertension, cardiopulmonary diseases, and operation for lower back pain | N=10; Age, mean (SD): 20.6 (0.7); Male: 100%; Clinic; 10 min (short period) a day for 5 days a week for 8 weeks; Equine therapy using a horse simulator machine to perform a 5 minute warm-up, walking for 5 minutes, then 4 maximal warm-up and 4 maximal test repetitions. | N=9; Age, mean (SD): 20.3(0.5); Male: 100%; Clinic; 20 min (middle period) a day for 5 days a week for 8 weeks; Equine therapy using a horse simulator machine to perform a 5 minute warm-up, walking for 5 minutes, then 4 maximal warm-up and 4 maximal test repetitions. | Primary: VAS
Oh, 2014^49^; High; 8 Weeks; Hanseo University, Korea; NR | Inclusion: Complaining of back pain in everyday life for over 3 months; Exclusion: Past or present neurological, hypertension, cardiopulmonary diseases, and operation for lower back pain | | N=10; Age, mean (SD): 20.4 (0.3); Male: 100%; Clinic; 8 weeks; Equine therapy using a horse simulator machine to perform a 5 minute warm-up, walking for 5 minutes, then 4 maximal warm-up and 4 maximal test repetitions. | Primary: VAS
Oh, 2014^49^; High; 8 Weeks; Hanseo University, Korea; NR | Inclusion: Complaining of back pain in everyday life for over 3 months; Exclusion: Past or present neurological, hypertension, cardiopulmonary diseases, and operation for lower back pain | | N=9; Age, mean (SD) 20.7 (0.4); Male: 100%; NA; 8 weeks; Usual care | Primary: VAS
Sato, 2021^40^; High; 8 Weeks; Chiba University Hospital, Japan; No funding for research | Inclusion: People with low back pain persisting for more than 3 months and were referred to the hospital without sufficient improvement after receiving conservative treatment at another orthopedic clinic; Exclusion: People with nerve stenosis whose symptoms could be explained on magnetic resonance imaging (MRI), severe intermittent claudication (100 meters or less), cases where lower limb manual muscle tests were graded 4/5 or less, or patients who were unable to ambulate independently, a history of spinal surgery within 1 year, restricted movement due to heart disease or other diseases, receiving exercise therapy at a health care facility during the study period, and significant cognitive impairment | N=20; Age, mean (SD): 49.3 (12.59); Female: 55%; NR; One 40 minute session a week for 8 weeks; Participants played the Nintendo Ring Fit Adventure game. In Adventure Mode, the player controls the character by jogging or squatting. In a battle scene, in addition to an aerobics menu, intensive resistance training and yoga exercises that exert stress on the muscles of the whole body are aimed at defeating the enemy and clearing the stage. They continued taking already prescribed medication. | N=20; Age, mean (SD): 55.6 (11.0); Female: 40%; Clinic; Patients came in every 2 weeks to be interviewed for pain. Medication doses, frequency and duration were not reported.; New oral treatments were given to each patient in the following order: (1) Non-Steroidal Anti-Inflammatory Drugs (NSAIDs), (2) tramadol, and (3) duloxetine. Each drug was started at the standard dose; if pain relief was not adequate, then the dose was gradually increased to its highest recommended level. If pain relief was still inadequate, the next drug was added. | Primary: VAS; Pain catastrophizing (8 wk); - PCS; - TSK; Non-eligible: pain self-efficacy questionnaire (PSEQ)
Thomas, 2016^45^; Some concerns in domain 4 only; 12 Days; Ohio University, US; NR | Inclusion: LBP category 1-3 (Classification System of the Quebec Task Force on Spinal Disorders); Exclusion: Age <18 or >50; LBP duration < 3 months and has not sought treatment; Tampa Scale for Kinesiophobia score < 35; health conditions that preclude safe participation; personal history of spine surgery or hip arthroplasty; currently taking narcotic pain medication; currently receiving treatments for back pain; personal history of exclusionary neurological, cardiorespiratory, or musculoskeletal disorders; active cancer or reports recent, unexplained weight loss; is blind; reports being pregnant; current or pending litigation related to back pain; clinically significant range for substance abuse (DAST>6), alcohol abuse (AUTID-C>7 for males and > 6 for females) or depression (CES-D >16) | N=27; Age, mean (SD): 23.9 (6.8); Female: 46.2%; Clinic; 3 sessions, separated by no more than 48 hours; The virtual dodgeball intervention was displayed on a 60 inch high definition 3D-TV. The participant played dodgeball against four virtual opponents in a basketball arena. The participant had to attempt to block or duck balls launched by the opponents. The intervention consisted of 3 sessions, separated by no more than 48 hours. | N=26; Age, mean (SD): 26.7 (8.5); Female: 50.0%; NA; NA; Usual care | Primary: VAS; Pain-related functioning (4 days):; - RMDQ; Adverse events (4 days); Pain catastrophizing (4 days):; - TSK; Non-eligible: Lumbar spine flexion, Game experience survey, Center for Epidemiological Studies - Depression
Yoo, 2014^47^; Some concerns; 8 Weeks; Hanseo University Hospital, Korea; NR | Inclusion: Complaining of back pain in everyday life for more than 3 months; Exclusion: Past or present neurological, hypertension or cardiopulmonary diseases, chronic disease and spine surgery. | N=24; Age, mean (SD): 20.4 (1.3); Male: 100%; Clinic; 3 days a week for 8 weeks; Participants underwent equine therapy using a horse simulator machine. They first completed a 10-minute warm-up, then did the completed the work out phase (including walking, sitting trotting, rising trotting), then completed a 10 minute cool-down. | N=23; Age, mean (SD): 20.7 (1.45); Male: 100%; NA; None; Usual care | Primary: VAS; Non-eligible: Night pain, exercise, drug relief, stiffness, walking freedom, walking discomfort, standing still, twisting, hard chair, soft chair, lying down, handicap, work interference, work modification, flexor PT, flexor PTBW, extensor PT, Extensor PTBW, PT ratio, flexor TW, flexor TWBW, extensor TWBW, TW ratio
Zadro, 2019^44^; Some concerns; 8 Weeks; The University of Sydney (participants from the community)Outpatient Physiotherapy Department of Westmead Hospital (participants on the waiting list), Australia; NR | Inclusion: Older than 55, nonspecific mechanical LBP for at least 3 months, usual pain intensity of ≥ 3 out of 10 on the numeric rating scale, sufficient English language ability to understand exercise instructions, ability to mobilize independently without the use of walking aids, access to a high-definition multimedia-interface–compatible television at home.; Exclusion: Diagnosis of serious pathology in the spine (such as fracture, metastatic disease, spinal stenosis, or caudaequina syndrome), evidence of nerve root compromise, any medical condition or disability that will prevent participation in the exercise program, including:, cardiovascular risk factors assessed with the PAR-Q, a screening tool recommended for all adults willing to initiate an exercise program, cognitive limitations, as indicated by a score of < 25/30 on the Mini-Mental State Examination, a reliable and valid test of cognitive function, high risk of falls, as indicated by a score of > 15 on the Falls Risk Assessment Tool, a reliable measure of the risk of falls in older adults, physical therapist treatment for LBP in the preceding 6 months. | N=30; Age, mean (SD): 68.8 (5.5); Women: 30%; Home; Three 60 minute sessions a week for 8 weeks; Wii U console with Wii Fit U software. PT visited home, set up equipment, guided first 1-2 hour session. Preselected flexibility, bodyweight, aerobic exercises in booklet to standardize. Fortnightly calls to encourage progression, monitor adverse events. Used symptoms in 24 hrs after to guide increasing/decreasing duration and intensity. | N=30; Age, mean (SD): 67.8 (6); Women: 21.7%; Home; NA; Usual care | Primary: PSEQ, FEQ-I; Pain-related functioning (8 wk):; - PSFS; - RMDQ; Pain intensity (8 wk):; - NRS; Pain catastrophizing (8 wk):; - TSK

Abbreviations: BPI=Brief Pain Inventory; DVPRS-II=Defense and Veterans Pain Rating Scale; FABQ=Fear Avoidance Beliefs Questionnaire; MODI=Modified Oswestry Disability Index; NR=not reported; ODI=Oswestry Disability Index; PCS=Pain Catastrophizing Scale; PGIC=Patient Global Impression of Change; PSFS=Patient Specific Functional Scale; QoL=quality of life; RMDQ=Roland-Morris Disability Questionnaire; SF-12=Short Form Health Survey; VAS=Visual Analog Scale.

Appendix Table E2 Detailed Results for Chronic Low Back Pain Studies

Author, Year; VR or AR; Risk of Bias | Effect Measure | Intervention; Baseline mean (SD); Follow-Up Mean (SD), Mean Change | Comparator; Baseline Mean (SD); Follow-Up Mean (SD), Mean Change | Comparison
Pain-Related Functioning or Interference
Afzal, 2022^38^; AR; Some concerns | MODI | 69.2 (9.1); 4 wk: 16.0 (6.8), −53.1^*^ | 65.1 (8.9); 4 wk: 40.6 (8.6), −24.5^*^ | Diff ∆^*^:; 4 wk: −28.6
Eccleston, 2022^27^; VR; Some concerns | ODI | 36.0 (7.6); 8 wk: 28.8 (15.6), −7.2^*^ | VR control; 37.2 (9.4); 8 wk: 38.5 (16.2), 1.3^*^ | Diff ∆^*^:; 8 wk: −8.5
Eccleston, 2022^27^; VR; Some concerns | ODI | 36.0 (7.6); 8 wk: 28.8 (15.6), −7.2^*^ | Usual care; 36.2 (7.6); 8 wk: 32.8 (8.6), −3.4^*^ | Diff ∆^*^:; 8 wk: −3.8
Eccleston, 2022^27^; VR; Some concerns | PROMIS pain interference | 64.5 (3.7); 8 wk: 59.0 (6.6), −5.5^*^ | VR control; 63.1 (3.4); 8 wk: 62.6 (5.3), −0.5^*^ | Diff ∆^*^:; 8 wk: −5.0
Eccleston, 2022^27^; VR; Some concerns | PROMIS pain interference | 64.5 (3.7); 8 wk: 59.0 (6.6), −5.5^*^ | Usual care; 63.1 (2.5); 8 wk: 60.9 (3.8), −2.2^*^ | Diff ∆^*^:; 8 wk: −3.3
Fatoye, 2022^36^; AR; High | ODI | 14.2 (9.4); 8 wk: 3.5 (3.5), −10.7^*^ | 21.1 (10.7); 8 wk: 6.8 (5.1), −14.4^*^ | Diff ∆^*^:; 8 wk: 3.7
Groenveld, 2023^28^; VR; Some concerns | ODI | 40.1 (19.1); 4 wk: 32.4 (15.1), −7.7^*^; 4 mo: 37.3 (14.5), −2.8^*^ | 42.8 (18.8); 4 wk: 38.8 (17.7), −4.0^*^; 4 mo: 40.9 (17.6), −1.9^*^ | Diff ∆^*^:; 4 wk: −3.7; 4 mo: −0.9
Groenveld, 2023^28^; VR; Some concerns | BPI-Interference | 5.9 (1.7); 4 wk: 4.1 (2.4), −1.8^*^; 4 mo: 4.6 (2.1), −1.3^*^ | 6.3 (2.0); 4 wk: 4.8 (2.5), −1.5^*^; 4 mo: 5.2 (2.0), −1.1^*^ | Diff ∆^*^:; 4 wk: −0.3; 4 mo: −0.2
Kammler-Sücker, 2023^26^; VR; Some concerns | NRS | 2.7 (2.0); Session 2 (~14 days): 2.5 (2.2), −0.2^*^; Session 3 (~27 days): 2.2 (2.2), −0.4^*^ | 1.7 (1.8); Session 2 (~14 days): 2.3 (2.4), 0.5^*^; Session 3 (~27 days): 1.7 (2.1), 0.0^*^ | Diff ∆^*^:; Session 2 (~14 days): −0.7; Session 3 (~27 days): −0.4
Kim, 2014^48^; AR; High | ODI | 34.9 (6.2); 4 wk: 13.8 (7.7), −21.1^*^ | 36.2 (5.0); 4 wk: 24.6 (10.9), −11.6^*^ | Diff ∆^*^:; 4 wk: −9.5
Kim, 2014^48^; AR; High | RMDQ | 18.6 (2.8); 4 wk: 7.5 (4.8), −11.2^*^ | 19.1 (2.9); 4 wk: 12.6 (6.5), −6.5^*^ | Diff ∆^*^:; 4 wk: −4.7
Kim, 2019^43^; AR; High | ODI | 20.2 (7.7); 4 wk: 14.7 (8.1), −5.52^*^; 8 wk: 11.6 (9.0), −8.7^*^; 6 mo: 8.3 (6.3), −12.0^*^ | 21.8 (7.1); 4 wk: 19.5 (9.3), −2.3^*^; 8 wk: 14.8 (9.4), −7.0^*^; 6 mo: 9.2 (3.3), −12.5^*^ | Diff ∆^*^:; 4 wk: −3.21; 8 wk: −1.7; 6 mo: 0.6
Kim, 2019^43^; AR; High | RMDQ | 7.0 (4.4); 4 wk: 3.3 (3.8), −5.2^*^; 8 wk: 2.9 (4.5), −4.1^*^; 6 mo: 1.9 (1.2), −5.2^*^ | 5.1 (2.7); 4 wk: 4.8 (2.5), −3.3^*^; 8 wk: 2.5 (2.3), −2.7^*^; 6 mo: 1.8 (1.1), −3.3^*^ | Diff ∆^*^:; 4 wk: −3.4; 8 wk: −1.4; 6 mo: −1.8
Li 2021^39^; AR; High | ODI | 15.7 (6.4); 2 wk: 12.8 (6.3), −2.9^*^ | MCE; 18.4 (9.4); 2 wk: 14.3 (21.3), −4.1^*^ | Diff ∆^*^:; 2 wk: 1.3
Li 2021^39^; AR; High | ODI | 15.7 (6.4); 2 wk: 12.8 (6.3), −2.9^*^ | CG; 12.7 (4.8); 2 wk: 9.6 (7.2), −3.1^*^ | Diff ∆^*^:; 2 wk: 0.2
Maddox, 2022^32,33^; VR; Some concerns in Domain 4 only | DVPRS-II overall interference | 4.8 (NR); 8 wk: 2.3 (NR), −2.5^*^; 3 mo: 2.7 (NR), −2.1^*^; 4 mo: 2.9 (NR), −1.9^*^; 5 mo: 3.1 (NR), −1.7^*^; 8 mo: 3.0 (2.6), −1.8^*^; 20 mo: 3.3 (2.7), −1.5^*^; 26 mo: 2.8 (2.1), −2.0^*^ | 5.1 (NR); 8 wk: 3.3 (NR), −1.8^*^; 3 mo: 3.8 (NR), −1.3^*^; 4 mo: 4.1 (NR), −1.0^*^; 5 mo: 4.1 (NR), −1.0^*^; 8 mo: 4.2 (2.2), −0.9^*^; 20 mo: 4.3 (2.5), −0.8^*^; 26 mo: 3.8 (2.3), −1.3^*^ | Diff ∆^*^:; 8 wk: −0.7; 3 mo: −0.8; 4 mo: −0.9; 5 mo: −0.7; 8 mo: −0.9; 20 mo: −0.7; 26 mo: −0.7
Mbada, 2019^50^; AR; High | ODI | 18.7 (NR); 8 wk: 21.1 (NR), 2.4^*^ | 27.8 (NR); 8 wk: 25.7 (NR), −2.1^*^ | Diff ∆^*^:; 8 wk: 4.5
Mbada, 2019^50^; AR; High | RMDQ | 6.8 (NR); 8 wk: 5.7 (4.7), −1.1^*^ | 11.3 (NR); 8 wk: 8.9 (4.1), −2.4^*^ | Diff ∆^*^:; 8 wk: 1.3
Yilmaz Yelvar, 2016^25^; VR; High | ODI | 20.7 (7.2); 2 wk: 16.9 (5.5), −3.8^*^ | 26.1 (11.0); 2 wk: 21.1 (9.9), −5.1^*^ | Diff ∆^*^:; 2 wk: 1.2
Zadro, 2019^44^; AR; Some concerns | RMDQ | 6.3 (4.8); 8 wk: 4.9 (4.5), −1.4^*^ | 7.4 (5.2); 8 wk: 6.4 (4.4), −1.0^*^ | Diff ∆^*^:; 8 wk: −0.4
Zadro, 2019^44^; AR; Some concerns | PSFS | 5.3 (1.4); 8 wk: 6.5 (2.1), 1.2^*^ | 4.3 (2.1); 8 wk: 4.8 (2.5), 0.5^*^ | Diff ∆^*^:; 8 wk: 0.7
Pain Intensity or Severity
Afzal, 2022^38^; AR; Some concerns | VAS | 6.5 (1.2); 4 wk: 1.0 (0.6), −5.5^*^ | 6.6 (1.0); 4 wk: 3.3 (0.8), −3.3^*^ | Diff ∆^*^:; 4 wk: −2.2
Eccleston, 2022^27^; VR; Some concerns | NRS | 6.0 (1.4); 8 wk: 4.1 (1.7), −1.9^*^ | VR control; 6.1 (1.4); 8 wk: 4.8 (2.3), −1.3^*^ | Diff ∆^*^:; 8 wk: −0.6
Eccleston, 2022^27^; VR; Some concerns | NRS | 6.0 (1.4); 8 wk: 4.1 (1.7), −1.9^*^ | Usual care; 5.7 (1.6); 8 wk: 4.4 (2.4), −1.3^*^ | Diff ∆^*^:; 8 wk: −0.6
Eccleston, 2022^27^; VR; Some concerns | PROMIS pain intensity | 66.5 (4.1); 8 wk: 60.0 (7.5), −6.5^*^ | VR control; 65.1 (5.4); 8 wk: 61.9 (8.3), −3.2^*^ | Diff ∆^*^:; 8 wk: −3.3
Eccleston, 2022^27^; VR; Some concerns | PROMIS pain intensity | 66.5 (4.1); 8 wk: 60.0 (7.5), −6.5^*^ | Usual care; 63.0 (5.5); 8 wk: 61.0 (5.9), −2.0^*^ | Diff ∆^*^:; 8 wk: −4.5
Groenveld, 2023^28^; VR; Some concerns | VAS – Daily Worst | 6.1 (NR); 30 days: 5.3 (NR), −0.8^*^ | 7.0 (NR); 30 days: 6.8 (NR), −0.2^*^ | Diff ∆^*^:; 30 days: −0.6
Groenveld, 2023^28^; VR; Some concerns | VAS – Daily Least | 3.7 (NR); 30 days: 4.1 (NR), 0.4^*^ | 4.1 (NR); 30 days: 4.9 (NR), 0.8^*^ | Diff ∆^*^:; 30 days: −0.4
Harvie, 2022^24^; VR; Some concerns in Domain 4 only | NRS, average pain over past week | 6.4 (1.4)^†^; 1 wk: 6.1 (1.3)^†^, −0.3^*^ | 6.6 (2.7)^†^; 1 wk: 5.8 (1.9)^†^, −0.8^*^ | Diff ∆^*^:; 1 wk: 0.5
Kammler-Sücker, 2023^26^; VR; Some concerns | NRS | 2.6 (1.1); 14 days: 2.4 (1.8), −0.2^*^; 27 days: 2.5 (2.1), −0.1^*^ | 1.9 (1.6); 14 days: 2.1 (2.3), 0.2^*^; 27 days: 1.8 (1.7), −0.1^*^ | Diff ∆^*^:; 14 days: −0.4; 27 days: 0.02
Kim, 2014^48^; AR; High | VAS | 7.0 (0.9); 4 wk: 2.3 (1.1), −4.7^*^ | 7.0 (0.8); 4 wk: 4.6 (1.9), −2.3^*^ | Diff ∆^*^:; 4 wk: −2.4
Kim, 2019^43^; AR; High | NRS | 4.7 (1.0); 4 wk: 2.25 (1.06),−2.45^*^; 8 wk: 1.3 (0.9), −3.4^*^; 6 mo: 1.4 (1.3), −3.3^*^ | 4.7 (0.8); 4 wk: 2.09 (1.46), =2.64^*^; 8 wk: 1.6 (1.6), −3.1^*^; 6 mo: 1.2 (1.0), −3.5^*^ | Diff ∆^*^:; 4 wk: 0.19; 8 wk: −0.3; 6 mo: 0.2
Li 2021^39^; AR; High | VAS | 4.4 (1.4); 2 wk: 3.2 (1.1), −1.2^*^ | MCE; 4.6 (1.8); 2 wk: 2.2 (1.9), −2.4^*^ | Diff ∆^*^:; 2 wk: 1.2
Li 2021^39^; AR; High | VAS | 4.4 (1.4); 2 wk: 3.2 (1.1), −1.2^*^ | CG; 3.6 (1.4); 2 wk: 2.2 (1.2), −1.5^*^ | Diff ∆^*^:; 2 wk: 0.3
Maddox, 2022^32,33^; VR; Some concerns in Domain 4 only | DVPRS-pain intensity | 5.1 (1.2); 8 wk: 3.0 (0.8), −2.2^*^; 3 mo: 3.6 (NR), −1.5^*^; 4 mo: 3.8 (NR), −1.3^*^; 5 mo: 3.7 (NR), −1.4^*^; 8 mo: 3.6 (2.2), −1.5^*^; 20 mo: 4.2 (2.2), −0.9^*^; 26 mo: 3.9 (2.1), −1.2^*^ | 5.2 (1.1); 8 wk: 4.0 (0.8), −1.2^*^; 3 mo: 4.4 (NR), −0.8^*^; 4 mo: 4.5 (NR), −0.7^*^; 5 mo: 4.5 (NR), −0.7^*^; 8 mo: 4.6 (1.8), −0.6^*^; 20 mo: 5.3 (1.9), 0.1^*^; 26 mo: 4.5 (2.0), −0.7^*^ | Diff ∆^*^:; 8 wk: −1.0; 3 mo: −0.7; 4 mo: −0.6; 5 mo: −0.7; 8 mo: −0.9; 20 mo: −1.0; 26 mo: −0.5
Mbada, 2019^50^; AR; High | VAS | 4.1 (1.8); 8 wk: 3.5 (1.7), −0.6^*^ | 5.0 (1.9); 8 wk: 3.5 (2.3), −1.5^*^ | Diff ∆^*^:; 8 wk: 0.9
Monteiro-Junior, 2015^46^; AR; High | NRS | 6.5 (1.1); 8 wk: 1.7 (1.9), −4.8^*^ | 6.6 (1.2); 8 wk: 1.4 (2.9), −5.2^*^ | Diff ∆^*^:; 8 wk: 0.4
Nambi 2020^37^; AR; Some concerns | VAS | 7.1 (0.6); 4 wk: 3.9 (0.5), −3.2^*^; 8 wk: 1.2 (0.4), −5.9^*^; 6 mo: 0.8 (0.4), −6.3^*^ | IKT-G; 7.3 (0.5); 4 wk: 4.8 (0.4), −2.5^*^; 8 wk: 2.7 (0.3), −4.6^*^; 6 mo: 1.9 (0.3), −5.4^*^ | Diff ∆^*^:; 4 wk: −0.7; 8 wk: −1.3; 6 mo: −0.9
Nambi 2020^37^; AR; Some concerns | VAS | 7.1 (0.6); 4 wk: 3.9 (0.5), −3.2^*^; 8 wk: 1.2 (0.4), −5.9^*^; 6 mo: 0.8 (0.4), −6.3^*^ | Control-G; 7.3 (0.6); 4 wk: 6.2 (0.4), −1.1^*^; 8 wk: 5.4 (0.4), −1.9^*^; 6 mo: 4.2 (0.5), −3.1^*^ | Diff ∆^*^:; 4 wk: −2.1; 8 wk: −4.0; 6 mo: −3.2
Nambi, 2020b^42^; AR; High | VAS | 7.5 (0.4); 4 wk: 2.4 (0.2), −5.1^*^; 6 mo: 0.6 (0.1), −6.9^*^ | 7.3 (0.3); 4 wk: 2.7 (0.3), −4.6^*^; 6 mo: 0.9 (0.2), −6.4^*^ | Diff ∆^*^:; 4 wk: −0.5; 6 mo: −0.5
Nambi, 2020b^42^; AR; High | VAS | 7.5 (0.4); 4 wk: 2.4 (0.2), −5.1^*^; 6 mo: 0.6 (0.1), −6.9^*^ | 7.4 (0.4); 4 wk: 4.5 (0.4), −2.9^*^; 6 mo: 3.5 (0.3), −3.9^*^ | Diff ∆^*^:; 4 wk: −2.2; 6 mo: −3.0
Nambi, 2021^41^; AR; High | VAS | 7.8 (0.6); 4 wk: 1.8 (0.3), −6.0^*^; 6 mo: 0.5 (0.2), −7.3^*^ | CPR; 7.5 (0.5); 4 wk: 3.6 (0.4), −3.9^*^; 6 mo: 2.8 (0.3), −4.7^*^ | Diff ∆^*^:; 4 wk: −2.1; 6 mo: −2.6
Nambi, 2021^41^; AR; High | VAS | 7.8 (0.6); 4 wk: 1.8 (0.3), −6.0^*^; 6 mo: 0.5 (0.2), −7.3^*^ | Control; 7.6 (0.4); 4 wk: 3.8 (0.5), −3.8^*^; 6 mo: 3.2 (0.2), −4.4^*^\ | Diff ∆^*^:; 4 wk: −2.2; 6 mo: −2.9
Nambi, 2023^35^; AR; Some concerns in Domain 4 only | VAS | 7.2 (0.4); 4 wk: 1.8 (0.3), −5.4^*^ | Isokinetic; 7.3 (0.3); 4 wk: 2.5 (0.5), −4.8^*^ | Diff ∆^*^:; 4 wk: −0.6
Nambi, 2023^35^; AR; Some concerns in Domain 4 only | VAS | 7.2 (0.4); 4 wk: 1.8 (0.3), −5.4^*^ | Conventional exercise; 7.2 (0.3); 4 wk: 4.8 (0.4), −2.4^*^ | Diff ∆^*^:; 4 wk: −3.0
Oh, 2014^49^; AR; High | VAS | Horse simulator 30 minutes; 5.6 (0.7); 8 wk: 3.4 (1.0), −2.1 | Control; 3.1 (0.6); 8 wk: 3.8 (0.9), 0.7^*^ | Diff ∆^*^:; 8 wk: −2.8
Oh, 2014^49^; AR; High | VAS | Horse simulator 20 minutes; 4.9 (0.5); 8 wk: 1.1 (0.1), −3.8^*^ | Control; 3.1 (0.6); 8 wk: 3.8 (0.9), 0.7^*^ | Diff ∆^*^:; 8 wk: −4.5
Oh, 2014^49^; AR; High | VAS | Horse simulator 10 minutes; 3.8 (0.5); 8 wk: 1.4 (0.4), −2.3^*^ | Control; 3.1 (0.6); 8 wk: 3.8 (0.9), 0.7^*^ | Diff ∆^*^:; 8 wk: −3.0
Sato, 2021^40^; AR; High | VAS | 7.4 (2.0); 8 wk: 4.8 (3.0), −2.6^*^ | 7.0 (0.9); 8 wk: 6.6 (1.1), −0.4^*^ | Diff ∆^*^:; 8 wk: −2.2
Yilmaz Yelvar, 2016^25^; VR; High | VAS | 6.0 (1.1); 2 wk: 2.5 (1.8), −3.5^*^ | 5.6 (2.4); 2 wk: 4.9 (3.4), −0.7^*^ | Diff ∆^*^:; 2 wk: −2.8
Yoo, 2014^47^; AR; Some concerns | VAS | 4.4 (2.1); 8 wk: 2.2 (2.2), −2.1^*^ | 1.5 (0.1); 8 wk: 1.0 (0.0), −0.5^*^ | Diff ∆^*^:; 8 wk: −1.6
Zadro, 2019^44^; AR; Some concerns | NRS | 5.2 (1.6); 8 wk: 3.8 (2.4), −1.4^*^ | 4.8 (1.7); 8 wk: 4.4 (2.3), −0.4^*^ | Diff ∆^*^:; 8 wk: −1.0
Adverse Events
Eccleston, 2022^27^; VR; Some concerns | NR | DTxP (n=12); All: 12 (100%); Mild: 4 (33%); Moderate: 10 (83%); Severe: 6 (50%); Treatment-related: 3 (25%); Serious: 0 | VR control (n=17); All: 14 (83%); Mild: 6 (35%); Moderate: 11 (65%); Severe: 5 (29%); Treatment-related: 6 (35%); Serious: 0 | Diff ∆^*^:; All: 18%; Severe: 21%
Eccleston, 2022^27^; VR; Some concerns | NR | DTxP (n=12); All: 12 (100%); Mild: 4 (33%); Moderate: 10 (83%); Severe: 6 (50%); Treatment-related: 3 (25%); Serious: 0 | Usual care (n=11); All: 7 (64%); Mild: 2 (18%); Moderate: 6 (55%); Severe: 4 (36%); Treatment-related: 2 (18%); Serious: 0 | Diff ∆^*^:; All: 36%; Severe: 14%
Groenveld, 2023^28^; VR; Some concerns | NR | 3 (20%) reported mild and temporary symptoms of dizziness | No AEs assessed | Diff ∆: NC
Thomas, 2016^45^; AR; Some concerns in Domain 4 only | NR | No AEs reported | No AEs reported | Diff ∆^*^:; 4 days: 0
Pain Catastrophizing & Kinesiophobia
Eccleston, 2022^27^; VR; Some concerns | TSK | 41.9 (4.4); 8 wk: 33.7 (7.4), −8.2^*^ | VR control; 43.2 (6.0); 8 wk: 43.1 (8.5), −0.1^*^ | Diff ∆^*^:; 8 wk: −8.1
Eccleston, 2022^27^; VR; Some concerns | TSK | 41.9 (4.4); 8 wk: 33.7 (7.4), −8.2^*^ | Usual care; 42.5 (5.4); 8 wk: 39.8 (7.1), −2.7^*^ | Diff ∆^*^:; 8 wk: −5.5
Groenveld, 2023^28^; VR; Some concerns | PCS | 21.7 (12.2); 4 wk: 23.4 (13.8), 1.7^*^; 4 mo: 23.9 (12.5), 2.2^*^ | 24.7 (7.8); 4 wk: 25.7 (9.5), 1.0^*^; 4 mo: 27.1 (9.7), 2.4^*^ | Diff ∆^*^:; 4 wk: 0.7; 4 mo: −0.2
Kim, 2014^48^; AR; High | FABQ | 65.5 (9.6); 4 wk: 17.6 (10.7), −47.9^*^ | 70.8 (4.6); 4 wk: 41.6 (18.0), −29.2^*^ | Diff ∆^*^:; 4 wk: −18.7
Kim, 2019^43^; AR; High | FABQ-physical | 15.4 (4.1); 4 wk: 9.0 (3.64), −6.4^*^; 8 wk: 8.8 (5.9), −6.6^*^; 6 mo: 4.1 (4.1), −11.2^*^ | 11.9 (5.6); 4 wk: 16.3 (9.55), 4.4^*^; 8 wk: 11.1 (9.1), −0.8^*^; 6 mo: 9.7 (7.1), −2.3^*^ | Diff ∆^*^:; 4 wk: −10.8; 8 wk: −5.7; 6 mo: −8.9
Kim, 2019^43^; AR; High | FABQ-work | 17.1 (5.3); 4 wk: 15.2 (7.1), −1.9^*^; 8 wk: 11.4 (7.5), −5.7^*^; 6 mo: 13.9 (7.1), −3.3^*^ | 20.5 (7.9); 4 wk: 22.4 (5.62), 1.9^*^; 8 wk: 14.7 (6.5), −5.8^*^; 6 mo: 16.5 (9.0), −4.0^*^ | Diff ∆^*^:; 4 wk: −3.78; 8 wk: 0.1; 6 mo: 0.7
Mbada, 2019^50^; AR; High | FABQ-work | 21.2 (NR); 8 wk: 24.5 (NR), 3.3^*^ | 25.7 (NR); 8 wk: 22.6 (NR), −3.1^*^ | Diff ∆^*^:; 8 wk: 6.4
Mbada, 2019^50^; AR; High | TSK | 16.5 (NR); 8 wk: 28.8 (NR), 12.3^*^ | 29.9 (NR); 8 wk: 18.7 (NR), −11.2^*^ | Diff ∆^*^:; 8 wk: 23.5
Nambi, 2020b^42^; AR; High | TSK | 57.5 (4.8); 4 wk: 26.4 (3.5), −31.1^*^; 6 mo: 20.1 (2.5), −37.4^*^ | IKT; 58.1 (4.5); 4 wk: 27.5 (3.8), −30.6^*^; 6 mo: 21.2 (2.4), −36.9^*^ | Diff ∆^*^:; 4 wk: −0.5; 6 mo: −0.5
Nambi, 2020b^42^; AR; High | TSK | 57.5 (4.8); 4 wk: 26.4 (3.5), −31.1^*^; 6 mo: 20.1 (2.5), −37.4^*^ | Control; 57.9 (4.3); 4 wk: 46.2 (4.1), −11.7^*^; 6 mo: 38.6 (3.9), −19.3^*^ | Diff ∆^*^:; 4 wk: −19.4; 6 mo: −18.1
Nambi, 2021^41^; AR; High | TSK | 56.5 (3.2); 4 wk: 28.3 (3.3), −28.1^*^; 6 mo: 20.1 (2.8), −36.4^*^ | CPR; 58.0 (3.8); 4 wk: 38.5 (3.5), −19.5^*^; 6 mo: 29.7 (2.2), −28.4^*^ | Diff ∆^*^:; 4 wk: −8.7; 6 mo: −8.0
Nambi, 2021^41^; AR; High | TSK | 56.5 (3.2); 4 wk: 28.3 (3.3), −28.1^*^; 6 mo: 20.1 (2.8), −36.4^*^ | Control; 57.7 (4.1); 4 wk: 45.4 (3.3), −12.3^*^; 6 mo: 39.1 (2.9), −18.6^*^ | Diff ∆^*^:; 4 wk: −15.9; 6 mo: −17.8
Sato, 2021^40^; AR; High | PCS | 43.5 (8.0); 8 wk: 39.9 (7.8), −3.6^*^ | 40.8 (0.0); 8 wk: 42.1 (6.9), 1.4^*^ | Diff ∆^*^:; 8 wk: −4.9
Sato, 2021^40^; AR; High | TSK | 42.5 (5.9); 8 wk: 39.7 (4.6), −2.8^*^ | 38.9 (5.4); 8 wk: 36.2 (3.2), −2.7^*^ | Diff ∆^*^:; 8 wk: −0.1
Yilmaz Yelvar, 2016^25^; VR; High | Tampa Scale of Kinesiophobia (TSK) | 43.7 (4.3); 2 wk: 29.6 (4.0), −14.2^*^ | 40.4 (5.6); 2 wk: NR (5.4), NC | Diff ∆: NC
Zadro, 2019^44^; AR; Some concerns | TSK | 33.6 (6.1); 8 wk: 32.3 (7.1), −1.3^*^ | 34.7 (5.8); 8 wk: 35.9 (5.8), 1.2^*^ | Diff ∆^*^:; 8 wk: −2.5
Pain Global Change
Eccleston, 2022^27^; VR; Some concerns | PGIC (assessed only at follow-up) | 8 wk: 2.7 (1.4); 5 mo: 3.0 (1.5) | VR control; 8 wk: 3.8 (1.5); 5 mo: 3.0 (1.5) | Diff ∆:; 8 wk: −1.1; 5 mo: 0.0
Eccleston, 2022^27^; VR; Some concerns | PGIC (assessed only at follow-up) | 8 wk: 2.7 (1.4); 5 mo: 3.0 (1.5) | Usual care; 8 wk: 3.9 (0.7) | Diff ∆:; 8 wk: −1.2
Harvie, 2022^24^; VR; Some concerns in Domain 4 only | PGIC (assessed only at follow-up) | At least minimally improved: 37%; No change: 55%; Minimally worse: 5% | At least minimally improved: 11%; No change: 89%; Minimally worse: 0% | Diff ∆^*^:; 1 wk at least minimally improved): 26%; 1 wk minimally worse: 5%
Quality of Life
Eccleston, 2022^27^; VR; Some concerns | European Quality of Life 5 (EuroQoL-5D-5L) Health State ( | 47.7 (16.8); 8 wk: 66.1 (22.2), 18.4^*^ | VR control; 63.8 (15.1); 8 wk: 58.1 (26.8), −5.7^*^ | Diff ∆^*^:; 8 wk: 24.1
Eccleston, 2022^27^; VR; Some concerns | European Quality of Life 5 (EuroQoL-5D-5L) Health State ( | 47.7 (16.8); 8 wk: 66.1 (22.2), 18.4^*^ | Usual care; 55.7 (19.6); 8 wk: 62.0 (23.9), 6.3^*^ | Diff ∆^*^:; 8 wk: 12.1
Groenveld, 2023^28^; VR; Some concerns | SF-12-physical | 34.9 (7.5); 4 wk: 39.1 (6.3), 4.2^*^; 4 mo: 38.5 (8.7), 3.6^*^ | 32.9 (7.7); 4 wk: 34.8 (7.1), 1.9^*^; 4 mo: 36.8 (7.5), 3.9^*^ | Diff ∆^*^:; 4 wk: 2.3; 4 mo: −0.3
Groenveld, 2023^28^; VR; Some concerns | SF-12-mental | 45.6 (7.2); 4 wk: 48.9 (7.5), 3.3^*^; 4 mo: 46.4 (10.1), 0.8^*^ | 43.0 (8.9); 4 wk: 46.0 (10.9), 3.0^*^; 4 mo: 46.2 (11.8), 3.2^*^ | Diff ∆^*^:; 4 wk: 0.3; 4 mo: −2.4
Mbada, 2019^50^; AR; High | SF-12-mental | 71.8 (6.0); 8 wk: 19.4 (11.6), −52.4^*^ | 70.0 (9.1); 8 wk: 26.6 (13.3), −43.4^*^ | Diff ∆^*^:; 8 wk: −9.0
Mbada, 2019^50^; AR; High | SF-12-physical | 68.8 (6.1); 8 wk: 11.6 (8.7), −57.2^*^ | 64.3 (10.8); 8 wk: 16.3 (13.0), −48.0^*^ | Diff ∆^*^:; 8 wk: −9.2
Yilmaz Yelvar, 2016^25^; VR; High | Nottingham Health Profile | 226.1 (75.9); 2 wk: 196.1 (109.2), −30.0^*^ | 158.4 (125.8); 2 wk: 140.9 (117.9), −17.5^*^ | Diff ∆^*^:; 2 wk: −12.5
Physical Performance
Mbada, 2019^50^; AR; High | Biering-Sorensen test of Statis Muscular Endurance (BSME) | 35.3 (22.5); 8 wk: −21.9 (14.6), −57.2^*^ | 20.6 (13.3); 8 wk: −15.1 (7.9), −35.7^*^ | Diff ∆^*^:; 8 wk: −21.5
Monteiro-Junior, 2015^46^; AR; High | Floor to Sit to Stand-Sit (max 5 pts) | 2.3 (1.5); 8 wk: 3.3 (0.9), 1.0^*^ | 2.8 (1.0); 8 wk: 3.2 (0.9), 0.4^*^ | Diff ∆^*^:; 8 wk: 0.6
Monteiro-Junior, 2015^46^; AR; High | Floor to Sit to Stand-Stand Up (max 5 pts) | 1.7 (1.6); 8 wk: 2.5 (1.0), 0.8^*^ | 2.5 (1.2); 8 wk: 2.8 (1.3), 0.3^*^ | Diff ∆^*^:; 8 wk: 0.5
Yilmaz Yelvar, 2016^25^; VR; High | Timed-up and go test (TUG) | 7.7 (1.0); 2 wk: 5.3 (0.9), −2.5^*^ | 8.0 (1.7); 2 wk: 7.6 (1.3), −0.4^*^ | Diff ∆^*^:; 2 wk: −3.9
Yilmaz Yelvar, 2016^25^; VR; High | 6-minute walk test | 414.3 (120.7); 2 wk: 504.9 (130.8), 90.6^*^ | 401.1 (64.0); 2 wk: 400.7 (59.9), −0.4^*^ | Diff ∆^*^:; 2 wk: 91.0
Opioid Use
Groenveld, 2023^28^; VR; Some concerns | Used opioids at least once weekly | N (%):; 1 wk: 9 (47); 4 wk: 5 (28), −19^*^ | N (%):; 1 wk: 7 (37); 4 wk: 7 (37), 0^*^ | Diff ∆^*^:; 4 wk: −19%

Notes.

* Calculated by study team.

† Values derived from figures using plotdigitizer.com, SD calculated from 95% CI whenever possible.

Abbreviations. AE=Adverse events; BPI=Brief Pain Inventory; CI=confidence intervals; DVPRS-II= Defense and Veterans Pain Rating Scale; MODI=Modified Oswestry Disability Index; NC=not calculable; NR=not reported; NRS=numeric rating system; ODI=Oswestry Disability Index; PCS=Pain Catrastrophizing Scale; PGIC=Patient Global Impression of Change scale; PSFW=Patient Specific Functional Scale; RMDQ=Roland-Morris Disability Questionnaire; SD=standard deviation; SF-12=Short Form Health Survey; TSK=Tampa Scale of Kinesiophobia; VAS=Visual Analog Scale.