# APPENDIX D RISK OF BIAS ASSESSMENTS

## RANDOMIZED CONTROLLED TRIALS (ROB-2)

Trial Name or Author Year | Bias from randomization process | Bias from deviation from intended interventions (Assignment) | Bias from deviation from intended interventions (Adherence) | Bias from missing outcome data | Bias in measurement of outcome | Bias in selection of reported result | Overall risk of bias (Low, Some concerns, High)
Afzal, 2022^38^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns
Ambrosino, 2020^75^ | Some concerns | Low | Low | Low | Some concerns | Some concerns | Some concerns
Bahat, 2020^90^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns
Carvalho, 2020^58^ | Some concerns | Low | High | High | Some concerns | Some concerns | High
Cetin, 2022^51^ | Low | High | High | High | Some concerns | Low | High
Chuan, 2023^71^ | Some concerns | Low | Some concerns | Low | Low | Low | Some concerns
Collado-Mateo, 2017^60^ | Low | Low | Some concerns | High | Some concerns | Low | High
Cuneo, 2023^70^ | Some concerns | High | High | High | Some concerns | Low | High
Darnall, 2020^72^ | Some concerns | Low | Some concerns | Some concerns | Some concerns | Some concerns | High
Ditchburn, 2020^81^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | High
Eccleston, 2022^27^ | Low | Low | Some concerns | Low | Low | Low | Some concerns
Eichler, 2019^84^ | Some concerns | Low | Low | High | Some concerns | Low | High
Elshazly, 2016^66^ | Some concerns | Low | Low | Low | Some concerns | Some concerns | Some concerns
Fatoye, 2022^36^ | Some concerns | High | High | High | Some concerns | Some concerns | High
Fuchs, 2022^82^ | Some concerns | Low | Some concerns | High | Some concerns | Some concerns | High
Garcia-Palacios, 2015^64^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | High
Gouveia, 2020^76^ | Low | Low | Some concerns | Some concerns | Some concerns | Low | Some concerns
Groenveld, 2023^28^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Harvie, 2022^24^ | Low | Low | Low | Low | Some concerns | Low | Some concerns in Domain 4 only
Janhunen, 2023^85^ | Low | Low | Some concerns | Some concerns | Some concerns | Low | Some concerns
Jin, 2018^83^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | High
Kammler-Sucker, 2023^26^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Karahan, 2016^77^ | Low | Low | Low | Low | Some concerns | Some concerns | Some concerns
Kim, 2014^48^ | Some concerns | Low | Low | Low | Some concerns | Some concerns | High
Kim, 2020^43^ | Some concerns | Some concerns | Some concerns | Some concerns | Some concerns | Some concerns | High
Lewis, 2021^78^ | Low | Low | Some concerns | High | Some concerns | Low | High
Li, 2021^39^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | High
Lin, 2020^67^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns
Maddox, 2022^32^ | Low | Low | Low | Low | Some concerns | Low | Some concerns in Domain 4 only
Mbada, 2019^50^ | High | Low | High | High | High | Some concerns | High
Mete, 2022^68^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | High
Monteiro-Junior, 2015^46^ | Some concerns | High | Low | High | Some concerns | Low | High
Nambi, 2020a^37^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | Some concerns
Nambi, 2020c^69^ | Low | Low | Low | Low | Some concerns | Some concerns | Some concerns
Nambi, 2021^41^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | High
Nambi, 2021^42^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Some concerns | High
Nambi, 2022^35^ | Low | Low | Low | Low | Some concerns | Low | Some concerns in Domain 4 only
Nusser, 2021^52^ | Some concerns | High | Low | High | Some concerns | Some concerns | High
Oh, 2014^49^ | Some concerns | Low | Low | High | High | Some concerns | High
Ozlu, 2023^65^ | Some concerns | High | High | High | Some concerns | Some concerns | High
Piqueras, 2013^86^ | Low | Low | High | High | Some concerns | Low | High
Polat, 2021^57^ | Some concerns | Low | Low | Some concerns | Some concerns | Some concerns | High
Prvu Bettger, 2020^87^ | Low | Low | Low | Low | Some concerns | Low | Some concerns in Domain 4 only
Reynolds, 2022^73^ | Some concerns | High | High | High | Some concerns | Low | High
Rezaei, 2019^56^ | Some concerns | Low | Low | High | Some concerns | Low | High
Rodriguez-Hernandez, 2021^92^ | Some concerns | Low | Some concerns | High | Some concerns | Low | High
Rothangel, 2018^79^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns
Sarig Bahat, 2015^55^ | Low | Low | Low | Low | Some concerns | Low | Some concerns in Domain 4 only
Sarig Bahat, 2018^54^ | Low | Low | Some concerns | Some concerns | Some concerns | Low | Some concerns
Sato, 2021^40^ | Low | Some concerns | Some concerns | Low | Some concerns | Some concerns | High
Shim, 2023^88^ | Low | Low | Some concerns | Some concerns | Some concerns | Low | Some concerns
Taveggia, 2016^94^ | Low | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns
Tejara, 2020^53^ | Low | Low | Low | Low | Some concerns | Low | Some concerns in Domain 4 only
Thomas, 2016^45^ | Low | Low | Low | Low | Some concerns | Low | Some concerns in Domain 4 only
Villafaina, 2019^59^ | Low | Low | Low | Some concerns | Some concerns | Low | Some concerns
Wankhade, 2022^74^ | Some concerns | Some concerns | High | Low | Some concerns | Some concerns | High
Yilmaz Yelvar, 2017^25^ | High | Low | High | Low | Some concerns | Some concerns | High
Yoo, 2014^47^ | Some concerns | Low | Low | Low | Some concerns | Some concerns | Some concerns
Zadro, 2019^44^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns

## NONRANDOMIZED COMPARISON STUDIES (ROBINS-I)

Study Name or Author Year | Preliminary considerations | Bias due to confounding | Selection bias | Bias in classification of interventions | Bias due to departures from intended interventions | Bias due to measurement of outcomes | Bias due to missing data | Bias in the selection of reported results | Overall risk of bias (Low, Moderate, Serious, Critical, No Information)
Abd-Elsayed, 2021^91^ | Critical | -- | -- | -- | -- | -- | -- | -- | Critical