# APPENDIX C ONGOING STUDIES

Trial # | Study Title | Status | Total N^*^ | Location
KQ1 Studies
NCT04468074 | Virtual Reality Treatment for Adults With Chronic Back Pain | Completed (no publication) | 72 | Boulder, Colorado, USA
NCT05634291 | Effects of the Nottingham Augmented Reality (AR) App for Arthritis Hand Joint Pain | Completed (no publication) | 36 | San Diego, California, USA
NCT05285462 | Feasibility of Virtual Reality Delivery of Pain Neuroscience Education | Completed (no publication) | 52 | Nashville, Tennessee, USA
NCT04849897 | Virtual Reality Guided Imagery for Chronic Pain | Completed (no publication) | 36 | Los Angeles, California, USA
NCT05398549 | Effects of Virtual Reality in Adhesive Capsulitis on Pain, Range of Motion and Function | Completed (no publication) | 36 | Lahore, Punjab, Pakistan
NCT04572074 | Virtual Reality for Cancer Pain Management | Completed (only protocol paper) | 128 | Washington, D.C., USA
NCT05701891 | Virtual Reality Integrated Within Physiotherapy for Patients With Complex Chronic Low Back Pain | Recruiting (only protocol paper) | 120 | Nijmegen, Netherlands
NCT05483816 | Multisensory Stimulation to Target Sensory Loss and Chronic Pain in Neuropathic Patients | Recruiting (no publication) | 80 | Zurich, Switzerland
NCT05172492 | Endocare for Pelvic-perineal Pain Related to Endometriosis Used at Home | Recruiting (no publication) | 120 | Bordeaux, Gironde, France
NCT05085821 | Cardio-visual Stimulation in Augmented Reality for Pain Reduction | Recruiting (no publication) | 50 | Nancy, France
NCT02995434 | Immersive Multimedia as an Adjunctive Measure for Pain Control in Cancer Patients | Recruiting (no publication) | 100 | Surrey and Vancouver, British Columbia, Canada
NCT05859321 | Virtual Reality Based Physical Therapy for Patients With Lower Back Pain | Recruiting (no publication) | 84 | Lahore, Punjab, Pakistan
NCT05838924 | Changing Lower Back Pain Through Virtual Reality | Recruiting (no publication) | 60 | Valencia, Spain
NCT05776992 | Effect of Various Virtual Reality Exercise Individuals With Low Back Pain | Recruiting (no publication) | 52 | Istanbul, Turkey
NCT05546749 | Virtual Reality for Chronic Pain and Opioid Use Disorder Pilot | Recruiting (no publication) | 40 | Bronx, New York, USA
NCT05726123 | Therapeutic Intervention With Neuromodulation and Inverse Virtual Reality in Patients With Fibromyalgia | Recruiting (no publication) | 60 | Madrid, Spain
NCT05595317 | The Effects of Non-Immersive Virtual Reality Exercises on Muscle Excitability in Knee Osteoarthritis | Recruiting (no publication) | 44 | Erzurum, Turkey
NCT04867187 | rTMS Efficacy Coupled With Mirror Therapy | Recruiting (no publication) | 64 | Bron and Saint-Étienne, France
NCT05296265 | Efficacy and Mechanisms of Virtual Reality Treatment of Phantom Leg Pain | Recruiting (no publication) | 40 | Elkins Park and Philadelphia, Pennsylvania, and Seattle, Washington, USA
NCT05254509 | Virtual Reality, Debriefing and Chronic Pain | Recruiting (no publication) | 50 | Pittsburgh, Pennsylvania, USA
NCT04933474 | Pragmatic Comparative Effectiveness Trial of Evidence-based, On-demand, Digital Behavioral Treatments for Chronic Pain | Recruiting (no publication) | 300 | Los Angeles, California, USA
NCT05005026 | Virtual Walking Intervention for Neuropathic Pain in Spinal Cord Injury | Recruiting (no publication) | 250 | Birmingham, Alabama & Richmond, Virginia, USA; Sydney, New South Wales, Australia
NCT04906707 | Home-Based Intervention for Chronic Pain in Adults With Sickle Cell Disease (RelieVRx) | Recruiting (no publication) | 50 | Atlanta, Georgia, USA
NCT05160038 | Embodied Virtual Reality for Chronic Pain | Recruiting (no publication) | 80 | Zurich, Zurich, Switzerland
NCT04907643 | Virtual Reality for GI Cancer Pain to Improve Patient Reported Outcomes | Recruiting (no publication) | 360 | Los Angeles, California, USA
NCT04253691 | Sleep and Pain Intervention for Chronic Insomnia Using Virtual Reality Pilot Study | Recruiting (no publication) | 60 | Columbia, Missouri, USA
NCT05348174 | Randomized Controlled Trial of Virtual Reality Assisted Guided Imagery (VRAGI) for Pain in Advanced Cancer Patients. | Not yet recruiting (only protocol paper) | 80 | Clemson, Columbia, and Greenville, South Carolina, USA
NCT05971966 | Effects of Virtual Reality Rehabilitation and Muscle Energy Technique in Patients With Patellofemoral Pain Syndrome. | Not yet recruiting (no publication) | 32 | Islamabad, Punjab, Pakistan
NCT05933941 | Virtual Reality as a Treatment Tool for Chronic Neck Pain in Patients With Fibromyalgia | Not yet recruiting (no publication) | 50 | Madrid, Spain
NCT05880511 | Augmented Reality Sensorimotor Training to Treat Chronic Neck | Not yet recruiting (no publication) | 40 | Hamilton, Ontario, Canada
NCT05810428 | Artificial Intelligence to Predict Surgical Outcomes and Assess Pain Neuromodulation in Trigeminal Neuralgia Subjects | Not yet recruiting (no publication) | 50 | Milan, Italy
NCT05639764 | Immersive Virtual Reality for Pain-related Movement Dysfunctions in Patients With Chronic Shoulder Pain | Not yet recruiting (no publication) | 66 | Málaga, Spain
NCT05263037 | EaseVRx-8w+ for the Treatment of Chronic Lower Back Pain | Active not recruiting (no publication)^‡^ | 1093 | Van Nuys, California, USA
NCT04241172 | TKR Rehabilitation Through the Immersive Virtual Reality in Aquatic Scenarios | Active not recruiting (no publication) | 96 | Rome, Italy
NCT03592394 | Virtual Reality for Chronic Neuropathic Pain | Unknown (no publication) | 40 | White Plains, New York, USA
NCT04651478 | Mental Representation Techniques for the Treatment of Parkinson’s Disease-related Pain | Unknown (only protocol paper) | 32 | Madrid, Spain
NCT04955613 | 6Degrees VR System for Treatment of Phantom Limb Pain | Unknown (no publication) | 122 | Ramat Gan, Israel
NCT04411264 | Evaluation of the Effect of Virtual Reality on Pain in the Management of Chronic Wounds. | Unknown (no publication) | 124 | Limoges and Saint-Pierre, France
NCT04237766 | Movement Visualization in Patients With Hemophilic Arthropathy | Unknown (no publication) | 140 | NR
NCT04966468 | Look of Life 2.0. Virtual Reality for Cancer Patients in Home Palliative Care | Unknown (no publication) | 60 | Bologna, Italy
NCT05088668 | Augmented Reality for Shoulder Pain and Scapular Dyskinesis | Suspended | 52 | Alcala de Henares, Spain
ACTRN12623000745640 | Supercharging Chronic Pain Education: Efficacy of Experiential Immersive Education (iED) using Virtual Reality for Pain Beliefs in Adults with Chronic Non-Cancer Pain. | Not yet recruiting | 90 | Southport, Queensland, Australia
ISRCTN59420095 | Trunk Flexion Improvement in People with Low Back Pain Through Visual-Haptic Illusion: A Randomised Controlled Trial | Completed (publication intended 3/31/23) | 60 | Savona, Italy
ISRCTN12473220 | At-Home Virtual Reality as a Therapeutic Approach for Individuals with Chronic Temporomandibular Joint Disorders | Completed (publication intended 12/30/24) | 54 | Baltimore, Maryland, USA
KQ2 Studies
NCT04010266 | RelieVRx for Total Knee Arthroplasty (TKA) for the Reduction of Acute Postoperative Pain and Opioid Use | Active not recruiting (no publication) | 113 | Danville and Wilkes-Barre, Pennsylvania, USA
NCT03987334 | Virtual Reality Rehabilitation in Neck Pain Subjects | Unknown (no publication) | 72 | Milan, Italy
NCT03476148 | Home Rehabilitation Using Interactive Device Versus Inpatient Rehabilitation in Total Knee Arthroplasty | Unknown (no publication) | 60 | NR

Notes.

* Total participants are actual enrolled for completed studies; all others are estimated totals.

‡ After the database searches were completed, including of registries for clinical trials, a report of this trial was published in December 2023 (Maddox et al 2023, doi: 10.1016/j.mcpdig.2023.09.003).

Abbreviations. NR=not reported; USA=United States of America.