# ABBREVIATIONS TABLE

Abbreviation: Definition
2D: 2-dimensional
3D-TV: 3-dimensional television
6MWT: 6-minute walk test
ACL: Anterior cruciate ligament
ACR: American College of Rheumatology
ADIM: Abdominal drawing-in maneuver
AE: Adverse event
AR: Augmented reality
ARAT: Action Research Arm Test
ASQOL: Ankylosing Spondylitis Quality of Life
BASDAI: Bath Ankylosing Spondylitis Disease Activity Index
BASFI: Bath Ankylosing Spondylitis Functional Index
BPI: Brief Pain Inventory
BSME: Biering-Sorensen test of Statis Muscular Endurance
CAP: Concerns About Pain
CAVE: Cave Automatic Virtual Environment
CBT: Cognitive behavioral therapy
CDC: Center for Disease Control
CI: Confidence interval
CINAHL: Cumulative Index to Nursing and Allied Health Literature
CLBP: Chronic low back pain
Cm: Centimeter
COE: Certainty of Evidence
CPM: Continuous passive motion
CRPS: Complex Regional Pain Syndrome
CTMT: Conventional thermal magnetic therapy
Diff ∆: Difference in change scores
DTxP: Digital therapeutics, virtual reality, psychological intervention for pain
DVPRS: Defense and Veterans Pain Rating Scale
ECOG: Eastern Cooperative Oncology Group
EuroQoL-5D-5L: European Quality of Life-5 questionnaire
EuroQoL-5D-VAS: European Quality of Life – Visual Analog Scale
FABQ: Fear Avoidance Belief Questionnaire
FACIT: Functional Assessment of Chronic Illness Therapy
FIM: Functional Independence Measure
FIQ: Fibromyalgia Impact Questionnaire
GPE: Global Perceived Effect scale
GRADE: Grading of Recommendations, Assessment, Development, and Evaluation
GRADEpro GDT: GRADEpro Guideline Development Tool
HAQ: Health Assessment Questionnaire
Hr: Hour
HSM: Horse simulator machine
HSR: VA Health Systems Research
IKT: Isokinetic training
IQR: Interquartile range
IREX: Interactive Rehabilitation and Exercise
KOOS: Knee Injury and Osteoarthritis Outcome Score
KQ: Key questions
KT: Kinematic training
LBP: Low back pain
M: Meters
MAS: Modified Ashworth Scale for Grading Spasticity
MCE: Motor control exercise
MI: Motricity Index
MIDAS: Migraine Disability Assessment Test
MME: Morphine milligram equivalence
MODI: Modified Oswestry Disability Index
MSK: Musculoskeletal
MVR: Mediated virtual reality
N/A: Not applicable
NC: Not calculable
NDI: Neck Disability Index
No.: Number
NR: Not reported
NRS: Numeric Rating Scale
NSAIDS: Non-steroidal anti-inflammatory drugs
OA: Osteoarthritis
ODI: Oswestry Disability Index
OKS: Oxford Knee Score
oMEDD: Oral morphine equivalent daily dose
OP: Operational Partners
PASS-20: Pain Anxiety Symptom Scale
PCS: Pain Catastrophizing Scale
PDI: Pain Disability Index
PGIC: Pain Global Impression of Change scale
PI: Prediction interval
PMOP: VA National Pain Management, Opioid Safety, and Prescription Drug Monitoring Program
PRO: Patient-reported outcomes
PROMIS: Patient-Reported Outcomes Measurement Information System
PROSPERO: International Prospective Register of Systematic Reviews
PSFS: Patient Specific Function Scale
PT: Physical therapy
QLQ-C30: The European Organisation for Research and Treatment of Cancer (EORTC) Quality of Life Questionnaire Core 30
RA: Rheumatoid arthritis
RAPT: Risk Assessment Prediction Tool
RCT: Randomized controlled trial
RFIQ: Revised Fibromyalgia Impact Questionnaire
RMDQ: Roland-Morris Disability Questionnaire
RoB: Risk of bias
ROBINS-I: Cochrane Risk Of Bias In Non-randomised Studies – of Interventions
ROM: Range of motion
SD: Standard deviation
SF-12: 12-item Short Form health survey
SF-36: 36-item Short Form health survey
SF-36 MCS: 36-item Short Form health survey mental component score
SF-36 PCS: 36-item Short Form health survey physical component score
SMD: Standardized mean difference
SMT: Sensorimotor training
SPADI: Shoulder Pain and Disability Index
SPPB: Short Performance Physical Battery
TENS: Transcutaneous electrical nerve stimulation
TEP: Technical Expert Panel
THA: Total hip arthroplasty
TKA: Total knee arthroplasty
TNF: Tumor necrosis factor
TSK: Tampa Scale of Kinesiophobia
TUG: Timed Up and Go test
UK: United Kingdom
US: United States
VA: Veteran’s Affairs
VAS: Visual Analog Scale
VERA: Virtual Exercise Rehabilitation Assistant
VHA: Veteran’s Health Administration
VR: Virtual reality
WHOQOL-BREF: World Health Organization Quality of Life Brief Version
WOMAC: Western Ontario and McMaster Universities Arthritis Index
XR: Extended reality
Yr: Years